# Appendix F Clinical Pathology Results

Table F‑1 Clinical Pathology Data for Rats at the 14-week Interim Evaluation in the Two-year GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
n | 10 | 10 | 10 | 10
Male
Hematology
Hematocrit (%) | 52.0 ± 0.3 | 51.7 ± 0.2 | 51.8 ± 0.6 | 52.4 ± 0.4
Manual hematocrit (%) | 50 ± 0 | 50 ± 0 | 50 ± 1 | 51 ± 1
Hemoglobin (g/dL) | 16.5 ± 0.1 | 16.5 ± 0.1 | 16.6 ± 0.2 | 16.7 ± 0.2
Erythrocytes (106/μL) | 8.88 ± 0.07 | 8.92 ± 0.05 | 9.15 ± 0.10 | 8.94 ± 0.08
Reticulocytes (106/μL) | 270.4 ± 3.9 | 259.4 ± 7.3 | 258.2 ± 7.0 | 265.6 ± 9.5
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.10 ± 0.10
Mean cell volume (fL) | 58.5 ± 0.4 | 58.0 ± 0.5 | 56.7 ± 0.5 | 58.6 ± 0.5
Mean cell hemoglobin (pg) | 18.6 ± 0.1 | 18.5 ± 0.1 | 18.2 ± 0.2 | 18.8 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 31.7 ± 0.1 | 31.9 ± 0.1 | 32.0 ± 0.2 | 32.0 ± 0.2
Platelets (103/μL) | 894 ± 41 | 896 ± 34 | 954 ± 57 | 896 ± 24
Leukocytes (103/μL) | 9.34 ± 0.50 | 9.23 ± 0.45 | 9.38 ± 0.52 | 9.63 ± 0.65
Segmented neutrophils (103/μL) | 1.19 ± 0.09 | 1.02 ± 0.06 | 1.29 ± 0.11 | 1.33 ± 0.11
Lymphocytes (103/μL) | 7.66 ± 0.48 | 7.78 ± 0.43 | 7.68 ± 0.53 | 7.87 ± 0.59
Monocytes (103/μL) | 0.26 ± 0.03 | 0.22 ± 0.02 | 0.20 ± 0.02 | 0.22 ± 0.02
Basophils (1━◂/ L) | 0.05 ± 0.01 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.05 ± 0.01
Eosinophils (103/μL) | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
Large unstained cells (103/μL) | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01
Clinical Chemistry
Urea nitrogen (mg/dL) | 18.1 ± 0.6 | 17.6 ± 0.4 | 17.7 ± 0.4 | 18.1 ± 0.5
Creatinine (mg/dL) | 0.50 ± 0.01 | 0.54 ± 0.02 | 0.54 ± 0.01* | 0.56 ± 0.01**
Glucose (mg/dL) | 135 ± 6 | 134 ± 4 | 127 ± 2 | 128 ± 3
Total protein (g/dL) | 6.1 ± 0.1 | 6.2 ± 0.1 | 6.1 ± 0.1 | 6.3 ± 0.1
Albumin (g/dL) | 3.6 ± 0.0 | 3.7 ± 0.1 | 3.7 ± 0.0 | 3.7 ± 0.0
Cholesterol (mg/dL) | 92 ± 2 | 86 ± 3 | 87 ± 3 | 88 ± 4
Triglycerides (mg/dL) | 88 ± 6 | 88 ± 10 | 98 ± 6 | 96 ± 6
Alanine aminotransferase (IU/L) | 55 ± 2 | 49 ± 1 | 57 ± 4 | 51 ± 2
Alkaline phosphatase (IU/L) | 284 ± 12 | 316 ± 19 | 315 ± 19 | 318 ± 16
Creatine kinase (IU/L) | 277 ± 83 | 467 ± 161 | 284 ± 68 | 664 ± 266
Sorbitol dehydrogenase (IU/L) | 33 ± 1 | 33 ± 1 | 34 ± 1 | 33 ± 1
Bile salt/acids (µmol/L) | 27.3 ± 3.8 | 20.5 ± 3.1 | 33.0 ± 4.8 | 29.6 ± 4.8
Female
Hematology
Hematocrit (%) | 48.1 ± 0.5 | 49.1 ± 0.5 | 48.6 ± 0.4 | 48.7 ± 0.6
Manual hematocrit (%) | 47 ± 0 | 49 ± 0* | 49 ± 0** | 49 ± 0*
Hemoglobin (g/dL) | 15.6 ± 0.2 | 15.9 ± 0.1 | 15.8 ± 0.1 | 15.8 ± 0.1
Erythrocytes (106/μL) | 8.15 ± 0.07 | 8.33 ± 0.12 | 8.29 ± 0.06 | 8.18 ± 0.11
Reticulocytes (106/μL) | 245.7 ± 14.9 | 232.8 ± 6.3 | 241.9 ± 13.8 | 273.1 ± 17.6
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 58.9 ± 0.3 | 59.0 ± 0.6 | 58.7 ± 0.6 | 59.5 ± 0.5
Mean cell hemoglobin (pg) | 19.1 ± 0.1 | 19.2 ± 0.2 | 19.0 ± 0.2 | 19.3 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.4 ± 0.1 | 32.5 ± 0.2 | 32.5 ± 0.2 | 32.3 ± 0.2
Platelets (103/μL) | 963 ± 40 | 933 ± 33 | 1,022 ± 38 | 954 ± 55
Leukocytes (103/μL) | 8.80 ± 0.50 | 7.90 ± 0.67 | 6.86 ± 0.51* | 7.34 ± 0.41
Segmented neutrophils (103/μL) | 1.15 ± 0.12 | 0.88 ± 0.09 | 0.93 ± 0.13 | 1.02 ± 0.10
Lymphocytes (103/μL) | 7.22 ± 0.40 | 6.66 ± 0.61 | 5.60 ± 0.40** | 6.00 ± 0.37
Monocytes (103/μL) | 0.19 ± 0.02 | 0.15 ± 0.01 | 0.16 ± 0.02 | 0.14 ± 0.01
Basophils (103/μL) | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.00* | 0.03 ± 0.00*
Eosinophils (103/μL) | 0.11 ± 0.02 | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01
Large unstained cells (103/μL) | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01** | 0.06 ± 0.01**
Clinical Chemistry
Urea nitrogen (mg/dL) | 17.5 ± 0.9 | 18.1 ± 0.8 | 16.9 ± 0.5 | 15.9 ± 0.9
Creatinine (mg/dL) | 0.57 ± 0.03 | 0.56 ± 0.03 | 0.56 ± 0.02 | 0.63 ± 0.02
Glucose (mg/dL) | 151 ± 9 | 146 ± 9 | 141 ± 5 | 146 ± 6
Total protein (g/dL) | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1
Albumin (g/dL) | 3.8 ± 0.0 | 3.8 ± 0.0 | 3.9 ± 0.0 | 3.9 ± 0.1
Cholesterol (mg/dL) | 78 ± 4 | 72 ± 3 | 69 ± 3 | 64 ± 3**
Triglycerides (mg/dL) | 70 ± 9 | 51 ± 4 | 61 ± 8 | 44 ± 5*
Alanine aminotransferase (IU/L) | 48 ± 2 | 41 ± 2 | 43 ± 2 | 41 ± 2
Alkaline phosphatase (IU/L) | 277 ± 24 | 273 ± 16 | 265 ± 13 | 226 ± 12
Creatine kinase (IU/L) | 209 ± 35 | 295 ± 54 | 218 ± 27 | 275 ± 68
Sorbitol dehydrogenase (IU/L) | 31 ± 4 | 28 ± 5 | 28 ± 4 | 32 ± 4
Bile salt/acids (µmol/L) | 33.7 ± 6.1 | 22.8 ± 3.7 | 28.0 ± 4.5 | 31.5 ± 6.3

* Significantly different (P ≤ 0.05) from the sham control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical analysis performed by Jonckheere (trend) and Shirley’s or Dunn’s tests.

Table F‑2 Clinical Pathology Data for Rats at the 14-week Interim Evaluation in the Two-year CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
n | 10 | 10 | 10 | 10
Male
Hematology
Hematocrit (%) | 52.0 ± 0.3 | 51.9 ± 0.4 | 51.4 ± 0.5 | 51.9 ± 0.8
Manual hematocrit (%) | 50 ± 0 | 50 ± 1 | 50 ± 1 | 50 ± 1^b^
Hemoglobin (g/dL) | 16.5 ± 0.1 | 16.6 ± 0.1 | 16.6 ± 0.1 | 16.7 ± 0.3
Erythrocytes (106/μL) | 8.88 ± 0.07 | 8.92 ± 0.07 | 8.91 ± 0.10 | 8.82 ± 0.13
Reticulocytes (106/μL) | 270.4 ± 3.9 | 266.8 ± 5.7 | 257.4 ± 5.6 | 274.8 ± 15.1
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 58.5 ± 0.4 | 58.2 ± 0.4 | 57.7 ± 0.5 | 58.9 ± 0.5
Mean cell hemoglobin (pg) | 18.6 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1 | 18.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.7 ± 0.1 | 32.0 ± 0.2 | 32.3 ± 0.2 | 32.1 ± 0.2
Platelets (103/μL) | 894 ± 41 | 839 ± 26 | 911 ± 22 | 926 ± 35
Leukocytes (103/μL) | 9.34 ± 0.50 | 10.46 ± 0.64 | 10.08 ± 0.55 | 9.52 ± 0.88
Segmented neutrophils (103/μL) | 1.19 ± 0.09 | 1.06 ± 0.14 | 1.11 ± 0.06 | 1.03 ± 0.10
Lymphocytes (103/μL) | 7.66 ± 0.48 | 8.94 ± 0.64 | 8.49 ± 0.52 | 8.09 ± 0.82
Monocytes (103/μL) | 0.26 ± 0.03 | 0.22 ± 0.03 | 0.21 ± 0.03 | 0.20 ± 0.03
Basophils (103/μL) | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.00 | 0.05 ± 0.01
Eosinophils (103/μL) | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.13 ± 0.04 | 0.07 ± 0.01
Large unstained cells (103/μL) | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.07 ± 0.01
Clinical Chemistry
Urea nitrogen (mg/dL) | 18.1 ± 0.6 | 17.2 ± 0.4 | 17.5 ± 0.4 | 18.5 ± 0.6
Creatinine (mg/dL) | 0.50 ± 0.01 | 0.50 ± 0.01 | 0.54 ± 0.02 | 0.59 ± 0.02**
Glucose (mg/dL) | 135 ± 6 | 133 ± 5 | 149 ± 8 | 154 ± 11
Total protein (g/dL) | 6.1 ± 0.1 | 6.1 ± 0.0 | 6.3 ± 0.1 | 6.2 ± 0.1
Albumin (g/dL) | 3.6 ± 0.0 | 3.6 ± 0.0 | 3.6 ± 0.0 | 3.7 ± 0.0
Cholesterol (mg/dL) | 92 ± 2 | 89 ± 2 | 92 ± 3 | 88 ± 3
Triglycerides (mg/dL) | 88 ± 6 | 84 ± 7 | 87 ± 5 | 72 ± 5
Alanine aminotransferase (IU/L) | 55 ± 2 | 48 ± 2 | 52 ± 3 | 50 ± 2
Alkaline phosphatase (IU/L) | 284 ± 12 | 287 ± 16 | 300 ± 15 | 309 ± 26
Creatine kinase (IU/L) | 277 ± 83 | 265 ± 31 | 387 ± 109 | 309 ± 64
Sorbitol dehydrogenase (IU/L) | 33 ± 1 | 31 ± 1 | 33 ± 2 | 35 ± 1
Bile salt/acids (µmol/L) | 27.3 ± 3.8 | 36.3 ± 4.5 | 33.7 ± 5.0 | 30.1 ± 5.4
Female
Hematology
Hematocrit (%) | 48.1 ± 0.5 | 48.9 ± 0.3 | 48.7 ± 0.4 | 48.4 ± 0.4
Manual hematocrit (%) | 47 ± 0 | 48 ± 0 | 48 ± 0* | 48 ± 0
Hemoglobin (g/dL) | 15.6 ± 0.2 | 15.8 ± 0.1 | 15.8 ± 0.1 | 15.7 ± 0.1
Erythrocytes (106/μL) | 8.15 ± 0.07 | 8.13 ± 0.08 | 8.23 ± 0.03 | 8.17 ± 0.08
Reticulocytes (106/μL) | 245.7 ± 14.9 | 282.5 ± 10.3 | 268.0 ± 19.8 | 267.9 ± 14.4
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 58.9 ± 0.3 | 60.2 ± 0.4 | 59.2 ± 0.5 | 59.3 ± 0.7
Mean cell hemoglobin (pg) | 19.1 ± 0.1 | 19.5 ± 0.2 | 19.2 ± 0.1 | 19.3 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.4 ± 0.1 | 32.4 ± 0.1 | 32.4 ± 0.2 | 32.6 ± 0.2
Platelets (103/μL) | 963 ± 40 | 978 ± 36 | 989 ± 38 | 983 ± 33
Leukocytes (103/μL) | 8.80 ± 0.50 | 8.12 ± 0.83 | 7.82 ± 0.56 | 8.83 ± 0.97
Segmented neutrophils (103/μL) | 1.15 ± 0.12 | 0.96 ± 0.15 | 0.98 ± 0.11 | 1.28 ± 0.28
Lymphocytes (103/μL) | 7.22 ± 0.40 | 6.75 ± 0.67 | 6.47 ± 0.48 | 7.12 ± 0.68
Monocytes (103/μL) | 0.19 ± 0.02 | 0.20 ± 0.03 | 0.18 ± 0.03 | 0.19 ± 0.03
Basophils (103/μL) | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.04 ± 0.01
Eosinophils (103/μL) | 0.11 ± 0.02 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.12 ± 0.03
Large unstained cells (103/μL) | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01* | 0.08 ± 0.01
Clinical Chemistry
Urea nitrogen (mg/dL) | 17.5 ± 0.9 | 17.9 ± 0.5 | 17.0 ± 0.6 | 16.7 ± 0.5
Creatinine (mg/dL) | 0.57 ± 0.03 | 0.58 ± 0.03 | 0.56 ± 0.01 | 0.59 ± 0.02
Glucose (mg/dL) | 151 ± 9 | 145 ± 9 | 140 ± 5 | 141 ± 7
Total protein (g/dL) | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.2 ± 0.1
Albumin (g/dL) | 3.8 ± 0.0 | 3.8 ± 0.0 | 3.9 ± 0.0 | 3.8 ± 0.0
Cholesterol (mg/dL) | 78 ± 4 | 71 ± 2 | 73 ± 3 | 71 ± 2
Triglycerides (mg/dL) | 70 ± 9 | 61 ± 5 | 54 ± 3 | 70 ± 8
Alanine aminotransferase (IU/L) | 48 ± 2 | 43 ± 2 | 44 ± 2 | 45 ± 1
Alkaline phosphatase (IU/L) | 277 ± 24 | 248 ± 16 | 257 ± 18 | 252 ± 17
Creatine kinase (IU/L) | 209 ± 35 | 212 ± 36 | 217 ± 41 | 418 ± 97
Sorbitol dehydrogenase (IU/L) | 31 ± 4 | 31 ± 4 | 28 ± 4 | 34 ± 5
Bile salt/acids (µmol/L) | 33.7 ± 6.1 | 36.8 ± 5.1 | 32.7 ± 5.8 | 29.9 ± 5.6

* Significantly different (P ≤ 0.05) from the sham control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical analysis performed by Jonckheere (trend) and Shirley’s or Dunn’s tests.

^b^ n = 9..