# Appendix E Genetic Toxicology

## E.1 Collection of Tissue Samples for Genotoxicity Testing

Exposures ceased at 7 a.m. on the day of necropsy at 14 weeks after weaning. Thirty-five male rats (five sham controls, 15 that were exposed to CDMA, and 15 that were exposed to GSM) were necropsied approximately 2 to 4 hours after cessation of exposure and 35 female rats (five sham controls, 15 that were exposed to CDMA, and 15 that were exposed to GSM) were necropsied approximately 5 to 7 hours after cessation of exposure. Animals were necropsied in the following order: one animal from each exposure group starting with the sham control group, moving through each of the exposed groups for each of the radiofrequency modulations in turn, then rotating back to the sham control group; animals were necropsied in numerical order within each exposure group. Five different tissues (cerebrum, frontal cortex, hippocampus, liver, and blood leukocytes) were collected from each animal for the comet assay. Because blood was examined in both the micronucleus and the comet assays, a single tube of blood was collected per animal by retroorbital bleeding, and the sample was divided into two aliquots, one that was processed for the comet assay and the other for the micronucleus assay.

## E.2 Comet Assay

For preparation of samples for the comet assay, a 50 µL sample of blood was transferred to a tube containing 1 mL of freshly prepared cold mincing buffer [Mg+2, Ca+2, and phenol free Hank’s Balanced Salt Solution (Life Technologies, Carlsbad, CA) with 20 mM ethylenediaminetetraacetic acid (EDTA) pH 7.3 to 7.5 and 10% v/v fresh dimethyl sulfoxide (DMSO)]. The liver and the hippocampus, cerebellum, and frontal cortex sections of the brain were rinsed with cold mincing buffer to remove residual blood and held on ice briefly (≤5 minutes) until processed. Small portions (3 to 4 mm) of the left lobe of the liver and each brain section were placed in tubes containing cold mincing solution and rapidly minced until finely dispersed. All samples prepared for the comet assay were immediately flash frozen in liquid nitrogen^211^ and subsequently transferred to a –80°C freezer for storage until shipment by overnight courier on dry ice to the analytical laboratory. Upon receipt, all samples were immediately placed in a –80°C freezer for storage until further processing.

Blood and tissue samples were thawed on ice and maintained on ice during slide preparation. Just prior to use, each cell suspension was shaken gently to mix the cells and placed back on ice for 15 to 30 seconds to allow clumps to settle. A portion of the supernatant was empirically diluted with 0.5% low melting point agarose (Lonza, Walkersville, MD) dissolved in Dulbecco’s phosphate buffer (Ca+2, Mg+2, and phenol free) at 37°C and layered onto each well of a 2‑well CometSlide™ (Trevigen, Gaithersburg, MD). Slides were immersed in cold lysing solution [2.5 M NaCl, 100 mM Na2EDTA, 10 mM tris(hydroxymethyl)aminomethane (Tris), pH 10, containing freshly added 10% DMSO (Fisher Scientific, Pittsburgh, PA) and 1% Triton X‑100] overnight in a refrigerator, protected from light. The following day, the slides were rinsed in 0.4 M Trizma base (pH 7.5), randomly placed onto the platform of a horizontal electrophoresis unit and treated with cold alkali solution (300 mM NaOH, 1 mM Na2EDTA, pH > 13) for 20 minutes to allow DNA unwinding, then electrophoresed at 4º to 9ºC for 20 minutes at 25 V (0.7 V/cm), with a current of approximately 300 mA. Following electrophoresis, slides were neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes and then dehydrated by immersion in absolute ethanol (Pharmco‑AAPER, Shelbyville, KY) for at least 5 minutes and allowed to air dry. Slides were prepared in a laboratory with a relative humidity of no more than 60% and stored at room temperature in a desiccator with a relative humidity of no more than 60% until stained and scored; stained slides were stored in a desiccator. NaCl, Na2EDTA, Triton X‑100, and Trizma base were purchased from Sigma-Aldrich (St. Louis, MO); NaOH was purchased from Fisher Scientific (Pittsburgh, PA).

After staining with SYBR^®^ Gold (Molecular Probes, Life Technologies, Grand Island, NY), slides, independently coded to mask treatment, were scored using Comet Assay IV Imaging Software, Version 4.3.1 (Perceptive Instruments, Ltd., Suffolk, UK) validated for GLP Part 11 compliance. In the alkaline (pH > 13) comet assay, when damaged nuclear DNA fragments, it undergoes unidirectional migration through the agarose gel within an electrical field, forming an image that resembles a comet, and the greater the amount of fragmentation, the greater the amount of DNA migration that will occur. The image analysis software partitions the intensity of the fluorescent signal of the DNA in the entire comet image into the percent that is attributable to the comet head and the percent attributable to the tail. Manual adjustment of the automated detection of head and tail features is sometimes required. To evaluate DNA damage levels, the extent of DNA migration was characterized for 100 scorable comet figures per animal/tissue as percent tail DNA (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

Comet figures are classified during the scoring process as scorable (evaluated for percent tail DNA), non‑scorable (due to inability to evaluate percent tail DNA, e.g., if comets overlapped), and “hedgehog.” Hedgehogs either have no defined head, i.e., all DNA appears to be in the tail, or the head and tail appear to be separated. Hedgehogs may represent cells that have sustained high levels of DNA damage and are apoptotic, although certain data suggest they may represent cells with high levels of repairable DNA damage.^212,213^ The frequency of hedgehogs (%HH) was determined by tabulating the number observed in a separate group of 100 cells per animal/tissue.

When rat samples were scored, a marked interanimal variation in percent tail DNA and high %HH values were observed in some tissues, yet the range of percent tail DNA values appeared to be truncated at approximately 65%. To better understand these observations, rat slides were reanalyzed by scoring 150 cells/tissue per animal, as recommended by the OECD guideline.^184^ In this rescoring of the rat samples, all scorable cells were included in the sample of 150 analyzed cells, regardless of the apparent level of DNA damage estimated by the scorer prior to software analysis of the images; highly damaged cells that were unscorable using the software (true HH) were not included. For the 150‑cell scoring method, the %HH was not independently determined due to limitations at the time in the comet assay software arising from the added number of cells scored. Therefore, %HH was estimated by dividing the number of comets having greater than or equal to 90% tail DNA by 150.

Although there was no concurrent positive control group in these cell phone RFR studies, slides were made with human TK6 cells treated with ethyl methanesulfonate (standard positive control compound for the comet assay) and were included in each electrophoresis run with each slide set as an internal technical positive control.

## E.3 Micronucleus Assay

For the micronucleus assay, sampling schedules were as described for the comet assay. At 14 weeks after weaning, blood samples (approximately 200 μL) obtained by retroorbital bleeding (one sample per rat) were placed into EDTA tubes and immediately refrigerated. The samples were sent on the day of collection to the analytical laboratory well insulated on cold packs via overnight delivery. Upon arrival, blood samples were diluted in anticoagulant (heparin) and fixed in ice cold methanol (Sigma-Aldrich, St. Louis, MO) according to instructions provided with the MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY). Fixed blood samples were stored in a –80°C freezer for at least 3 days prior to analysis by flow cytometry.

Flow cytometric analysis of red blood cell samples was performed using MicroFlowPLUS Kit reagents and a FACSCalibur™ dual-laser bench top system (Becton Dickinson Biosciences, San Jose, CA) as described by MacGregor et al.^214^ and Witt et al.^215^ Both mature [normochromatic erythrocytes (NCEs)] and immature [reticulocytes; polychromatic erythrocytes (PCEs)] erythrocytes were analyzed for the presence of micronuclei. Immature erythrocytes are distinguished by the presence of an active transferrin receptor (CD‑71) on the cell surface. For each sample, 20,000 ( ± 2,000) immature CD71‑positive erythrocytes were analyzed by flow cytometry to determine the frequency of micronucleated PCEs. Aggregates were excluded on the basis of forward and side scatter, platelets were excluded based on staining with an anti‑CD61 antibody, and nucleated leukocytes were excluded on the basis of intense propidium iodide staining. Typically, more than one million NCEs (CD‑71 negative) were enumerated concurrently during PCE analysis, allowing for calculation of the percentage of PCEs (% PCEs) among total erythrocytes as a measure of bone marrow toxicity.

## E.4 Data Analysis for the Comet and Micronucleus Assays

Data from both the comet and the micronucleus assays were analyzed using the same statistical methods.^216^ Mean percent tail DNA was calculated for each cell type for each animal; likewise, mean micronucleated PCEs/1,000 PCEs and micronucleated NCEs/1,000 NCEs, as well as % PCEs, were calculated for each animal. These data are summarized in the tables as mean ± standard error of the mean. Levene’s test was used to determine if variances among exposed groups were equal at P = 0.05. When variances were equal, linear regression analysis was used to test for linear trend and Williams’ test was used to evaluate pairwise differences of each exposed group with the sham control group. When variances were unequal, nonparametric methods were used to analyze the data; Jonckheere’s test was used to evaluate linear trend and Dunn’s test was used to assess the significance of pairwise differences of each exposed group with the sham control group. To maintain the overall significance level at 0.05, the trend as well as the pairwise differences from the sham control group were declared statistically significant if P < 0.025. A result was considered positive if the trend test was significant and if at least one exposed group was significantly elevated over the sham control group, or if two or more exposed groups were significantly increased over the corresponding sham control group. A response was considered equivocal if only the trend test was significant or if only a single exposed group was significantly increased over the sham control.

## E.5 Results

Twenty tissue samples obtained from animals in the 14-week interim evaluation study were evaluated for DNA damage using the comet assay (two sexes, two cell phone RFR modulations, five tissues). Results are reported based on the standard 100-cell scoring approach in use at the time these data were collected; data obtained using a 150-cell scoring approach, recommended in a recently adopted international guideline for the in vivo comet assay, are noted for comparison. The only clear positive result was observed in hippocampus cells of male rats exposed to the CDMA modulation (Table E‑1). Data obtained using the 150-cell scoring approach did not meet the statistical criteria for a positive result, although the mean % tail DNA values were elevated over the sham controls in all exposure groups, and the values increased with increasing dose level (Table E‑3). An exposure‑related increase in DNA damage was seen in the cells of the frontal cortex of male rats exposed to the CDMA modulation (Table E‑1). However, although the trend test was significant (P = 0.004), no individual exposure groups were significantly elevated over the sham control group and the result was therefore judged to be equivocal. Data obtained using the 150-cell scoring approach showed a similar pattern of response in the male frontal cortex (CDMA) and were also considered to be equivocal based on a significant trend test (P = 0.005) (Table E‑3). For male rat blood leukocytes exposed to either the CDMA or GSM modulation (Table E‑1 and Table E‑2), results from scoring 100 cells were negative; however, these leukocyte samples showed equivocal responses with the 150-cell method due to a significant trend test (P = 0.012) or pairwise test (P = 0.021) for CDMA- and GSM-exposed rats, respectively (Table E‑3 and Table E‑4). No statistically significant increases in the percent tail DNA were observed in any of the female rat samples scored with the 100-cell approach (Table E‑5 and Table E‑6). The 150-cell scoring approach yielded a significant trend test (P = 0.013) in peripheral blood leukocytes of female rats exposed to the CDMA modulation, but these results were driven by data from a single animal (Table E‑7).

In contrast to what was seen in the mice, a high degree of interanimal variability was observed in the % tail DNA values in rats within a treatment group, and this level of variability reduced the statistical power to detect increases in DNA migration, although the magnitudes of the increases observed in some rats suggested these were treatment-related effects. To rule out any influence from technical artifacts or protocol features, % tail DNA values and %HH were correlated to the position of slides in the electrophoresis chambers, the interval from exposure cessation to tissue collection, and the date of slide preparation; no patterns emerged for any of these variables and the level of DNA damage observed.

The possibility that the longer interval from exposure cessation to tissue collection for the female rats may have been a factor in the absence of any detectable exposure-related increases in DNA damage cannot be ruled out due to the increased opportunity for DNA repair during this interval.

Similar to what was seen in the mice, no significant increases in micronucleated red blood cells or in the % PCEs were observed in rats of either sex exposed to either modulation of cell phone RFR (Table E‑9).

Table E‑1 DNA Damage in Male Rats Exposed to CDMA-modulated Cell Phone RFR for 19 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 6.18 ± 0.72 | | 2.00 ± 0.71
CDMA | 1.5 | 6.00 ± 0.48 | 1.000 | 1.00 ± 0.77
| 3 | 9.51 ± 1.17 | 0.081 | 10.60 ± 3.89
| 6 | 12.78 ± 3.96 | 0.049 | 12.20 ± 6.84
| | P = 0.004^e^
Hippocampus
Sham Control | 0 | 5.88 ± 0.39 | | 3.40 ± 1.21
CDMA | 1.5 | 8.06 ± 1.20 | 0.135 | 3.80 ± 2.33
| 3 | 8.16 ± 0.98 | 0.151 | 6.20 ± 2.56
| 6 | 10.42 ± 2.18 | 0.019 | 4.40 ± 2.98
| | P = 0.014
Cerebellum
Sham Control | 0 | 5.57 ± 0.92 | | 0.40 ± 0.24
CDMA | 1.5 | 5.60 ± 0.71 | 1.000 | 1.80 ± 0.80
| 3 | 10.70 ± 3.66 | 0.504 | 9.40 ± 6.81
| 6 | 10.58 ± 3.52 | 0.731 | 8.00 ± 3.91
| | P = 0.156
Liver
Sham Control | 0 | 13.81 ± 2.88 | | 33.60 ± 17.89
CDMA | 1.5 | 22.99 ± 2.77 | 0.081 | 68.60 ± 15.70
| 3 | 16.04 ± 2.14 | 0.098 | 7.80 ± 0.86
| 6 | 20.79 ± 3.10 | 0.057 | 41.10 ± 14.80
| | P = 0.154
Peripheral Blood
Sham Control | 0 | 1.48 ± 0.29 | | 0.20 ± 0.20
CDMA | 1.5 | 1.22 ± 0.45 | 0.596 | 0.80 ± 0.80
| 3 | 2.13 ± 0.34 | 0.156 | 0.40 ± 0.40
| 6 | 2.08 ± 0.43 | 0.166 | 1.40 ± 1.17
| | P = 0.071

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ No exposure to CDMA-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E‑2 DNA Damage in Male Rats Exposed to GSM-modulated Cell Phone RFR for 19 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 6.18 ± 0.72 | | 2.00 ± 0.71
GSM | 1.5 | 6.98 ± 0.42 | 0.465 | 1.40 ± 0.51
| 3 | 8.66 ± 1.96 | 0.247 | 8.20 ± 2.69
| 6 | 6.30 ± 0.32 | 1.000 | 3.00 ± 1.55
| | P = 0.343^e^
Hippocampus
Sham Control | 0 | 5.88 ± 0.39 | | 3.40 ± 1.21
GSM | 1.5 | 11.82 ± 2.68 | 0.092 | 4.80 ± 2.84
| 3 | 9.64 ± 1.27 | 0.111 | 4.80 ± 1.53
| 6 | 11.69 ± 3.92 | 0.072 | 10.20 ± 7.98
| | P = 0.103
Cerebellum
Sham Control | 0 | 5.57 ± 0.92 | | 0.40 ± 0.24
GSM | 1.5 | 7.36 ± 2.48 | 0.295 | 2.40 ± 1.91
| 3 | 6.37 ± 0.77 | 0.354 | 3.40 ± 1.17
| 6 | 8.48 ± 1.85 | 0.149 | 5.00 ± 2.86
| | P = 0.132
Liver
Sham Control | 0 | 13.81 ± 2.88 | | 33.60 ± 17.89
GSM | 1.5 | 13.26 ± 2.38 | 0.547 | 21.00 ± 12.30
| 3 | 13.09 ± 2.32 | 0.634 | 28.40 ± 15.07
| 6 | 14.49 ± 2.71 | 0.536 | 24.80 ± 16.13
| | P = 0.404
Peripheral Blood
Sham Control | 0 | 1.48 ± 0.29 | | 0.20 ± 0.20
GSM | 1.5 | 1.83 ± 0.63 | 0.352 | 3.20 ± 2.71
| 3 | 1.78 ± 0.33 | 0.419 | 1.20 ± 0.49
| 6 | 1.50 ± 0.27 | 0.446 | 0.40 ± 0.24
| | P = 0.550

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ No exposure to GSM-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E‑3 DNA Damage in Male Rats Exposed to CDMA-modulated Cell Phone RFR for 19 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Frontal Cortex
Sham Control^e^ | 0 | 9.73 ± 0.81 | | 0.27 ± 0.27
CDMA | 1.5 | 8.24 ± 0.39 | 1.000 | 0.13 ± 0.13
| 3 | 18.77 ± 3.27 | 0.043 | 2.53 ± 1.29
| 6 | 23.62 ± 8.66 | 0.092 | 3.20 ± 1.72
| | P = 0.005^f^
Hippocampus
Sham Control | 0 | 8.99 ± 1.55 | | 1.07 ± 0.45
CDMA | 1.5 | 12.27 ± 2.21 | 0.244 | 0.40 ± 0.27
| 3 | 15.46 ± 2.25 | 0.107 | 2.53 ± 0.90
| 6 | 16.77 ± 5.44 | 0.069 | 2.40 ± 1.44
| | P = 0.043
Cerebellum
Sham Control | 0 | 4.90 ± 0.82 | | 0.00 ± 0.00
CDMA | 1.5 | 6.33 ± 1.00 | 0.681 | 0.27 ± 0.16
| 3 | 13.75 ± 6.01 | 0.504 | 2.93 ± 2.20
| 6 | 15.86 ± 5.91 | 0.163 | 2.40 ± 1.07
| | P = 0.061
Liver
Sham Control | 0 | 25.71 ± 8.71 | | 1.73 ± 1.73
CDMA | 1.5 | 55.41 ± 7.91 | 0.136 | 14.67 ± 5.57
| 3 | 19.11 ± 2.28 | 0.164 | 0.80 ± 0.49
| 6 | 40.01 ± 7.90 | 0.114 | 9.07 ± 7.10
| | P = 0.385
Peripheral Blood
Sham Control | 0 | 0.69 ± 0.20 | | 0.00 ± 0.00
CDMA | 1.5 | 1.16 ± 0.47 | 0.295 | 0.00 ± 0.00
| 3 | 1.83 ± 0.74 | 0.121 | 0.13 ± 0.13
| 6 | 2.57 ± 0.80 | 0.026 | 0.00 ± 0.00
| | P = 0.012

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ and OECD.^184^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

cPairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ Percent hedgehogs = estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to CDMA-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E‑4 DNA Damage in Male Rats Exposed to GSM-modulated Cell Phone RFR for 19 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Frontal Cortex
Sham Control^e^ | 0 | 9.73 ± 0.81 | | 0.27 ± 0.27
GSM | 1.5 | 11.96 ± 1.65 | 0.634 | 0.40 ± 0.27
| 3 | 17.98 ± 5.12 | 0.545 | 1.20 ± 0.57
| 6 | 9.57 ± 1.57 | 1.000 | 0.13 ± 0.13
| | P = 0.500^f^
Hippocampus
Sham Control | 0 | 8.99 ± 1.55 | | 1.07 ± 0.45
GSM | 1.5 | 17.24 ± 4.09 | 0.186 | 0.27 ± 0.16
| 3 | 14.77 ± 2.54 | 0.227 | 1.47 ± 0.57
| 6 | 21.32 ± 9.55 | 0.080 | 3.60 ± 2.03
| | P = 0.076
Cerebellum
Sham Control | 0 | 4.90 ± 0.82 | | 0.00 ± 0.00
GSM | 1.5 | 9.43 ± 4.69 | 0.190 | 1.33 ± 1.17
| 3 | 8.66 ± 2.17 | 0.232 | 1.47 ± 0.68
| 6 | 12.11 ± 3.89 | 0.088 | 1.07 ± 1.07
| | P = 0.076
Liver
Sham Control | 0 | 25.71 ± 8.71 | | 1.73 ± 1.73
GSM | 1.5 | 23.27 ± 9.43 | 0.539 | 4.13 ± 3.64
| 3 | 25.15 ± 8.43 | 0.604 | 0.40 ± 0.40
| 6 | 28.25 ± 10.55 | 0.534 | 4.93 ± 3.94
| | P = 0.390
Peripheral Blood
Sham Control | 0 | 0.69 ± 0.20 | | 0.00 ± 0.00
GSM | 1.5 | 3.97 ± 2.75 | 0.146 | 0.27 ± 0.27
| 3 | 1.97 ± 0.35 | 0.021 | 0.00 ± 0.00
| 6 | 1.28 ± 0.23 | 0.272 | 0.00 ± 0.00
| | P = 0.089

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ and OECD.^184^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ Percent hedgehogs = estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to GSM-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E‑5 DNA Damage in Female Rats Exposed to CDMA-modulated Cell Phone RFR for 19 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 7.03 ± 1.21 | | 3.80 ± 1.46
CDMA | 1.5 | 12.70 ± 5.15 | 0.205 | 19.00 ± 15.04
| 3 | 9.50 ± 2.27 | 0.249 | 9.80 ± 5.12
| 6 | 13.00 ± 3.63 | 0.150 | 25.40 ± 11.44
| | P = 0.166^e^
Hippocampus
Sham Control | 0^f^ | 13.14 ± 1.20 | | 9.00 ± 2.58
CDMA | 1.5 | 14.94 ± 0.70 | 0.346 | 8.40 ± 1.96
| 3 | 15.24 ± 1.97 | 0.379 | 9.40 ± 2.89
| 6 | 19.11 ± 5.27 | 0.126 | 21.20 ± 11.12
| | P = 0.080
Cerebellum
Sham Control | 0 | 5.94 ± 0.98 | | 3.80 ± 1.07
CDMA | 1.5 | 4.91 ± 0.58 | 0.671 | 2.00 ± 1.05
| 3 | 5.46 ± 0.83 | 0.747 | 2.00 ± 0.63
| 6 | 5.86 ± 0.84 | 0.650 | 1.20 ± 0.37
| | P = 0.421
Liver
Sham Control | 0 | 10.09 ± 0.87 | | 7.00 ± 1.87
CDMA | 1.5 | 15.26 ± 3.35 | 0.634 | 33.40 ± 15.11
| 3 | 11.49 ± 2.05 | 1.000 | 12.40 ± 3.59
| 6 | 18.35 ± 3.44 | 0.163 | 31.40 ± 12.33
| | P = 0.113
Peripheral Blood
Sham Control | 0 | 3.15 ± 0.40 | | 0.20 ± 0.20
CDMA | 1.5 | 3.77 ± 1.19 | 0.371 | 1.20 ± 0.80
| 3 | 4.13 ± 0.54 | 0.361 | 0.40 ± 0.40
| 6 | 6.06 ± 2.18 | 0.082 | 9.80 ± 8.81
| | P = 0.048

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ No exposure to CDMA-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

^f^ n = 4.

Table E‑6 DNA Damage in Female Rats Exposed to GSM-modulated Cell Phone RFR for 19 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 7.03 ± 1.21 | | 3.80 ± 1.46
GSM | 1.5 | 4.87 ± 0.47 | 0.820 | 2.20 ± 0.73
| 3 | 6.18 ± 0.67 | 0.843 | 5.60 ± 2.36
| 6 | 6.74 ± 0.74 | 0.723 | 6.40 ± 2.73
| | P = 0.386^e^
Hippocampus
Sham Control | 0^f^ | 13.14 ± 1.20 | | 9.00 ± 2.58
GSM | 1.5^f^ | 13.22 ± 1.56 | 0.936 | 7.25 ± 3.20
| 3^f^ | 17.67 ± 3.64 | 0.351 | 19.50 ± 7.89
| 6 | 13.21 ± 1.03 | 1.000 | 10.00 ± 3.81
| | P = 0.334
Cerebellum
Sham Control | 0 | 5.94 ± 0.98 | | 3.80 ± 1.07
GSM | 1.5 | 5.69 ± 0.75 | 0.662 | 2.00 ± 0.71
| 3 | 4.62 ± 0.85 | 0.749 | 0.60 ± 0.24
| 6 | 6.62 ± 0.96 | 0.381 | 2.40 ± 1.03
| | P = 0.302
Liver
Sham Control | 0 | 10.09 ± 0.87 | | 7.00 ± 1.87
GSM | 1.5 | 9.91 ± 2.60 | 1.000 | 13.20 ± 11.23
| 3 | 9.46 ± 2.07 | 1.000 | 17.00 ± 14.76
| 6 | 18.99 ± 6.20 | 1.000 | 35.20 ± 19.42
| | P = 0.394
Peripheral Blood
Sham Control | 0 | 3.15 ± 0.40 | | 0.20 ± 0.20
GSM | 1.5 | 2.80 ± 0.33 | 0.593 | 0.80 ± 0.49
| 3 | 3.39 ± 0.68 | 0.447 | 0.60 ± 0.24
| 6 | 3.93 ± 0.63 | 0.203 | 1.00 ± 0.32
| | P = 0.093

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ No exposure to GSM-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

^f^ n = 4.

Table E‑7 DNA Damage in Female Rats Exposed to CDMA-modulated Cell Phone RFR for 19 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Frontal Cortex
Sham Control^e^ | 0 | 12.23 ± 2.18 | | 0.40 ± 0.16
CDMA | 1.5 | 25.37 ± 12.96 | 0.782 | 8.67 ± 7.67
| 3 | 18.70 ± 5.28 | 0.634 | 1.87 ± 0.88
| 6 | 33.49 ± 11.14 | 0.092 | 7.20 ± 5.62
| | P = 0.035^f^
Hippocampus
Sham Control | 0^g^ | 18.08 ± 1.30 | | 0.83 ± 0.32
CDMA | 1.5 | 20.58 ± 2.06 | 0.531 | 1.07 ± 0.34
| 3 | 20.63 ± 1.92 | 0.382 | 1.33 ± 0.21
| 6 | 29.55 ± 9.44 | 0.218 | 6.53 ± 5.23
| | P = 0.068
Cerebellum
Sham Control | 0 | 4.93 ± 1.09 | | 0.00 ± 0.00
CDMA | 1.5 | 4.61 ± 1.61 | 0.621 | 0.53 ± 0.53
| 3 | 3.89 ± 0.43 | 0.709 | 0.13 ± 0.13
| 6 | 5.88 ± 0.63 | 0.342 | 0.27 ± 0.16
| | P = 0.249
Liver
Sham Control | 0 | 12.41 ± 1.64 | | 0.13 ± 0.13
CDMA | 1.5 | 26.15 ± 8.57 | 0.145 | 4.00 ± 3.67
| 3 | 16.17 ± 2.17 | 0.176 | 0.67 ± 0.42
| 6 | 26.65 ± 6.91 | 0.059 | 2.00 ± 1.17
| | P = 0.102
Peripheral Blood
Sham Control | 0 | 3.32 ± 0.09 | | 0.13 ± 0.13
CDMA | 1.5 | 4.45 ± 1.53 | 1.000 | 0.40 ± 0.27
| 3 | 3.94 ± 0.40 | 0.465 | 0.13 ± 0.13
| 6 | 12.76 ± 7.59 | 0.028 | 2.93 ± 2.77
| | P = 0.013

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ and OECD.^184^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ Percent hedgehogs = estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to CDMA-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

^g^ n = 4.

Table E‑8 DNA Damage in Female Rats Exposed to GSM-modulated Cell Phone RFR for 19 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Frontal Cortex
Sham Controle | 0 | 12.23 ± 2.18 | | 0.40 ± 0.16
GSM | 1.5 | 6.28 ± 1.00 | 0.856 | 0.00 ± 0.00
| 3 | 9.83 ± 1.11 | 0.877 | 0.67 ± 0.21
| 6 | 13.74 ± 2.79 | 0.376 | 0.13 ± 0.13
| | P = 0.137^f^
Hippocampus
Sham Control | 0^g^ | 18.08 ± 1.30 | | 0.83 ± 0.32
GSM | 1.5^g^ | 17.54 ± 3.59 | 1.000 | 1.50 ± 1.29
| 3^g^ | 28.08 ± 7.0 | 0.662 | 3.66 ± 1.40
| 6 | 18.19 ± 3.35 | 1.000 | 2.93 ± 1.53
| | P = 0.534
Cerebellum
Sham Control | 0 | 4.93 ± 1.09 | | 0.00 ± 0.00
GSM | 1.5 | 5.11 ± 0.63 | 0.731 | 0.00 ± 0.00
| 3 | 3.51 ± 0.74 | 1.000 | 0.00 ± 0.00
| 6 | 6.54 ± 2.33 | 1.000 | 0.27 ± 0.16
| | P = 0.705
Liver
Sham Control | 0 | 12.41 ± 1.64 | | 0.13 ± 0.13
GSM | 1.5 | 17.05 ± 7.24 | 1.000 | 0.93 ± 0.62
| 3 | 14.06 ± 5.68 | 1.000 | 0.27 ± 0.16
| 6 | 26.03 ± 10.69 | 1.000 | 4.00 ± 3.23
| | P = 0.580
Peripheral Blood
Sham Control | 0 | 3.32 ± 0.09 | | 0.13 ± 0.13
GSM | 1.5 | 3.07 ± 0.43 | 1.000 | 0.27 ± 0.16
| 3 | 2.82 ± 0.52 | 1.000 | 0.13 ± 0.13
| 6 | 3.86 ± 0.76 | 1.000 | 0.40 ± 0.16
| | P = 0.580

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^211^ and OECD.^184^ Groups of five rats per exposure group; exposure began in utero on gestation day 6. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ Percent hedgehogs = estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to GSM-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

^g^ n = 4.

Table E‑9 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to CDMA- or GSM-modulated Cell Phone RFR for 19 Weeks^a^

| Dose (W/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Sham Control^d^ | 0 | 5 | 0.84 ± 0.10 | | 0.33 ± 0.11 | | 0.95 ± 0.05
CDMA | 1.5 | 5 | 0.56 ± 0.02 | 0.989 | 0.12 ± 0.02 | 1.000 | 0.83 ± 0.07 | 0.588
| 3 | 5 | 0.55 ± 0.06 | 0.997 | 0.13 ± 0.02 | 1.000 | 0.88 ± 0.05 | 0.700
| 6 | 5 | 0.43 ± 0.07 | 0.998 | 0.13 ± 0.05 | 1.000 | 0.99 ± 0.07 | 0.741
| | | P = 0.999^e^ | | P = 0.970 | | P = 0.389
GSM | 1.5 | 5 | 0.61 ± 0.11 | 0.920 | 0.14 ± 0.04 | 1.000 | 1.03 ± 0.03 | 0.352
| 3 | 5 | 0.60 ± 0.11 | 0.961 | 0.08 ± 0.02 | 1.000 | 1.00 ± 0.06 | 0.425
| 6 | 5 | 0.49 ± 0.08 | 0.972 | 0.13 ± 0.02 | 1.000 | 1.08 ± 0.06 | 0.114
| | | P = 0.985 | | P = 0.911 | | P = 0.123
Female
Sham Control | 0 | 5 | 0.62 ± 0.07 | | 0.13 ± 0.04 | | 0.66 ± 0.08
CDMA | 1.5 | 5 | 0.54 ± 0.08 | 1.000 | 0.18 ± 0.03 | 0.263 | 0.92 ± 0.17 | 0.337
| 3 | 5 | 0.72 ± 0.12 | 0.778 | 0.16 ± 0.02 | 0.316 | 0.73 ± 0.12 | 0.406
| 6 | 5 | 0.51 ± 0.04 | 1.000 | 0.19 ± 0.06 | 0.219 | 0.82 ± 0.05 | 0.297
| | | P = 0.541 | | P = 0.212 | | P = 0.430
GSM | 1.5 | 5 | 0.61 ± 0.10 | 0.519 | 0.20 ± 0.04 | 0.377 | 0.76 ± 0.07 | 0.376
| 3 | 5 | 0.70 ± 0.08 | 0.495 | 0.11 ± 0.02 | 0.447 | 0.74 ± 0.09 | 0.455
| 6 | 5 | 0.59 ± 0.07 | 0.525 | 0.13 ± 0.03 | 0.476 | 0.99 ± 0.03 | 0.010
| | | P = 0.566 | | P = 0.737 | | P = 0.008

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^215^ Exposure began in utero on gestation day 6; NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte. Statistical analysis runs Levene’s test to determine if variances of exposed groups are equal (P = 0.05). If variances are significantly different, Jonckheere’s test is used for trend with Dunn’s test for pairwise comparisons; otherwise, linear regression is used to test for trend and Williams’ test for pairwise comparisons.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ No exposure to CDMA- or GSM-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.