# Appendix D Summary of Lesions in Female Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

Table D‑1 Summary of the Incidence of Neoplasms in Female Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1 | – | – | –
Moribund | 30 | 29 | 28 | 16
Natural deaths | 11 | 15 | 12 | 13
Survivors
Died last week of study | 1 | 2 | – | –
Terminal euthanasia | 47 | 44 | 50 | 61
Animals examined microscopically | 100 | 100 | 100 | 100
Fourteen-week Interim Evaluation
Integumentary System
Mammary gland | (10) | (10) | (10) | (10)
Adenocarcinoma | – | – | – | 1 (10%)
Skin | (10) | (10) | (10) | (10)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Intestine large, cecum | (84) | (82) | (86) | (80)
Intestine large, colon | (89) | (89) | (88) | (88)
Intestine large, rectum | (90) | (88) | (87) | (88)
Granular cell tumor benign | 1 (1%) | – | – | –
Intestine small, duodenum | (88) | (86) | (87) | (85)
Intestine small, ileum | (86) | (83) | (84) | (83)
Intestine small, jejunum | (83) | (81) | (84) | (79)
Leiomyosarcoma | 1 (1%) | – | – | –
Liver | (90) | (90) | (90) | (90)
Carcinoma, metastatic, adrenal cortex | – | – | 1 (1%)
Hepatocellular adenoma | 7 (8%) | 2 (2%) | 2 (2%) | 1 (1%)
Hepatocellular carcinoma | – | – | – | 1 (1%)
Mesentery | (4) | (3) | (11) | (4)
Adenocarcinoma, metastatic, uterus | 1 (25%) | – | – | –
Oral mucosa | (1) | (1) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Pancreas | (90) | (90) | (90) | (89)
Salivary glands | (90) | (90) | (90) | (90)
Parotid gland, squamous cell carcinoma | – | – | – | 1 (1%)
Stomach, forestomach | (90) | (90) | (90) | (90)
vSarcoma | 1 (1%) | – | – | 1 (1%)
Squamous cell papilloma | – | – | – | 1 (1%)
Stomach, glandular | (90) | (90) | (89) | (88)
Sarcoma, metastatic, stomach, forestomach | 1 (1%) | – | – | –
Tongue | (1) | (0) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Blood vessel | (0) | (0) | (0) | (1)
Heart | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, mammary gland | – | – | 1 (1%) | –
Endocardium, schwannoma malignant | – | 1 (1%) | – | 2 (2%)
Myocardium, schwannoma malignant | – | 1 (1%) | – | –
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (90)
Adenoma | 1 (1%) | 2 (2%) | 2 (2%) | 1 (1%)
Carcinoma | 1 (1%) | – | 1 (1%) | –
Adrenal medulla | (86) | (89) | (87) | (88)
Pheochromocytoma benign | 1 (1%) | 7 (8%) | 3 (3%) | 4 (5%)
Pheochromocytoma complex | – | – | 1 (1%) | –
Pheochromocytoma malignant | – | 2 (2%) | 1 (1%) | –
Islets, pancreatic | (90) | (89) | (90) | (88)
Adenoma | 5 (6%) | 4 (4%) | 5 (6%) | 4 (5%)
Carcinoma | 2 (2%) | 2 (2%) | – | 2 (2%)
Parathyroid gland | (87) | (80) | (85) | (85)
Pituitary gland | (90) | (89) | (89) | (90)
Pars distalis, adenoma | 42 (47%) | 40 (45%) | 30 (34%) | 40 (44%)
Pars distalis, adenoma, multiple | 1 (1%) | 1 (1%) | – | –
Pars distalis, carcinoma | 1 (1%) | 1 (1%) | 1 (1%) | –
Thyroid gland | (90) | (90) | (90) | (89)
Bilateral, C-cell, adenoma | – | – | – | 1 (1%)
Bilateral, C-cell, carcinoma | – | – | 1 (1%) | –
C-cell, adenoma | 6 (7%) | 9 (10%) | 3 (3%) | 7 (8%)
C-cell, carcinoma | – | 3 (3%) | 2 (2%) | 2 (2%)
Follicular cell, adenoma | – | – | 1 (1%) | –
Follicular cell, carcinoma | 1 (1%) | 1 (1%) | – | –
General Body System
Tissue NOS | (8) | (11) | (8) | (6)
Abdominal, schwannoma malignant | 1 (13%) | – | – | –
Abdominal, fat, lipoma | – | – | 1 (13%) | –
Genital System
Clitoral gland | (87) | (88) | (89) | (86)
Carcinoma | – | – | 1 (1%) | –
Schwannoma malignant | – | – | – | 1 (1%)
Ovary | (90) | (90) | (89) | (90)
Cystadenocarcinoma | – | 1 (1%) | – | –
Cystadenoma | 1 (1%) | – | – | –
Granulosa cell tumor benign | 1 (1%) | – | – | –
Granulosa cell tumor malignant | 2 (2%) | – | – | –
Sertoli cell tumor benign | 1 (1%) | – | – | –
Periovarian tissue, schwannoma malignant | – | – | – | 1 (1%)
Rete ovarii, adenoma | – | – | 1 (1%) | 1 (1%)
Oviduct | (1) | (0) | (0) | (0)
Uterus | (90) | (90) | (90) | (90)
Adenocarcinoma | 3 (3%) | – | – | 3 (3%)
Adenoma | – | – | 1 (1%) | 1 (1%)
Carcinoma | – | 1 (1%) | – | –
Hemangiosarcoma | 2 (2%) | – | – | –
Leiomyosarcoma | – | – | 2 (2%) | –
Polyp, glandular | – | 2 (2%) | 2 (2%) | –
Polyp stromal | 15 (17%) | 11 (12%) | 9 (10%) | 12 (13%)
Polyp stromal, multiple | 1 (1%) | 4 (4%) | 4 (4%) | 5 (6%)
Schwannoma malignant | 1 (1%) | – | – | –
Squamous cell carcinoma | – | – | 1 (1%) | –
Cervix, leiomyosarcoma | 1 (1%) | – | – | –
Cervix, polyp stromal | – | – | 1 (1%) | –
Cervix, schwannoma malignant | 1 (1%) | – | 2 (2%) | –
Vagina | (2) | (1) | (0) | (1)
Polyp, stromal | – | 1 (100%) | – | –
Schwannoma malignant | 1 (50%) | – | – | –
Schwannoma malignant, metastatic, uterus | 1 (50%) | – | – | –
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Lymph node | (13) | (8) | (11) | (20)
Iliac, adenocarcinoma, metastatic, mammary gland | – | – | – | 1 (5%)
Lymph node, mandibular | (90) | (90) | (89) | (90)
Lymph node, mesenteric | (90) | (90) | (90) | (89)
Spleen | (90) | (90) | (90) | (90)
Hemangiosarcoma | 1 (1%) | – | – | –
Thymus | (87) | (83) | (87) | (87)
Thymoma benign | 1 (1%) | – | 1 (1%) | –
Thymoma malignant | 1 (1%) | – | – | –
Integumentary System
Mammary gland | (90) | (90) | (90) | (90)
Adenocarcinoma | 9 (10%) | 7 (8%) | 6 (7%) | 3 (3%)
Adenocarcinoma, multiple | 1 (1%) | 1 (1%) | – | 1 (1%)
Adenoma | 4 (4%) | 4 (4%) | 1 (1%) | 2 (2%)
Adenoma, multiple | 4 (4%) | – | – | –
Fibroadenoma | 34 (38%) | 40 (44%) | 34 (38%) | 32 (36%)
Fibroadenoma, multiple | 29 (32%) | 21 (23%) | 29 (32%) | 30 (33%)
Skin | (90) | (90) | (90) | (90)
Keratoacanthoma | – | 1 (1%) | 2 (2%) | 1 (1%)
Squamous cell carcinoma, metastatic, salivary glands | – | – | – | 1 (1%)
Subcutaneous tissue, fibroma | 2 (2%) | – | 1 (1%) | 3 (3%)
Subcutaneous tissue, lipoma | – | – | 1 (1%) | 2 (2%)
Subcutaneous tissue, malignant fibrous histiocytoma | 1 (1%) | – | – | –
Subcutaneous tissue, sarcoma | 2 (2%) | – | – | –
Subcutaneous tissue, squamous cell carcinoma | – | 2 (2%) | – | –
Vulva, squamous cell carcinoma | – | – | – | 1 (1%)
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Vertebra, chondroma | – | – | 1 (1%) | –
Skeletal muscle | (90) | (90) | (90) | (90)
Nervous System
Brain | (90) | (90) | (90) | (90)
Carcinoma, metastatic, pituitary gland | 1 (1%) | – | – | –
Glioma malignant | – | 3 (3%) | – | –
Meningioma malignant | – | – | – | 1 (1%)
Neuroblastoma | – | 1 (1%) | – | –
Sarcoma | – | 1 (1%) | – | –
Meninges, granular cell tumor benign | 1 (1%) | 1 (1%) | – | 2 (2%)
Pineal gland, pinealoma | – | 1 (1%) | – | –
Nerve trigeminal | (84) | (84) | (85) | (84)
Squamous cell carcinoma, metastatic, salivary glands | – | – | – | 1 (1%)
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Peripheral nerve, tibial | (90) | (90) | (89) | (89)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Spinal cord, lumbar | (90) | (90) | (89) | (90)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Trigeminal ganglion | (81) | (77) | (81) | (75)
Carcinoma, metastatic, pituitary gland | – | – | 1 (1%) | –
Squamous cell carcinoma, metastatic, salivary glands | – | – | – | 1 (1%)
Respiratory System
Lung | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, mammary gland | – | 2 (2%) | 1 (1%) | 1 (1%)
Carcinoma, metastatic, adrenal cortex | – | – | 1 (1%) | –
Carcinoma, metastatic, thyroid gland | – | 1 (1%) | 1 (1%) | –
Carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Nose | (90) | (89) | (90) | (89)
Trachea | (89) | (88) | (89) | (89)
Carcinoma, metastatic, thyroid gland | – | – | 1 (1%) | –
Special Senses System
Ear | (0) | (0) | (1) | (1)
Neural crest tumor | – | – | 1 (100%) | 1 (100%)
Eye | (88) | (86) | (88) | (86)
Sarcoma | – | 1 (1%) | – | –
Harderian gland | (90) | (90) | (90) | (90)
Urinary System
Kidney | (90) | (90) | (90) | (89)
Bilateral, renal tubule, carcinoma | 1 (1%) | – | 2 (2%) | –
Renal tubule, adenoma | 1 (1%) | – | 1 (1%) | –
Urinary bladder | (88) | (88) | (90) | (90)
Leiomyosarcoma | 1 (1%) | – | – | –
Schwannoma malignant, metastatic, tissue NOS | 1 (1%) | – | – | –
Systemic Lesions
Multiple organsb | (90) | (90) | (90) | (90)
Histiocytic sarcoma | – | – | 2 (2%) | –
Leukemia mononuclear | – | 3 (3%) | – | –
Lymphoma malignant | 5 (6%) | 2 (2%) | 4 (4%) | 3 (3%)
Neoplasm Summary
Total animals with primary neoplasmsc
Fourteen-week interim evaluation | – | – | – | 1
Two-year study | 89 | 88 | 82 | 85
Total primary neoplasms
Fourteen-week interim evaluation | – | – | – | 1
Two-year study | 202 | 185 | 164 | 174
Total animals with benign neoplasms
Two-year study | 82 | 84 | 78 | 79
Total benign neoplasms
Two-year study | 159 | 151 | 136 | 150
Total animals with malignant neoplasms
Fourteen-week interim evaluation | – | – | – | 1
Two-year study | 37 | 27 | 24 | 22
Total malignant neoplasms
Fourteen-week interim evaluation | – | – | – | 1
Two-year study | 43 | 34 | 27 | 23
Total animals with metastatic neoplasms
Two-year study | 5 | 4 | 6 | 2
Total metastatic neoplasms
Two-year study | 5 | 4 | 11 | 5
Total animals with malignant neoplasms- uncertain primary site
Two-year study | – | 1 | – | –
Total animals with uncertain neoplasms- benign or malignant
Two-year study | – | – | 1 | 1
Total uncertain neoplasms benign or malignant
Two-year study | – | – | 1 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D‑2 Statistical Analysis of Primary Neoplasms in Female Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 1/86 (1%) | 7/89 (8%) | 3/87 (3%) | 4/88 (5%)
Rate per litters^b^ | 1/35 (3%) | 7/34 (21%) | 3/35 (9%) | 4/35 (11%)
Adjusted rate^c^ | 1.5% | 9.6% | 4.4% | 5.2%
Terminal rate^d^ | 1/45 (2%) | 5/44 (11%) | 3/48 (6%) | 4/60 (7%)
First incidence (days) | 737 (T) | 464 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test^e^ | P = 0.466 | P = 0.059 | P = 0.322 | P = 0.248
Litter C-A/Fisher’s test^f^ | P = 0.379 | P = 0.025 | P = 0.307 | P = 0.178
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 1/86 (1%) | 9/89 (10%) | 5/87 (6%) | 4/88 (5%)
Rate per litters | 1/35 (3%) | 9/34 (26%) | 5/35 (14%) | 4/35 (11%)
Adjusted rate | 1.5% | 12.3% | 7.2% | 5.2%
Terminal rate | 1/45 (2%) | 7/44 (16%) | 4/48 (8%) | 4/60 (7%)
First incidence (days) | 737 (T) | 464 | 652 | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.546 | P = 0.022 | P = 0.126 | P = 0.242
Litter C-A/Fisher’s test | P = 0.457 | P = 0.006 | P = 0.099 | P = 0.178
Liver: Hepatocellular Adenoma
Overall rate | 7/90 (8%) | 2/90 (2%) | 2/90 (2%) | 1/90 (1%)
Rate per litters | 6/35 (17%) | 2/34 (6%) | 2/35 (6%) | 1/35 (3%)
Adjusted rate | 10.1% | 2.7% | 2.8% | 1.3%
Terminal rate | 6/48 (13%) | 1/45 (2%) | 2/50 (4%) | 1/61 (2%)
First incidence (days) | 707 | 493 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.042N | P = 0.118N | P = 0.125N | P = 0.052N
Litter C-A/Fisher’s test | P = 0.039N | P = 0.139N | P = 0.130N | P = 0.053N
Liver: Hepatocellular Adenoma or Hepatocellular Carcinoma
Overall rate | 7/90 (8%) | 2/90 (2%) | 2/90 (2%) | 2/90 (2%)
Rate per litters | 6/35 (17%) | 2/34 (6%) | 2/35 (6%) | 2/35 (6%)
Adjusted rate | 10.1% | 2.7% | 2.8% | 2.5%
Terminal rate | 6/48 (13%) | 1/45 (2%) | 2/50 (4%) | 2/61 (3%)
First incidence (days) | 707 | 493 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.089N | P = 0.112N | P = 0.118N | P = 0.096N
Litter C-A/Fisher’s test | P = 0.108N | P = 0.139N | P = 0.130N | P = 0.130N
Mammary Gland: Fibroadenoma
Overall rate | 63/90 (70%) | 61/90 (68%) | 63/90 (70%) | 62/90 (69%)
Rate per litters | 31/35 (89%) | 32/34 (94%) | 33/35 (94%) | 31/35 (89%)
Adjusted rate | 77.0% | 73.3% | 75.2% | 73.1%
Terminal rate | 36/48 (75%) | 33/45 (73%) | 36/50 (72%) | 45/61 (74%)
First incidence (days) | 464 | 300 | 268 | 492
Rao-Scott adjusted Poly-3 test | P = 0.356N | P = 0.358N | P = 0.462N | P = 0.344N
Litter C-A/Fisher’s test | P = 0.505N | P = 0.351 | P = 0.337 | P = 0.645
Mammary Gland: Adenoma
Overall rate | 8/90 (9%) | 4/90 (4%) | 1/90 (1%) | 2/90 (2%)
Rate per litters | 7/35 (20%) | 4/34 (12%) | 1/35 (3%) | 2/35 (6%)
Adjusted rate | 11.3% | 5.4% | 1.4% | 2.5%
Terminal rate | 5/48 (10%) | 1/45 (2%) | 1/50 (2%) | 2/61 (3%)
First incidence (days) | 524 | 647 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.035N | P = 0.207N | P = 0.039N | P = 0.063N
Litter C-A/Fisher’s test | P = 0.034N | P = 0.274N | P = 0.027N | P = 0.075N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 64/90 (71%) | 62/90 (69%) | 63/90 (70%) | 62/90 (69%)
Rate per litters | 31/35 (89%) | 32/34 (94%) | 33/35 (94%) | 31/35 (89%)
Adjusted rate | 77.7% | 74.5% | 75.2% | 73.1%
Terminal rate | 36/48 (75%) | 33/45 (73%) | 36/50 (72%) | 45/61 (74%)
First incidence (days) | 464 | 300 | 268 | 492
Rao-Scott adjusted Poly-3 test | P = 0.307N | P = 0.386N | P = 0.427N | P = 0.312N
Litter C-A/Fisher’s test | P = 0.505N | P = 0.351 | P = 0.337 | P = 0.645
Mammary Gland: Adenocarcinoma
Overall rate | 10/90 (11%) | 8/90 (9%) | 6/90 (7%) | 4/90 (4%)
Rate per litters | 9/35 (26%) | 8/34 (24%) | 5/35 (14%) | 4/35 (11%)
Adjusted rate | 14.2% | 10.4% | 8.2% | 4.9%
Terminal rate | 6/48 (13%) | 1/45 (2%) | 3/50 (6%) | 2/61 (3%)
First incidence (days) | 622 | 300 | 493 | 305
Rao-Scott adjusted Poly-3 test | P = 0.042N | P = 0.330N | P = 0.196N | P = 0.055N
Litter C-A/Fisher’s test | P = 0.059N | P = 0.528N | P = 0.185N | P = 0.109N
Mammary Gland: Adenoma or Adenocarcinoma
Overall rate | 16/90 (18%) | 12/90 (13%) | 7/90 (8%) | 6/90 (7%)
Rate per litters | 13/35 (37%) | 12/34 (35%) | 5/35 (14%) | 6/35 (17%)
Adjusted rate | 22.2% | 15.5% | 9.5% | 7.4%
Terminal rate | 9/48 (19%) | 2/45 (4%) | 4/50 (8%) | 4/61 (7%)
First incidence (days) | 524 | 300 | 493 | 305
Rao-Scott adjusted Poly-3 test | P = 0.009N | P = 0.214N | P = 0.041N | P = 0.014N
Litter C-A/Fisher’s test | P = 0.017N | P = 0.536N | P = 0.027N | P = 0.053N
Mammary Gland: Fibroadenoma, Adenoma, or Adenocarcinoma
Overall rate | 66/90 (73%) | 68/90 (76%) | 66/90 (73%) | 66/90 (73%)
Rate per litters | 31/35 (89%) | 33/34 (97%) | 34/35 (97%) | 32/35 (91%)
Adjusted rate | 79.6% | 78.7% | 78.1% | 76.6%
Terminal rate | 36/48 (75%) | 33/45 (73%) | 37/50 (74%) | 47/61 (77%)
First incidence (days) | 464 | 300 | 268 | 305
Rao-Scott adjusted Poly-3 test | P = 0.352N | P = 0.518N | P = 0.478N | P = 0.393N
Litter C-A/Fisher’s test | P = 0.519 | P = 0.187 | P = 0.178 | P = 0.500
Pancreatic Islets: Adenoma
Overall rate | 5/90 (6%) | 4/89 (4%) | 5/90 (6%) | 4/88 (5%)
Rate per litters | 4/35 (11%) | 4/34 (12%) | 5/35 (14%) | 4/35 (11%)
Adjusted rate | 7.2% | 5.5% | 6.9% | 5.1%
Terminal rate | 5/48 (10%) | 2/45 (4%) | 3/50 (6%) | 4/61 (7%)
First incidence (days) | 737 (T) | 647 | 627 | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.405N | P = 0.460N | P = 0.585N | P = 0.424N
Litter C-A/Fisher’s test | P = 0.558 | P = 0.629 | P = 0.500 | P = 0.645
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 7/90 (8%) | 6/89 (7%) | 5/90 (6%) | 6/88 (7%)
Rate per litters | 6/35 (17%) | 6/34 (18%) | 5/35 (14%) | 6/35 (17%)
Adjusted rate | 10.1% | 8.2% | 6.9% | 7.6%
Terminal rate | 6/48 (13%) | 3/45 (7%) | 3/50 (6%) | 5/61 (8%)
First incidence (days) | 711 | 647 | 627 | 702
Rao-Scott adjusted Poly-3 test | P = 0.367N | P = 0.451N | P = 0.347N | P = 0.404N
Litter C-A/Fisher’s test | P = 0.538N | P = 0.603 | P = 0.500N | P = 0.624
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 43/90 (48%) | 41/89 (46%) | 30/89 (34%) | 40/90 (44%)
Rate per litters | 28/35 (80%) | 26/34 (76%) | 21/35 (60%) | 25/35 (71%)
Adjusted rate | 57.1% | 52.9% | 39.5% | 49.0%
Terminal rate | 28/48 (58%) | 20/45 (44%) | 16/50 (32%) | 31/61 (51%)
First incidence (days) | 464 | 578 | 493 | 626
Rao-Scott adjusted Poly-3 test | P = 0.156N | P = 0.360N | P = 0.026N | P = 0.204N
Litter C-A/Fisher’s test | P = 0.203N | P = 0.474N | P = 0.058N | P = 0.289N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 44/90 (49%) | 42/89 (47%) | 31/89 (35%) | 40/90 (44%)
Rate per litters | 29/35 (83%) | 26/34 (76%) | 21/35 (60%) | 25/35 (71%)
Adjusted rate | 57.9% | 54.1% | 40.7% | 49.0%
Terminal rate | 28/48 (58%) | 20/45 (44%) | 16/50 (32%) | 31/61 (51%)
First incidence (days) | 464 | 578 | 493 | 626
Rao-Scott adjusted Poly-3 test | P = 0.131N | P = 0.381N | P = 0.030N | P = 0.180N
Litter C-A/Fisher’s test | P = 0.144N | P = 0.360N | P = 0.031N | P = 0.197N
Skin (Subcutaneous Tissue): Fibroma, Sarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 5/90 (6%) | 0/90 (0%) | 1/90 (1%) | 3/90 (3%)
Rate per litters | 5/35 (14%) | 0/34 (0%) | 1/35 (3%) | 3/35 (9%)
Adjusted rate | 7.0% | 0% | 1.4% | 3.7%
Terminal rate | 1/48 (2%) | 0/45 (0%) | 1/50 (2%) | 1/61 (2%)
First incidence (days) | 268 | –^g^ | 737 (T) | 550
Rao-Scott adjusted Poly-3 test | P = 0.413N | P = 0.057N | P = 0.142N | P = 0.335N
Litter C-A/Fisher’s test | P = 0.426N | P = 0.029N | P = 0.099N | P = 0.355N
Thyroid Gland (C-cell): Adenoma
Overall rate | 6/90 (7%) | 9/90 (10%) | 3/90 (3%) | 8/89 (9%)
Rate per litters | 6/35 (17%) | 9/34 (26%) | 3/35 (9%) | 7/35 (20%)
Adjusted rate | 8.5% | 12.1% | 4.2% | 10.1%
Terminal rate | 3/48 (6%) | 6/45 (13%) | 2/50 (4%) | 6/61 (10%)
First incidence (days) | 608 | 578 | 674 | 669
Rao-Scott adjusted Poly-3 test | P = 0.548N | P = 0.326 | P = 0.232N | P = 0.473
Litter C-A/Fisher’s test | P = 0.507N | P = 0.259 | P = 0.239N | P = 0.500
Thyroid Gland: (C-cell): Adenoma or Carcinoma
Overall rate | 6/90 (7%) | 11/90 (12%) | 6/90 (7%) | 10/89 (11%)
Rate per litters | 6/35 (17%) | 11/34 (32%) | 6/35 (17%) | 9/35 (26%)
Adjusted rate | 8.5% | 14.8% | 8.3% | 12.6%
Terminal rate | 3/48 (6%) | 8/45 (18%) | 4/50 (8%) | 8/61 (13%)
First incidence (days) | 608 | 578 | 643 | 669
Rao-Scott adjusted Poly-3 test | P = 0.390 | P = 0.175 | P = 0.579N | P = 0.288
Litter C-A/Fisher’s test | P = 0.402 | P = 0.118 | P = 0.624 | P = 0.281
Uterus: Polyp Stromal
Overall rate | 16/90 (18%) | 17/90 (19%) | 16/90 (18%) | 17/90 (19%)
Rate per litters | 11/35 (31%) | 13/34 (38%) | 15/35 (43%) | 13/35 (37%)
Adjusted rate | 22.7% | 23.0% | 22.0% | 21.2%
Terminal rate | 14/48 (29%) | 13/45 (29%) | 12/50 (24%) | 14/61 (23%)
First incidence (days) | 531 | 605 | 631 | 587
Rao-Scott adjusted Poly-3 test | P = 0.437N | P = 0.552 | P = 0.532N | P = 0.490N
Litter C-A/Fisher’s test | P = 0.374 | P = 0.367 | P = 0.229 | P = 0.401
All Organs: Malignant Lymphoma
Overall rate | 5/90 (6%) | 2/90 (2%) | 4/90 (4%) | 3/90 (3%)
Rate per litters | 5/35 (14%) | 2/34 (6%) | 4/35 (11%) | 3/35 (9%)
Adjusted rate | 7.0% | 2.7% | 5.5% | 3.7%
Terminal rate | 0/48 (0%) | 1/45 (2%) | 1/50 (2%) | 0/61 (0%)
First incidence (days) | 268 | 706 | 483 | 587
Rao-Scott adjusted Poly-3 test | P = 0.339N | P = 0.209N | P = 0.472N | P = 0.297N
Litter C-A/Fisher’s test | P = 0.382N | P = 0.226N | P = 0.500N | P = 0.355N
All Organs: Benign Neoplasms
Overall rate | 82/90 (91%) | 84/90 (93%) | 78/90 (87%) | 79/90 (88%)
Rate per litters | 35/35 (100%) | 34/34 (100%) | 35/35 (100%) | 35/35 (100%)
Adjusted rate | 97.1% | 97.7% | 90.7% | 91.1%
Terminal rate | 48/48 (100%) | 44/45 (98%) | 44/50 (88%) | 55/61 (90%)
First incidence (days) | 464 | 300 | 268 | 492
Rao-Scott adjusted Poly-3 test | P = 0.039N | P = 0.602 | P = 0.098N | P = 0.113N
Litter C-A/Fisher’s test | –^h^ | – | – | –
All Organs: Malignant Neoplasms
Overall rate | 37/90 (41%) | 28/90 (31%) | 24/90 (27%) | 22/90 (24%)
Rate per litters | 25/35 (71%) | 19/34 (56%) | 19/35 (54%) | 20/35 (57%)
Adjusted rate | 48.1% | 35.1% | 31.0% | 26.6%
Terminal rate | 21/48 (44%) | 10/45 (22%) | 10/50 (20%) | 14/61 (23%)
First incidence (days) | 268 | 300 | 483 | 305
Rao-Scott adjusted Poly-3 test | P = 0.006N | P = 0.073N | P = 0.026N | P = 0.005N
Litter C-A/Fisher’s test | P = 0.185N | P = 0.137N | P = 0.108N | P = 0.159N
All Organs: Benign or Malignant Neoplasms
Overall rate | 89/90 (99%) | 88/90 (98%) | 82/90 (91%) | 85/90 (94%)
Rate per litters | 35/35 (100%) | 34/34 (100%) | 35/35 (100%) | 35/35 (100%)
Adjusted rate | 100% | 98.7% | 93.0% | 96.4%
Terminal rate | 48/48 (100%) | 44/45 (98%) | 44/50 (88%) | 59/61 (97%)
First incidence (days) | 268 | 300 | 268 | 305
Rao-Scott adjusted Poly-3 test | P = 0.127N | P = 0.582N | P = 0.051N | P = 0.203N
Litter C-A/Fisher’s test | – | – | – | –

(T) = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Number of litters with tumor-bearing animals/number of litters examined at site.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ The Litter Cochran-Armitage and Fishers exact tests directly compare the litter incidence rates.

^g^ Not applicable; no neoplasms in animal group.

^h^ Value of statistic cannot be computed.

Table D‑3 Historical Incidence of Malignant Schwannoma in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Heart: Malignant Schwannoma | All Organs: Malignant Schwannoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/49 | 2/50
Indole-3-carbinol (March 2007) | 0/50 | 2/50
Radiofrequency radiation (September 2012) | 0/90 | 4/90
Overall Historical Incidence
Total (%) | 0/239 | 8/240 (3.3%)
Mean ± standard deviation | – | 3.1% ± 2.1%
Range | – | 0%–4%

^a^ Data as of November 2017.

Table D‑4 Historical Incidence of Malignant Glioma of the Brain in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 1/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50
Radiofrequency radiation (September 2012) | 0/90
Overall Historical Incidence
Total (%) | 1/190 (0.5%)
Mean ± standard deviation | 0.7% ± 1.2%
Range | 0%–2%

^a^ Data as of November 2017; due to differences in sectioning method, indole-3-carbinol was excluded from evaluation of brain lesions.

Table D‑5 Historical Incidence of Pituitary Gland (Pars Distalis) Neoplasms in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 18/50 | 0/50 | 18/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 19/50 | 0/50 | 19/50
Indole-3-carbinol (March 2007) | 18/50 | 0/50 | 18/50
Radiofrequency radiation (September 2012) | 43/90 | 1/90 | 44/90
Overall Historical Incidence
Total (%) | 98/240 (40.8%) | 1/240 (0.4%) | 99/240 (41.3%)
Mean ± standard deviation | 39.4% ± 5.6% | 0.3% ± 0.6% | 39.7% ± 6.2%
Range | 36%–48% | 0%–1% | 36%–49%

^a^ Data as of November 2017.

Table D‑6 Historical Incidence of Hepatocellular Neoplasms in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 2/50 | 0/50 | 2/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50 | 0/50 | 0/50
Indole-3-carbinol (March 2007) | 2/50 | 0/50 | 2/50
Radiofrequency radiation (September 2012) | 7/90 | 0/90 | 7/90
Overall Historical Incidence
Total (%) | 11/240 (4.6%) | 0/240 | 11/240 (4.6%)
Mean ± standard deviation | 3.9% ± 3.2% | – | 3.9% ± 3.2%
Range | 0%–8% | – | 0%–8%

^a^ Data as of November 2017.

Table D‑7 Historical Incidence of Adrenal Medulla Neoplasms in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Benign Pheochromocytoma | Malignant Pheochromocytoma | Complex Pheochromocytoma | Benign, Malignant, or Complex Pheochromocytoma
Historical Incidence: All Studies
p-Chloro-α,α,α- trifluorotoluene (January 2011) | 0/49 | 0/49 | 0/49 | 0/49
2-Hydroxy-4-methoxybenzophenone (November 2010) | 3/50 | 2/50 | 0/50 | 5/50
Indole-3-carbinol (March 2007) | 0/50 | 0/50 | 0/50 | 0/50
Radiofrequency radiation (September 2012) | 1/86 | 0/86 | 0/86 | 1/86
Overall Historical Incidence
Total (%) | 4/235 (1.7%) | 2/235 (0.9%) | 0/235 | 6/235 (2.6%)
Mean ± standard deviation | 1.8% ± 2.9% | 1.0% ± 2.0% | – | 2.8% ± 4.8%
Range | 0%-6% | 0%-4% | – | 0%-10%

^a^ Data as of November 2017.

Table D‑8 Summary of the Incidence of Non-neoplastic Lesions in Female Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1 | – | – | –
Moribund | 30 | 29 | 28 | 16
Natural deaths | 11 | 15 | 12 | 13
Survivors
Died last week of study | 1 | 2 | – | –
Terminal euthanasia | 47 | 44 | 50 | 61
Animals examined microscopically | 100 | 100 | 100 | 100
Fourteen-week Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Intestine large, rectum | (10) | (10) | (10) | (10)
Lymphoid tissue, hyperplasia | 1 (10%) | – | 2 (20%) | 1 (10%)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, mixed cell | 1 (10%) | 1 (10%) | – | 2 (20%)
Inflammation, chronic active | – | – | – | 1 (10%)
Pancreas | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Salivary glands | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Cardiovascular System
Aorta | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | – | – | 2 (20%) | 2 (20%)
Endocardium, inflammation, chronic active | – | – | – | 1 (10%)
Ventricle right, cardiomyopathy | – | – | 1 (10%) | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (10) | (10) | (9) | (9)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | 2 (20%) | – | – | –
Pars intermedia, cyst | 1 (10%) | – | 2 (20%) | –
Rathke’s cleft, cyst | – | 1 (10%) | – | –
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | – | – | 1 (10%) | –
Genital System
Clitoral gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 4 (40%) | 4 (40%) | 4 (40%) | 2 (20%)
Ovary | (10) | (10) | (10) | (10)
Follicle, cyst | 1 (10%) | – | 1 (10%) | –
Uterus | (10) | (10) | (10) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node | (0) | (0) | (1) | (0)
Pigment | – | – | 1 (100%) | –
Lymph node, mandibular | (10) | (10) | (10) | (9)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Extramedullary hematopoiesis | – | – | – | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%) | 2 (20%) | 1 (10%) | –
Hyperplasia, epithelial | – | – | – | 1 (10%)
Integumentary System
Mammary gland | (10) | (10) | (10) | (10)
Skin | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Musculoskeletal System
Bone | (10) | (10) | (10) | (10)
Skeletal muscle | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | – | – | – | 1 (10%)
Alveolus, infiltration cellular, histiocyte | 2 (20%) | – | – | –
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Conjunctiva, inflammation, chronic active | – | – | – | 1 (10%)
Harderian gland | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | –
Inflammation, chronic | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Infiltration cellular, mixed cell | – | – | – | 1 (10%)
Inflammation, chronic active | – | – | – | 1 (10%)
Nephropathy, chronic progressive | 3 (30%) | 3 (30%) | 4 (40%) | 4 (40%)
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined with No Lesions Observed
General Body System
Nervous System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Dilation | – | 2 (2%) | – | –
Inflammation, acute | – | – | – | 1 (1%)
Muscularis, degeneration | – | 1 (1%) | – | –
Intestine large, cecum | (84) | (82) | (86) | (80)
Ulcer | – | – | 1 (1%) | –
Artery, inflammation, chronic active | – | 2 (2%) | – | –
Intestine large, colon | (89) | (89) | (88) | (88)
Diverticulum | – | – | 1 (1%) | –
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Intestine large, rectum | (90) | (88) | (87) | (88)
Hyperplasia, lymphocyte | – | – | 3 (3%) | –
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Intestine small, duodenum | (88) | (86) | (87) | (85)
Intestine small, ileum | (86) | (83) | (84) | (83)
Hyperplasia, lymphocyte | 1 (1%) | – | – | –
Intestine small, jejunum | (83) | (81) | (84) | (79)
Liver | (90) | (90) | (90) | (90)
Angiectasis | 6 (7%) | 3 (3%) | 9 (10%) | 3 (3%)
Basophilic focus | 11 (12%) | 11 (12%) | 7 (8%) | 15 (17%)
Clear cell focus | 2 (2%) | 4 (4%) | 7 (8%) | 3 (3%)
Congestion | – | – | – | 1 (1%)
Eosinophilic focus | 9 (10%) | 17 (19%) | 10 (11%) | 9( 10%)
Extramedullary hematopoiesis | 15 (17%) | 11 (12%) | 13 (14%) | 13 (14%)
Hepatodiaphragmatic nodule | 1 (1%) | – | – | 3 (3%)
Infiltration cellular, histiocyte | – | 1 (1%) | – | –
Infiltration cellular, mixed cell | 1 (1%) | 2 (2%) | 4 (4%) | 2 (2%)
Inflammation, granulomatous | – | 1 (1%) | – | –
Mitotic alteration | – | – | – | 1 (1%)
Mixed cell focus | 29 (32%) | 17 (19%) | 29 (32%) | 35 (39%)
Pigment | – | 1 (1%) | – | –
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Bile duct, cyst | 11 (12%) | 14 (16%) | 6 (7%) | 9 (10%)
Bile duct, fibrosis | 1 (1%) | 1 (1%) | 4 (4%) | –
Bile duct, hyperplasia | 9 (10%) | 10 (11%) | 12 (13%) | 7 (8%)
Hepatocyte, hypertrophy | 2 (2%) | 2 (2%) | 1 (1%) | 1 (1%)
Hepatocyte, increased mitoses | 2 (2%) | – | – | –
Hepatocyte, necrosis | 4 (4%) | 9 (10%) | 7 (8%) | 4 (4%)
Hepatocyte, vacuolation, cytoplasmic | 1 (1%) | 5 (6%) | 5 (6%) | 9 (10%)
Kupffer cell, hyperplasia | 3 (3%) | – | – | 1 (1%)
Kupffer cell, hypertrophy | 2 (2%) | – | – | –
Kupffer cell, pigment | – | – | 1 (1%) | 1 (1%)
Periductal, cholangiofibrosis | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Serosa, inflammation, chronic active | 1 (1%) | – | – | –
Mesentery | (4) | (3) | (11) | (4)
Hemorrhage | – | – | 1 (9%) | –
Inflammation, chronic active | 1 (25%) | – | – | 1 (25%)
Necrosis | 1 (25%) | 1 (33%) | 5 (45%) | 2 (50%)
Artery, inflammation, chronic active | – | 2 (67%) | 2 (18%) | –
Vein, degeneration | – | – | 1 (9%) | –
Vein, inflammation, chronic active | – | – | 1 (9%) | 1 (25%)
Oral mucosa | (1) | (1) | (0) | (0)
Inflammation, chronic active | – | 1 (100%) | – | –
Pancreas | (90) | (90) | (90) | (89)
Ectopic liver | 1 (1%) | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | – | – | 3 (3%)
Necrosis | – | – | – | 1 (1%)
Acinus, atrophy | 5 (6%) | 2 (2%) | 6 (7%) | 2 (2%)
Acinus, hyperplasia | 1 (1%) | 4 (4%) | 2 (2%) | 2 (2%)
Artery, inflammation, chronic active | – | 5 (6%) | – | 1 (1%)
Periductal, cholangiofibrosis | – | 3 (3%) | 2 (2%) | 1 (1%)
Salivary glands | (90) | (90) | (90) | (90)
Degeneration | – | 1 (1%) | – | –
Artery, inflammation, chronic active | – | 3 (3%) | – | –
Duct, parotid gland, dilation | 1 (1%) | 1 (1%) | 2 (2%) | –
Duct, parotid gland, fibrosis | – | – | 1 (1%) | –
Parotid gland, atrophy | 4 (4%) | 7 (8%) | 9 (10%) | 1 (1%)
Parotid gland, fibrosis | – | – | 2 (2%) | 3 (3%)
Parotid gland, inflammation, suppurative | – | 1 (1%) | – | –
Parotid gland, inflammation, acute | – | 1 (1%) | 1 (1%) | –
Parotid gland, mineral | – | – | – | 1 (1%)
Parotid gland, vacuolation, cytoplasmic | – | – | 1 (1%) | –
Sublingual gland, atrophy | – | 2 (2%) | 3 (3%) | –
Sublingual gland, fibrosis | – | – | 1 (1%) | –
Sublingual gland, metaplasia | – | 1 (1%) | – | 1 (1%)
Submandibular gland, atrophy | – | – | 1 (1%) | 1 (1%)
Stomach, forestomach | (90) | (90) | (90) | (90)
Cyst, squamous | – | – | – | 1 (1%)
Edema | 2 (2%) | 2 (2%) | 2 (2%) | 3 (3%)
Erosion | 2 (2%) | 1 (1%) | – | –
Fibrosis | 1 (1%) | 1 (1%) | 1 (1%) | –
Inflammation, acute | – | – | – | 1 (1%)
Inflammation, chronic active | 4 (4%) | 5 (6%) | 2 (2%) | 1 (1%)
Ulcer | 1 (1%) | 3 (3%) | 3 (3%) | 3 (3%)
Epithelium, hyperplasia | 10 (11%) | 11 (12%) | 8 (9%) | 8 (9%)
Epithelium, hyperplasia, basal cell | 1 (1%) | 1 (1%) | 2 (2%) | –
Stomach, glandular | (90) | (90) | (89) | (88)
Cyst | – | 1 (1%) | – | –
Erosion | 1 (1%) | – | 1 (1%) | 1 (1%)
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Tongue | (1) | (0) | (0) | (0)
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Blood vessel | (0) | (0) | (0) | (1)
Pulmonary artery, degeneration | – | – | – | 1 (100%)
Heart | (90) | (90) | (90) | (90)
Cardiomyopathy | 40 (44%) | 43 (48%) | 33 (37%) | 45 (50%)
Artery, inflammation, chronic | – | 1 (1%) | – | –
Artery, mineral | – | 1 (1%) | – | –
Artery, necrosis | – | 1 (1%) | – | –
Atrium, endocardium, hyperplasia, Schwann cell | – | – | 1 (1%) | –
Endocardium, hyperplasia, Schwann cell | – | 1 (1%) | – | 1 (1%)
Epicardium, inflammation, acute | – | – | 1 (1%) | –
Ventricle right, cardiomyopathy | 4 (4%) | 7 (8%) | 9 (10%) | 9 (10%)
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (90)
Accessory adrenal cortical nodule | 5 (6%) | 7 (8%) | 6 (7%) | 12 (13%)
Atrophy | 1 (1%) | – | 2 (2%) | –
Degeneration, cystic | 22 (24%) | 19 (21%) | 18 (20%) | 19 (21%)
Extramedullary hematopoiesis | – | – | 1 (1%) | –
Hyperplasia | 14 (16%) | 31 (34%) | 26 (29%) | 19 (21%)
Hypertrophy | 52 (58%) | 55 (61%) | 56 (62%) | 50 (56%)
Necrosis | 2 (2%) | 2 (2%) | 2 (2%) | 4 (4%)
Pigment | 1 (1%) | – | 1 (1%) | –
Vacuolation, cytoplasmic | 18 (20%) | 17 (19%) | 11 (12%) | 14 (16%)
Adrenal medulla | (86) | (89) | (87) | (88)
Hyperplasia | 13 (15%) | 20 (22%) | 20 (23%) | 18 (20%)
Hypertrophy | – | – | – | 1 (1%)
Necrosis | 1 (1%) | – | – | 1 (1%)
Islets, pancreatic | (90) | (89) | (90) | (88)
Hyperplasia | 15 (17%) | 12 (13%) | 14 (16%) | 13 (15%)
Parathyroid gland | (87) | (80) | (85) | (85)
Cyst | – | – | 2 (2%) | –
Fibrosis | 13 (15%) | 11 (14%) | 6 (7%) | 10 (12%)
Hyperplasia | – | 2 (3%) | – | 3 (4%)
Hyperplasia, focal | 3 (3%) | – | 2 (2%) | –
Hypertrophy, focal | – | – | – | 1 (1%)
Pituitary gland | (90) | (89) | (89) | (90)
Angiectasis | – | 1 (1%) | – | –
Atrophy | – | – | 1 (1%) | –
Cyst | 1 (1%) | – | 1 (1%) | –
Fibrosis | – | – | 1 (1%) | –
Pigment | – | – | 2 (2%) | –
Pars distalis, angiectasis | 2 (2%) | – | – | –
Pars distalis, cyst | 7 (8%) | 5 (6%) | 3 (3%) | 1 (1%)
Pars distalis, hyperplasia | 20 (22%) | 22 (25%) | 26 (29%) | 22 (24%)
Pars distalis, vacuolation, cytoplasmic | – | – | 1 (1%) | –
Pars intermedia, cyst | 3 (3%) | 3 (3%) | 1 (1%) | 3 (3%)
Pars intermedia, hyperplasia | 1 (1%) | – | 1 (1%) | –
Pars nervosa, developmental malformation | – | – | – | 1 (1%)
Thyroid gland | (90) | (90) | (90) | (89)
C-cell, hyperplasia | 28 (31%) | 30 (33%) | 34 (38%) | 38 (43%)
C-cell, hypoplasia | – | – | – | 1 (1%)
Follicle, cyst | 1 (1%) | – | 1 (1%) | –
Follicular cell, hyperplasia | – | 1 (1%) | – | –
General Body System
Tissue NOS | (8) | (11) | (8) | (6)
Cyst | – | 1 (9%) | – | –
Inflammation, chronic active | 1 (13%) | 1 (9%) | – | –
Abdominal, fat, necrosis | – | 5 (45%) | 3 (38%) | 2 (33%)
Fat, necrosis | 6 (75%) | 4 (36%) | 4 (50%) | 3 (50%)
Mediastinum, cyst | – | – | – | 1 (17%)
Mediastinum, hemorrhage | – | 1 (9%) | – | –
Mediastinum, inflammation, chronic | – | 1 (9%) | – | –
Genital System
Clitoral gland | (87) | (88) | (89) | (86)
Hyperplasia | – | 1 (1%) | – | –
Inflammation, suppurative | 1 (1%) | 1 (1%) | – | –
Inflammation, granulomatous | – | – | – | 1 (1%)
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic | – | – | 1 (1%) | 1 (1%)
Inflammation, chronic active | 28 (32%) | 43 (49%) | 35 (39%) | 42 (49%)
Duct, dilation | 47 (54%) | 64 (73%) | 65 (73%) | 60 (70%)
Duct, hyperplasia | – | 3 (3%) | 4 (4%) | 1 (1%)
Ovary | (90) | (90) | (89) | (90)
Atrophy | 72 (80%) | 69 (77%) | 56 (63%) | 77 (86%)
Congestion | 1 (1%) | – | – | –
Cyst | 22 (24%) | 27 (30%) | 23 (26%) | 34 (38%)
Fibrosis | – | 1 (1%) | 1 (1%) | 1 (1%)
Hemorrhage | – | – | – | 1 (1%)
Inflammation, chronic | – | 1 (1%) | 1 (1%) | –
Inflammation, chronic active | – | – | 1 (1%) | –
Pigment | – | – | – | 1 (1%)
Bursa, dilation | 4 (4%) | 4 (4%) | 2 (2%) | 1 (1%)
Follicle, cyst | – | – | – | 1 (1%)
Periovarian tissue, cyst | – | – | 1 (1%) | –
Rete ovarii, cyst | – | – | 1 (1%) | –
Rete ovarii, hyperplasia | 15 (17%) | 17 (19%) | 14 (16%) | 11 (12%)
Oviduct | (1) | (0) | (0) | (0)
Cyst | 1 (100%) | – | – | –
Uterus | (90) | (90) | (90) | (90)
Adenomyosis | – | 2 (2%) | 2 (2%) | –
Angiectasis | 1 (1%) | – | – | –
Cyst | 5 (6%) | 6 (7%) | 7 (8%) | 11 (12%)
Dilation | 8 (9%) | 10 (11%) | 11 (12%) | 8 (9%)
Fibrosis | 1 (1%) | – | 1 (1%)
Hemorrhage | – | – | 1 (1%) | 4 (4%)
Infiltration cellular, plasma cell | – | 1 (1%) | – | –
Inflammation, suppurative | 4 (4%) | 11 (12%) | 8 (9%) | 12 (13%)
Inflammation, acute | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Inflammation, chronic active | – | – | 4 (4%) | 1 (1%)
Thrombus | 1 (1%) | 1 (1%) | – | –
Cervix, hyperplasia, stromal | 2 (2%) | 1 (1%) | 1 (1%) | 1 (1%)
Cervix, thrombus | – | 1 (1%) | – | –
Cervix, epithelium, hyperplasia | – | 1 (1%) | – | –
Cervix, serosa, fibrosis | 1 (1%) | – | – | –
Endometrium, hyperplasia, cystic | 37 (41%) | 43 (48%) | 35 (39%) | 46 (51%)
Epithelium, metaplasia, squamous | 48 (53%) | 39 (43%) | 28 (31%) | 46 (51%)
Glands, dilation | – | 1 (1%) | – | –
Vagina | (2) | (1) | (0) | (1)
Cyst | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Fibrosis | – | 2 (2%) | – | –
Hypercellularity | 56 (62%) | 52 (58%) | 43 (48%) | 43 (48%)
Lymph node | (13) | (8) | (11) | (20)
Erythrophagocytosis | – | 1 (13%) | – | –
Axillary, erythrophagocytosis | – | – | – | 1 (5%)
Axillary, proliferation, plasma cell | 1 (8%) | – | – | –
Bronchial, erythrophagocytosis | – | – | 1 (9%) | –
Bronchial, proliferation, plasma cell | – | – | 1 (9%) | –
Deep cervical, erythrophagocytosis | – | – | – | 1 (5%)
Iliac, erythrophagocytosis | 3 (23%) | 3 (38%) | 1 (9%) | 3 (15%)
Iliac, hyperplasia, lymphocyte | 1 (8%) | – | 1 (9%) | 6 (30%)
Iliac, infiltration cellular, histiocyte | – | – | – | 1 (5%)
Iliac, inflammation, acute | 1 (8%) | – | – | –
Iliac, pigment | 1 (8%) | – | – | 3 (15%)
Iliac, proliferation, plasma cell | 6 (46%) | 1 (13%) | 2 (18%) | 5 (25%)
Iliac, lymphatic sinus, ectasia | – | 1 (13%) | 1 (9%) | 5 (25%)
Inguinal, erythrophagocytosis | 1 (8%) | – | – | –
Inguinal, hyperplasia, lymphocyte | – | – | 1 (9%) | –
Inguinal, pigment | – | – | 1 (9%) | –
Inguinal, proliferation, plasma cell | 1 (8%) | – | – | –
Inguinal, lymphatic sinus, ectasia | 1 (8%) | 1 (13%) | 1 (9%) | –
Lumbar, erythrophagocytosis | 1 (8%) | 2 (25%) | – | –
Lumbar, hyperplasia, lymphocyte | – | – | – | 1 (5%)
Lumbar, lymphatic sinus, ectasia | – | – | – | 1 (5%)
Lymphatic sinus, renal, ectasia | – | 1 (13%) | – | –
Mediastinal, congestion | 1 (8%) | – | – | –
Mediastinal, erythrophagocytosis | – | 2 (25%) | 4 (36%) | 4 (20%)
Mediastinal, proliferation, plasma cell | 1 (8%) | – | – | –
Pancreatic, erythrophagocytosis | 1 (8%) | – | 1 (9%) | –
Pancreatic, infiltration cellular, histiocyte | – | – | – | 1 (5%)
Renal, erythrophagocytosis | – | 2 (25%) | – | –
Lymph node, mandibular | (90) | (90) | (89) | (90)
Congestion | – | 2 (2%) | – | 1 (1%)
Erythrophagocytosis | – | 1 (1%) | 2 (2%) | 3 (3%)
Hemorrhage | 1 (1%) | – | – | –
Hyperplasia, lymphocyte | 46 (51%) | 49 (54%) | 45 (51%) | 43 (48%)
Infiltration cellular, histiocyte | – | – | – | 1 (1%)
Pigment | – | – | – | 1 (1%)
Proliferation, plasma cell | 68 (76%) | 68 (76%) | 58 (65%) | 56 (62%)
Lymphatic sinus, ectasia | 1 (1%) | 2 (2%) | 2 (2%) | 3 (3%)
Lymph node, mesenteric | (90) | (90) | (90) | (89)
Atrophy | 1 (1%) | – | – | –
Erythrophagocytosis | 1 (1%) | 3 (3%) | 2 (2%) | –
Hyperplasia, lymphocyte | – | – | 1 (1%) | –
Infiltration cellular, histiocyte | 2 (2%) | – | – | 1 (1%)
Lymphatic sinus, ectasia | – | – | 1 (1%) | 1 (1%)
Spleen | (90) | (90) | (90) | (90)
Accessory spleen | – | 1 (1%) | – | –
Extramedullary hematopoiesis | 80 (89%) | 74 (82%) | 79 (88%) | 82 (91%)
Fibrosis | – | 1 (1%) | – | –
Hemorrhage | – | 1 (1%) | – | 1 (1%)
Hyperplasia, lymphocyte | – | 1 (1%) | – | –
Hyperplasia, stromal | 1 (1%) | – | 1 (1%) | –
Pigment | 74 (82%) | 79 (88%) | 77 (86%) | 79 (88%)
Red pulp, atrophy | 7 (8%) | 11 (12%) | 13 (14%) | 6 (7%)
White pulp, atrophy | 3 (3%) | 3 (3%) | 4 (4%) | 1 (1%)
Thymus | (87) | (83) | (87) | (87)
Atrophy | 75 (86%) | 67 (81%) | 74 (85%) | 63 (72%)
Cyst | 39 (45%) | 34 (41%) | 34 (39%) | 45 (52%)
Ectopic parathyroid gland | 1 (1%) | 2 (2%) | 2 (2%) | 2 (2%)
Hemorrhage | 2 (2%) | 5 (6%) | 5 (6%) | 3 (3%)
Hyperplasia, epithelial | 55 (63%) | 59 (71%) | 54 (62%) | 38 (44%)
Hyperplasia, lymphocyte | – | – | 1 (1%) | –
Artery, inflammation, chronic active | – | 2 (2%) | 1 (1%) | –
Integumentary System
Mammary gland | (90) | (90) | (90) | (90)
Galactocele | 24 (27%) | 17 (19%) | 17 (19%) | 10 (11%)
Hyperplasia | 49 (54%) | 50 (56%) | 46 (51%) | 34 (38%)
Inflammation, granulomatous | – | – | 2 (2%) | –
Inflammation, acute | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | 2 (2%) | 1 (1%)
Duct, dilation | 56 (62%) | 61 (68%) | 51 (57%) | 70 (78%)
Skin | (90) | (90) | (90) | (90)
Cyst epithelial inclusion | 1 (1%) | 1 (1%) | 3 (3%) | 1 (1%)
Hyperkeratosis | – | 1 (1%) | – | –
Inflammation, chronic active | 1 (1%) | – | – | 1 (1%)
Ulcer | – | – | 1 (1%) | –
Epidermis, hyperplasia | 2 (2%) | – | – | –
Lymphatic, subcutaneous tissue, angiectasis | – | – | – | 1 (1%)
Subcutaneous tissue, inflammation, chronic active | – | 1 (1%) | – | –
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Fibrous osteodystrophy | – | 1 (1%) | – | –
Cranium, fracture | 1 (1%) | – | – | –
Mandible, fracture | 1 (1%) | – | – | –
Maxilla, fracture | 1 (1%) | – | – | –
Skeletal muscle | (90) | (90) | (90) | (90)
Degeneration | 3 (3%) | 7 (8%) | 10 (11%) | 2 (2%)
Diaphragm, hernia | – | – | – | 1 (1%)
Nervous System
Brain | (90) | (90) | (90) | (90)
Compression | 26 (29%) | 31 (34%) | 16 (18%) | 20 (22%)
Congestion | 1 (1%) | – | – | –
Cyst | – | 1 (1%) | – | –
Edema | 2 (2%) | 1 (1%) | – | –
Hemorrhage | – | 1 (1%) | – | –
Mineral | – | 1 (1%) | 1 (1%) | –
Pigment | – | – | 1 (1%) | –
Cerebrum, degeneration | – | – | 1 (1%) | –
Choroid plexus, mineral | – | 1 (1%) | – | –
Glial cell, hyperplasia | – | – | 1 (1%) | 1 (1%)
Meninges, hyperplasia | 1 (1%) | – | 1 (1%) | –
Meninges, hyperplasia, granular cell | 1 (1%) | – | – | 1 (1%)
Meninges, mineral | – | – | 1 (1%) | –
Neuron, necrosis | – | 1 (1%) | – | –
Pineal gland, infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Pineal gland, mineral | 1 (1%) | – | – | –
Pineal gland, vacuolation, cytoplasmic | 1 (1%) | – | 2 (2%) | –
Nerve trigeminal | (84) | (84) | (85) | (84)
Degeneration | 64 (76%) | 70 (83%) | 64 (75%) | 72 (86%)
Gliosis | – | – | 1 (1%) | –
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Degeneration | 80 (89%) | 83 (92%) | 83 (92%) | 89 (99%)
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Peripheral nerve, tibial | (90) | (90) | (89) | (89)
Degeneration | 77 (86%) | 77 (86%) | 83 (93%) | 86 (97%)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Degeneration | 24 (27%) | 29 (32%) | 22 (24%) | 35 (39%)
Spinal cord, lumbar | (90) | (90) | (89) | (90)
Degeneration | 10 (11%) | 11 (12%) | 15 (17%) | 12 (13%)
Nerve, degeneration | 74 (82%) | 77 (86%) | 77 (87%) | 80 (89%)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Degeneration | 59 (66%) | 64 (71%) | 59 (66%) | 70 (78%)
Trigeminal ganglion | (81) | (77) | (81) | (75)
Degeneration | 33 (41%) | 21 (27%) | 22 (27%) | 28 (37%)
Respiratory System
Lung | (90) | (90) | (90) | (90)
Congestion | 3 (3%) | 12 (13%) | 9 (10%) | 5 (6%)
Foreign body | – | 1 (1%) | – | 1 (1%)
Hemorrhage | 1 (1%) | 6 (7%) | – | 1 (1%)
Inflammation, suppurative | 2 (2%) | – | – | 1 (1%)
Inflammation, granulomatous | 1 (1%) | 5 (6%) | 1 (1%) | 2 (2%)
Inflammation, chronic active | 6 (7%) | 6 (7%) | 6 (7%) | 11 (12%)
Alveolar epithelium, hyperplasia | – | 1 (1%) | – | –
Alveolar epithelium, metaplasia, squamous | – | 1 (1%) | – | 2 (2%)
Alveolus, infiltration cellular, histiocyte | 71 (79%) | 77 (86%) | 84 (93%) | 81 (90%)
Artery, inflammation, chronic active | 1 (1%) | – | – | –
Artery, muscularis, hyperplasia | – | – | – | 1 (1%)
Bronchus, hyperplasia | – | 1 (1%) | – | –
Epithelium alveolus, hyperplasia | 2 (2%) | 2 (2%) | 3 (3%) | 1 (1%)
Pleura, inflammation, acute | – | – | 1 (1%) | –
Nose | (90) | (89) | (90) | (89)
Foreign body | – | 1 (1%) | 1 (1%) | 2 (2%)
Inflammation, suppurative | 1 (1%) | 3 (3%) | 1 (1%) | 3 (3%)
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Nerve, degeneration | – | 1 (1%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 89 (99%) | 89 (100%) | 86 (96%) | 86 (97%)
Olfactory epithelium, hyperplasia | – | – | 1 (1%) | –
Olfactory epithelium, metaplasia, respiratory | 1 (1%) | – | – | 2 (2%)
Olfactory epithelium, metaplasia, squamous | – | 1 (1%) | – | –
Respiratory epithelium, accumulation, hyaline droplet | 12 (13%) | 19 (21%) | 22 (24%) | 11 (12%)
Respiratory epithelium, hyperplasia | – | 1 (1%) | – | 3 (3%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 1 (1%)
Trachea | (89) | (88) | (89) | (89)
Inflammation, chronic active | 1 (1%) | 1 (1%) | – | –
Epithelium, hyperplasia | – | 1 (1%) | – | –
Epithelium, metaplasia, squamous | – | 1 (1%) | – | –
Glands, cyst | 1 (1%) | 1 (1%) | – | 2 (2%)
Special Senses System
Ear | (0) | (0) | (1) | (1)
Eye | (88) | (86) | (88) | (86)
Anterior chamber, exudate | – | 1 (1%) | – | –
Anterior chamber, inflammation, acute | – | – | 1 (1%) | 2 (2%)
Anterior chamber, iris, synechia | – | 1 (1%) | – | –
Choroid, inflammation, chronic active | – | – | 1 (1%) | –
Cornea, fibrosis | – | 1 (1%) | – | –
Cornea, inflammation, acute | 1 (1%) | 2 (2%) | 1 (1%) | 2 (2%)
Cornea, inflammation, chronic active | – | 1 (1%) | – | –
Cornea, neovascularization | – | 1 (1%) | – | –
Cornea, ulcer | – | – | – | 1 (1%)
Cornea, epithelium, hyperplasia | 1 (1%) | 2 (2%) | – | 1 (1%)
Lens, cataract | 1 (1%) | 3 (3%) | – | –
Retina, atrophy | 18 (20%) | 17 (20%) | 18 (20%) | 18 (21%)
Retina, dysplasia | 1 (1%) | 1 (1%) | 1 (1%) | 3 (3%)
Harderian gland | (90) | (90) | (90) | (90)
Atrophy | 13 (14%) | 15 (17%) | 16 (18%) | 17 (19%)
Cyst | – | – | – | 1 (1%)
Hyperplasia | – | – | – | 1 (1%)
Hypertrophy | – | – | – | 1 (1%)
Infiltration cellular, lymphocyte | 2 (2%) | – | – | 1 (1%)
Inflammation, granulomatous | 7 (8%) | 6 (7%) | 4 (4%) | 9 (10%)
Inflammation, chronic | 7 (8%) | 1 (1%) | 1 (1%) | 2 (2%)
Inflammation, chronic active | 1 (1%) | 4 (4%) | 2 (2%) | –
Urinary System
Kidney | (90) | (90) | (90) | (89)
Inflammation, acute | 1 (1%) | – | – | –
Nephropathy, chronic progressive | 74 (82%) | 76 (84%) | 76 (84%) | 65 (73%)
Artery, inflammation, chronic active | 1 (1%) | – | – | –
Pelvis, dilation | 3 (3%) | – | 2 (2%) | –
Pelvis, inflammation, suppurative | – | 2 (2%) | – | –
Pelvis, mineral | – | – | – | 1 (1%)
Pelvis, urothelium, hyperplasia | – | 1 (1%) | – | –
Renal tubule, cyst | 3 (3%) | 2 (2%) | – | –
Renal tubule, hyperplasia | – | – | 1 (1%) | –
Renal tubule, necrosis | – | 1 (1%) | – | –
Urinary bladder | (88) | (88) | (90) | (90)
Dilation | 1 (1%) | – | – | –
Edema | – | 3 (3%) | – | –
Fibrosis | – | – | 1 (1%) | –
Hemorrhage | – | 1 (1%) | 1 (1%) | –
Infiltration cellular, histiocyte | – | 1 (1%) | 1 (1%) | –
Inflammation, acute | 3 (3%) | 2 (2%) | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Necrosis | 1 (1%) | – | – | –
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Urothelium, hyperplasia | 1 (1%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.