# Appendix C Summary of Lesions in Male Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

Table C-1 Summary of the Incidence of Neoplasms in Male Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1
Moribund | 44 | 24 | 13 | 6
Natural deaths | 20 | 23 | 21 | 41
Survivors
Died last week of study | – | – | 1 | –
Terminal euthanasia | 25 | 43 | 55 | 43
Animals examined microscopically | 100 | 100 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Intestine large, cecum | (75) | (76) | (74) | (68)
Intestine large, colon | (81) | (83) | (82) | (76)
Intestine large, rectum | (83) | (81) | (80) | (76)
Serosa, sarcoma, metastatic, skeletal muscle | – | – | – | 1(1%)
Intestine small, duodenum | (81) | (84) | (83) | (66)
Adenocarcinoma | – | – | 1 (1%) | –
Osteosarcoma | – | – | 1 (1%) | –
Serosa, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Intestine small, ileum | (78) | (76) | (77) | (63)
Intestine small, jejunum | (73) | (73) | (75) | (62)
Adenocarcinoma | 2 (3%) | 1 (1%) | – | –
Liver | (90) | (90) | (89) | (88)
Hepatocellular adenoma | – | 2 (2%) | 4 (4%) | –
Hepatocellular carcinoma | – | – | 1 (1%) | 1 (1%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Mesentery | (39) | (19) | (17) | (6)
Oral mucosa | (0) | (1) | (1) | (0)
Squamous cell carcinoma | – | – | 1 (100%) | –
Pancreas | (90) | (88) | (87) | (78)
Adenoma | 13 (14%) | 16 (18%) | 19 (22%) | 5 (6%)
Adenoma, multiple | 5 (6%) | 6 (7%) | 7 (8%) | 2 (3%)
Carcinoma | 1 (1%) | 1 (1%) | 2 (2%) | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | 1 (1%) | – | –
Salivary glands | (90) | (90) | (90) | (86)
Parotid gland, adenoma | – | – | 1 (1%) | –
Sublingual gland, schwannoma malignant, metastatic, uncertain primary site | 1 (1%) | – | – | –
Stomach, forestomach | (90) | (90) | (89) | (90)
Squamous cell carcinoma | – | – | 1 (1%) | –
Squamous cell papilloma | 1 (1%) | – | – | –
Stomach, glandular | (86) | (86) | (85) | (78)
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Blood vessel | (1) | (2) | (1) | (0)
Heart | (90) | (90) | (90) | (90)
Atrium, schwannoma malignant | – | – | – | 1 (1%)
Endocardium, schwannoma malignant | – | 1 (1%) | – | 4 (4%)
Myocardium, schwannoma malignant | – | 1 (1%) | 3 (3%) | 1 (1%)
Pericardium, schwannoma malignant, metastatic, thymus | – | – | 1 (1%) | –
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (89)
Adenoma | 1 (1%) | 3 (3%) | – | –
Carcinoma | – | 3 (3%) | – | 2 (2%)
Adrenal medulla | (88) | (90) | (90) | (90)
Pheochromocytoma benign | 8 (9%) | 17 (19%) | 19 (21%) | 12 (13%)
Pheochromocytoma benign, multiple | 1 (1%) | 1 (1%) | 2 (2%) | –
Pheochromocytoma complex | 1 (1%) | – | – | –
Pheochromocytoma malignant | 1 (1%) | 3 (3%) | 3 (3%) | 1 (1%)
Bilateral, pheochromocytoma benign | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Islets, pancreatic | (90) | (88) | (87) | (79)
Adenoma | 5 (6%) | 11 (13%) | 7 (8%) | 7 (9%)
Adenoma, multiple | – | – | 1 (1%) | –
Carcinoma | 8 (9%) | 6 (7%) | 13 (15%) | 5 (6%)
Carcinoma, multiple | – | – | – | 1 (1%)
Parathyroid gland | (83) | (83) | (83) | (82)
Adenoma | 1 (1%) | 1 (1%) | 2 (2%) | 1 (1%)
Pituitary gland | (89) | (90) | (90) | (90)
Schwannoma malignant, metastatic, tissue NOS | – | 1 (1%) | – | 1 (1%)
Schwannoma malignant, metastatic, uncertain primary site | – | 1 (1%) | – | –
Pars distalis, adenoma | 17 (19%) | 25 (28%) | 33 (37%) | 11 (12%)
Pars distalis, adenoma, multiple | – | – | 1 (1%) | 2 (2%)
Thyroid gland | (89) | (87) | (86) | (85)
Bilateral, C-cell, adenoma | – | 2 (2%) | – | –
Bilateral, C-cell, carcinoma | – | – | 1 (1%) | –
C-cell, adenoma | 8 (9%) | 12 (14%) | 14 (16%) | 11 (13%)
C-cell, carcinoma | 2 (2%) | – | 1 (1%) | 4 (5%)
Follicular cell, adenoma | – | – | – | 1 (1%)
General Body System
Tissue NOS | (3) | (1) | (3) | (3)
Schwannoma malignant | – | 1 (100%) | – | 1 (33%)
Fat, schwannoma malignant | – | – | – | 1 (33%)
Mediastinum, chemodectoma benign | – | – | 1 (33%) | –
Mediastinum, schwannoma malignant | 1 (33%) | – | – | –
Genital System
Bulbourethral gland | (1) | (1) | (0) | (0)
Coagulating gland | (0) | (2) | (3) | (0)
Ductus deferens | (1) | (0) | (1) | (0)
Leiomyoma | – | – | 1 (100%) | –
Epididymis | (90) | (90) | (90) | (90)
Penis | (0) | (4) | (2) | (1)
Preputial gland | (88) | (88) | (89) | (89)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Prostate | (90) | (90) | (90) | (85)
Adenoma | 2 (2%) | – | 2 (2%) | 1 (1%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Seminal vesicle | (90) | (90) | (90) | (90)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Testis | (90) | (89) | (90) | (90)
Hemangioma | – | – | 1 (1%) | –
Interstitial cell, adenoma | 2 (2%) | 2 (2%) | 1 (1%) | 1 (1%)
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (1%) | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Lymph node | (25) | (23) | (24) | (16)
Iliac, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (6%)
Lumbar, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (6%)
Lymph node, mandibular | (89) | (90) | (90) | (88)
Lymph node, mesenteric | (90) | (89) | (88) | (88)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Spleen | (90) | (90) | (90) | (85)
Hemangiosarcoma | 3 (3%) | – | – | –
Thymus | (88) | (85) | (87) | (82)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Schwannoma malignant | – | – | 1 (1%) | –
Integumentary System
Mammary gland | (82) | (77) | (80) | (80)
Fibroadenoma | 2 (2%) | 5 (6%) | 2 (3%) | 1 (1%)
Skin | (90) | (90) | (90) | (90)
Basal cell adenoma | 1 (1%) | 1 (1%) | – | –
Keratoacanthoma | 5 (6%) | 4 (4%) | 5 (6%) | 4 (4%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Squamous cell carcinoma | – | – | 3 (3%) | –
Squamous cell papilloma | 2 (2%) | 1 (1%) | 3 (3%) | 1 (1%)
Trichoepithelioma | – | – | – | 1 (1%)
Conjunctiva, sarcoma | – | – | 1 (1%) | –
Sebaceous gland, adenoma | 1 (1%) | – | – | 1 (1%)
Subcutaneous tissue, fibroma | 2 (2%) | 11 (12%) | 6 (7%) | 4 (4%)
Subcutaneous tissue, fibroma, multiple | – | – | 1 (1%) | –
Subcutaneous tissue, fibrosarcoma | 1 (1%) | – | 1 (1%) | –
Subcutaneous tissue, hemangiosarcoma | – | 1 (1%) | – | –
Subcutaneous tissue, hibernoma | – | – | 1 (1%) | –
Subcutaneous tissue, lipoma | 2 (2%) | 5 (6%) | 4 (4%) | 1 (1%)
Subcutaneous tissue, malignant fibrous histiocytoma | – | – | – | 1 (1%)
Subcutaneous tissue, myxosarcoma | – | 2 (2%) | – | –
Subcutaneous tissue, myxosarcoma, multiple | – | – | 1 (1%) | –
Subcutaneous tissue, neural crest tumor | – | 1 (1%) | – | –
Subcutaneous tissue, sarcoma | 2 (2%) | – | – | –
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Bone, vertebra | (0) | (0) | (1) | (0)
Skeletal muscle | (90) | (90) | (90) | (90)
Hemangioma | – | 1 (1%) | – | –
Hemangiosarcoma | – | – | 1 (1%) | –
Sarcoma | – | – | – | 1 (1%)
Nervous System
Brain | (90) | (90) | (90) | (90)
Glioma malignant | – | – | – | 3 (3%)
Meningioma benign | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, tissue NOS | – | 1 (1%) | – | 1 (1%)
Schwannoma malignant, metastatic, uncertain primary site | – | 1 (1%) | – | –
Choroid plexus, granular cell tumor benign | – | – | – | 1 (1%)
Meninges, granular cell tumor benign | 1 (1%) | – | 1 (1%) | 1 (1%)
Meninges, granular cell tumor malignant | | 1 (1%) | 1 (1%) | –
Nerve trigeminal | (84) | (90) | (88) | (90)
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Peripheral nerve, tibial | (88) | (90) | (90) | (89)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Trigeminal ganglion | (75) | (77) | (79) | (83)
Schwannoma malignant, metastatic, tissue NOS | – | 1 (1%) | – | –
Respiratory System
Lung | (90) | (90) | (90) | (90)
Alveolar/bronchiolar adenoma | 1 (1%) | 2 (2%) | 1 (1%) | –
Alveolar/bronchiolar carcinoma | – | – | 1 (1%) | –
Carcinoma, metastatic, kidney | – | – | – | 1 (1%)
Carcinoma, metastatic, thyroid gland | – | – | 1 (1%) | –
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (1%)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 2 (2%) | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Schwannoma malignant, metastatic, thymus | – | – | 1 (1%) | –
Nose | (89) | (90) | (90) | (87)
Schwannoma malignant, metastatic, tissue NOS | – | – | – | 1 (1%)
Schwannoma malignant, metastatic, uncertain primary site | 1 (1%) | 1 (1%) | – | –
Trachea | (90) | (88) | (88) | (72)
Special Senses System
Eye | (85) | (83) | (81) | (72)
Schwannoma malignant, metastatic, uncertain primary site | – | 1 (1%) | – | –
Retrobulbar, schwannoma malignant, metastatic, uncertain primary site | 2 (2%) | – | – | –
Harderian gland | (90) | (90) | (90) | (89)
Schwannoma malignant, metastatic, tissue NOS | – | 1 (1%) | – | 1 (1%)
Schwannoma malignant, metastatic, uncertain primary site | 2 (2%) | 1 (1%) | – | –
Lacrimal gland | (2) | (1) | (1) | (1)
Zymbal’s gland | (0) | (0) | (1) | (1)
Adenoma | – | – | 1 (100%) | 1 (100%)
Urinary System
Kidney | (90) | (90) | (90) | (87)
Lipoma | 1 (1%) | 2 (2%) | 1 (1%) | –
Liposarcoma | – | – | 1 (1%) | –
Nephroblastoma | – | – | – | 1 (1%)
Oncocytoma benign | 1 (1%) | – | – | –
Bilateral, renal tubule, adenoma | – | – | 1 (1%) | –
Bilateral, renal tubule, adenoma, multiple | 1 (1%) | – | – | –
Bilateral, renal tubule, carcinoma | 1 (1%) | – | 1 (1%) | –
Pelvis, urothelium, carcinoma | – | – | – | 1 (1%)
Perirenal tissue, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Renal tubule, adenoma | 1 (1%) | 1 (1%) | – | –
Renal tubule, adenoma, multiple | 1 (1%) | – | – | –
Renal tubule, carcinoma | – | – | – | 1 (1%)
Urinary bladder | (89) | (83) | (83) | (78)
Serosa, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (1%)
Systemic Lesions
Multiple organs^b^ | (90) | (90) | (90) | (90)
Histiocytic sarcoma | – | – | – | 1 (1%)
Leukemia mononuclear | – | 2 (2%) | 4 (4%) | 1 (1%)
Lymphoma malignant | 2 (2%) | 2 (2%) | 1 (1%) | 4 (4%)
Mesothelioma malignant | 2 (2%) | 2 (2%) | 3 (3%) | 1 (1%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 56 | 74 | 76 | 63
Total primary neoplasms
Two-year study | 114 | 160 | 193 | 108
Total animals with benign neoplasms
Two-year study | 49 | 66 | 69 | 49
Total benign neoplasms
Two-year study | 87 | 132 | 145 | 71
Total animals with malignant neoplasms
Two-year study | 24^d^ | 26^d^ | 41 | 34
Total malignant neoplasms
Two-year study | 27 | 27 | 48 | 37
Total animals with metastatic neoplasms
Two-year study | 2 | 3 | 5 | 4
Total metastatic neoplasms
Two-year study | 6 | 10 | 6 | 22
Total animals with malignant neoplasms- uncertain primary site
Two-year study | 2 | 1 | – | –
Total animals with uncertain neoplasms- benign or malignant
Two-year study | – | 1 | – | –
Total uncertain neoplasms
Two-year study | – | 1 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

^d^ Includes one animal that had a neoplasm of unknown primary origin.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 10/88 (11%) | 19/90 (21%) | 22/90 (24%) | 13/90 (14%)
Rate per litters^b^ | 8/35 (23%) | 13/35 (37%) | 17/35 (49%) | 12/35 (34%)
Adjusted rate^c^ | 15.2% | 25.4% | 27.8% | 19.1%
Terminal rate^d^ | 3/23 (13%) | 14/43 (33%) | 16/56 (29%) | 9/43 (21%)
First incidence (days) | 510 | 647 | 642 | 497
Rao-Scott adjusted Poly-3 test^e^ | P = 0.440 | P = 0.121 | P = 0.070 | P = 0.363
Litter C-A/Fisher’s test^f^ | P = 0.219 | P = 0.148 | P = 0.022 | P = 0.214
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 11/88 (13%) | 21/90 (23%) | 23/90 (26%) | 14/90 (16%)
Rate per litters | 9/35 (26%) | 15/35 (43%) | 18/35 (51%) | 13/35 (37%)
Adjusted rate | 16.7% | 28.1% | 29.1% | 20.4%
Terminal rate | 3/23 (13%) | 16/43 (37%) | 17/56 (30%) | 9/43 (21%)
First incidence (days) | 510 | 647 | 642 | 497
Rao-Scott adjusted Poly-3 test | P = 0.474 | P = 0.091 | P = 0.070 | P = 0.368
Litter C-A/Fisher’s test | P = 0.251 | P = 0.104 | P = 0.024 | P = 0.220
Heart: Schwannoma Malignant
Overall rate | 0/90 (0%) | 2/90 (2%) | 3/90 (3%) | 6/90 (7%)
Rate per litters | 0/35 (0%) | 2/35 (6%) | 3/35 (9%) | 6/35 (17%)
Adjusted rate | 0% | 2.7% | 3.8% | 8.8%
Terminal rate | 0/25 (0%) | 2/43 (5%) | 2/56 (4%) | 3/43 (7%)
First incidence (days) | –^g^ | 730 (T) | 642 | 488
Rao-Scott adjusted Poly-3 test | P = 0.011 | P = 0.273 | P = 0.175 | P = 0.030
Litter C-A/Fisher’s test | P = 0.006 | P = 0.246 | P = 0.120 | P = 0.012
Mammary Gland: Fibroadenoma
Overall rate | 2/90 (2%) | 5/90 (6%) | 2/90 (2%) | 1/90 (1%)
Rate per litters | 2/35 (6%) | 5/35 (14%) | 2/35 (6%) | 1/35 (3%)
Adjusted rate | 3.0% | 6.7% | 2.6% | 1.5%
Terminal rate | 1/25 (4%) | 4/43 (9%) | 2/56 (4%) | 1/43 (2%)
First incidence (days) | 440 | 550 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.229N | P = 0.271 | P = 0.608N | P = 0.468N
Litter C-A/Fisher’s test | P = 0.219N | P = 0.214 | P = 0.693 | P = 0.500N
Pancreas: Adenoma
Overall rate | 18/90 (20%) | 22/88 (25%) | 26/87 (30%) | 7/78 (9%)
Rate per litters | 16/35 (46%) | 16/35 (46%) | 18/35 (51%) | 7/35 (20%)
Adjusted rate | 26.8% | 29.6% | 33.5% | 11.2%
Terminal rate | 9/25 (36%) | 13/43 (30%) | 20/56 (36%) | 5/43 (12%)
First incidence (days) | 580 | 568 | 577 | 621
Rao-Scott adjusted Poly-3 test | P = 0.034N | P = 0.436 | P = 0.268 | P = 0.035N
Litter C-A/Fisher’s test | P = 0.015N | P = 0.595 | P = 0.406 | P = 0.020N
Pancreas: Adenoma or Carcinoma
Overall rate | 18/90 (20%) | 22/88 (25%) | 27/87 (31%) | 7/78 (9%)
Rate per litters | 16/35 (46%) | 16/35 (46%) | 18/35 (51%) | 7/35 (20%)
Adjusted rate | 26.8% | 29.6% | 34.8% | 11.2%
Terminal rate | 9/25 (36%) | 13/43 (30%) | 21/56 (38%) | 5/43 (12%)
First incidence (days) | 580 | 568 | 577 | 621
Rao-Scott adjusted Poly-3 test | P = 0.037N | P = 0.436 | P = 0.223 | P = 0.035N
Litter C-A/Fisher’s test | P = 0.015N | P = 0.595 | P = 0.406 | P = 0.020N
Pancreatic Islets: Adenoma
Overall rate | 5/90 (6%) | 11/88 (13%) | 8/87 (9%) | 7/79 (9%)
Rate per litters | 5/35 (14%) | 8/35 (23%) | 6/35 (17%) | 7/35 (20%)
Adjusted rate | 7.6% | 15.1% | 10.5% | 11.2%
Terminal rate | 2/25 (8%) | 8/43 (19%) | 7/56 (13%) | 6/43 (14%)
First incidence (days) | 624 | 605 | 726 | 665
Rao-Scott adjusted Poly-3 test | P = 0.458 | P = 0.167 | P = 0.396 | P = 0.364
Litter C-A/Fisher’s test | P = 0.413 | P = 0.270 | P = 0.500 | P = 0.376
Pancreatic Islets: Carcinoma
Overall rate | 8/90 (9%) | 6/88 (7%) | 13/87 (15%) | 6/79 (8%)
Rate per litters | 8/35 (23%) | 6/35 (17%) | 12/35 (34%) | 6/35 (17%)
Adjusted rate | 12.0% | 8.3% | 17.0% | 9.5%
Terminal rate | 3/25 (12%) | 6/43 (14%) | 10/56 (18%) | 3/43 (7%)
First incidence (days) | 663 | 730 (T) | 642 | 582
Rao-Scott adjusted Poly-3 test | P = 0.512N | P = 0.313N | P = 0.268 | P = 0.411N
Litter C-A/Fisher’s test | P = 0.446N | P = 0.383N | P = 0.214 | P = 0.383N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 13/90 (14%) | 17/88 (19%) | 18/87 (21%) | 13/79 (16%)
Rate per litters | 12/35 (34%) | 14/35 (40%) | 14/35 (40%) | 11/35 (31%)
Adjusted rate | 19.4% | 23.3% | 23.5% | 20.6%
Terminal rate | 5/25 (20%) | 14/43 (33%) | 14/56 (25%) | 9/43 (21%)
First incidence (days) | 624 | 605 | 642 | 582
Rao-Scott adjusted Poly-3 test | P = 0.510 | P = 0.357 | P = 0.343 | P = 0.506
Litter C-A/Fisher’s test | P = 0.395N | P = 0.402 | P = 0.402 | P = 0.500N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 17/89 (19%) | 25/90 (28%) | 34/90 (38%) | 13/90 (14%)
Rate per litters | 13/35 (37%) | 18/35 (51%) | 24/35 (69%) | 12/35 (34%)
Adjusted rate | 24.9% | 32.7% | 41.8% | 19.0%
Terminal rate | 5/25 (20%) | 16/43 (37%) | 22/56 (39%) | 6/43 (14%)
First incidence (days) | 527 | 605 | 471 | 567
Rao-Scott adjusted Poly-3 test | P = 0.226N | P = 0.208 | P = 0.030 | P = 0.273N
Litter C-A/Fisher’s test | P = 0.398N | P = 0.168 | P = 0.008 | P = 0.500N
Skin: Keratoacanthoma
Overall rate | 5/90 (6%) | 4/90 (4%) | 5/90 (6%) | 4/90 (4%)
Rate per litters | 5/35 (14%) | 3/35 (9%) | 5/35 (14%) | 3/35 (9%)
Adjusted rate | 7.4% | 5.4% | 6.4% | 6.0%
Terminal rate | 0/25 (0%) | 2/43 (5%) | 4/56 (7%) | 3/43 (7%)
First incidence (days) | 552 | 610 | 726 | 665
Rao-Scott adjusted Poly-3 test | P = 0.477N | P = 0.430N | P = 0.521N | P = 0.490N
Litter C-A/Fisher’s test | P = 0.360N | P = 0.355N | P = 0.633 | P = 0.355N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 7/90 (8%) | 5/90 (6%) | 8/90 (9%) | 5/90 (6%)
Rate per litters | 7/35 (20%) | 4/35 (11%) | 8/35 (23%) | 4/35 (11%)
Adjusted rate | 10.4% | 6.7% | 10.2% | 7.5%
Terminal rate | 1/25 (4%) | 3/43 (7%) | 6/56 (11%) | 4/43 (9%)
First incidence (days) | 552 | 610 | 717 | 665
Rao-Scott adjusted Poly-3 test | P = 0.413N | P = 0.302N | P = 0.577N | P = 0.372N
Litter C-A/Fisher’s test | P = 0.308N | P = 0.256N | P = 0.500 | P = 0.256N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 7/90 (8%) | 5/90 (6%) | 10/90 (11%) | 5/90 (6%)
Rate per litters | 7/35 (20%) | 4/35 (11%) | 10/35 (29%) | 4/35 (11%)
Adjusted rate | 10.4% | 6.7% | 12.8% | 7.5%
Terminal rate | 1/25 (4%) | 3/43 (7%) | 7/56 (13%) | 4/43 (9%)
First incidence (days) | 552 | 610 | 717 | 665
Rao-Scott adjusted Poly-3 test | P = 0.443N | P = 0.297N | P = 0.410 | P = 0.368N
Litter C-A/Fisher’s test | P = 0.341N | P = 0.256N | P = 0.289 | P = 0.256N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Trichoepithelioma, Basal Cell Adenoma or Squamous Cell Carcinoma
Overall rate | 8/90 (9%) | 6/90 (7%) | 10/90 (11%) | 6/90 (7%)
Rate per litters | 8/35 (23%) | 5/35 (14%) | 10/35 (29%) | 5/35 (14%)
Adjusted rate | 11.9% | 8.0% | 12.8% | 9.0%
Terminal rate | 2/25 (8%) | 4/43 (9%) | 7/56 (13%) | 4/43 (9%)
First incidence (days) | 552 | 610 | 717 | 630
Rao-Scott adjusted Poly-3 test | P = 0.430N | P = 0.296N | P = 0.516 | P = 0.371N
Litter C-A/Fisher’s test | P = 0.334N | P = 0.270N | P = 0.393 | P = 0.270N
Skin (Subcutaneous Tissue): Lipoma
Overall rate | 2/90 (2%) | 5/90 (6%) | 4/90 (4%) | 1/90 (1%)
Rate per litters | 2/35 (6%) | 3/35 (9%) | 4/35 (11%) | 1/35 (3%)
Adjusted rate | 3.1% | 6.7% | 5.1% | 1.5%
Terminal rate | 2/25 (8%) | 3/43 (7%) | 3/56 (5%) | 0/43 (0%)
First incidence (days) | 730 (T) | 693 | 726 | 713
Rao-Scott adjusted Poly-3 test | P = 0.331N | P = 0.350 | P = 0.480 | P = 0.536N
Litter C-A/Fisher’s test | P = 0.370N | P = 0.500 | P = 0.337 | P = 0.500N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 2/90 (2%) | 11/90 (12%) | 7/90 (8%) | 4/90 (4%)
Rate per litters | 2/35 (6%) | 11/35 (31%) | 7/35 (20%) | 4/35 (11%)
Adjusted rate | 3.1% | 14.4% | 8.8% | 6.0%
Terminal rate | 2/25 (8%) | 5/43 (12%) | 6/56 (11%) | 2/43 (5%)
First incidence (days) | 730 (T) | 447 | 383 | 665
Rao-Scott adjusted Poly-3 test | P = 0.500N | P = 0.025 | P = 0.143 | P = 0.328
Litter C-A/Fisher’s test | P = 0.500N | P = 0.006 | P = 0.075 | P = 0.337
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, Sarcoma, Myxosarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 5/90 (6%) | 13/90 (14%) | 10/90 (11%) | 5/90 (6%)
Rate per litters | 5/35 (14%) | 12/35 (34%) | 10/35 (29%) | 5/35 (14%)
Adjusted rate | 7.5% | 16.9% | 12.6% | 7.5%
Terminal rate | 2/25 (8%) | 6/43 (14%) | 8/56 (14%) | 3/43 (7%)
First incidence (days) | 567 | 447 | 383 | 665
Rao-Scott adjusted Poly-3 test | P = 0.335N | P = 0.081 | P = 0.236 | P = 0.600N
Litter C-A/Fisher’s test | P = 0.342N | P = 0.046 | P = 0.122 | P = 0.633
Thyroid Gland (C-cell): Adenoma
Overall rate | 8/89 (9%) | 14/87 (16%) | 14/86 (16%) | 11/85 (13%)
Rate per litters | 7/35 (20%) | 13/35 (37%) | 13/34 (38%) | 10/35 (29%)
Adjusted rate | 12.1% | 18.7% | 18.5% | 16.8%
Terminal rate | 6/25 (24%) | 5/43 (12%) | 13/56 (23%) | 8/43 (19%)
First incidence (days) | 498 | 517 | 677 | 582
Rao-Scott adjusted Poly-3 test | P = 0.327 | P = 0.186 | P = 0.194 | P = 0.278
Litter C-A/Fisher’s test | P = 0.363 | P = 0.093 | P = 0.080 | P = 0.289
Thyroid Gland (C-cell): Carcinoma
Overall rate | 2/89 (2%) | 0/87 (0%) | 2/86 (2%) | 4/85 (5%)
Rate per litters | 1/35 (3%) | 0/35 (0%) | 1/34 (3%) | 4/35 (11%)
Adjusted rate | 3.0% | 0% | 2.6% | 6.2%
Terminal rate | 0/25 (0%) | 0/43 (0%) | 2/56 (4%) | 3/43 (7%)
First incidence (days) | 541 | – | 730 (T) | 717
Rao-Scott adjusted Poly-3 test | P = 0.173 | P = 0.339N | P = 0.666N | P = 0.398
Litter C-A/Fisher’s test | P = 0.034 | P = 0.500N | P = 0.746 | P = 0.178
Thyroid Gland (C-cell): Adenoma or Carcinoma
Overall rate | 10/89 (11%) | 14/87 (16%) | 16/86 (19%) | 15/85 (18%)
Rate per litters | 8/35 (23%) | 13/35 (37%) | 13/34 (38%) | 12/35 (34%)
Adjusted rate | 14.9% | 18.7% | 21.1% | 22.9%
Terminal rate | 6/25 (24%) | 5/43 (12%) | 15/56 (27%) | 11/43 (26%)
First incidence (days) | 498 | 517 | 677 | 582
Rao-Scott adjusted Poly-3 test | P = 0.151 | P = 0.351 | P = 0.233 | P = 0.172
Litter C-A/Fisher’s test | P = 0.249 | P = 0.148 | P = 0.130 | P = 0.214
All Organs: Benign Neoplasms
Overall rate | 49/90 (54%) | 66/90 (73%) | 69/90 (77%) | 49/90 (54%)
Rate per litters | 26/35 (74%) | 34/35 (97%) | 35/35 (100%) | 31/35 (89%)
Adjusted rate | 65.3% | 80.2% | 82.3% | 66.4%
Terminal rate | 18/25 (72%) | 37/43 (86%) | 50/56 (89%) | 28/43 (65%)
First incidence (days) | 440 | 447 | 383 | 497
Rao-Scott adjusted Poly-3 test | P = 0.422N | P = 0.036 | P = 0.017 | P = 0.508
Litter C-A/Fisher’s test | P = 0.108 | P = 0.007 | P < 0.001 | P = 0.109
All Organs: Malignant Neoplasms
Overall rate | 24/90 (27%) | 26/90 (29%) | 41/90 (46%) | 34/90 (38%)
Rate per litters | 18/35 (51%) | 20/35 (57%) | 28/35 (80%) | 25/35 (71%)
Adjusted rate | 33.2% | 34.2% | 49.2% | 46.1%
Terminal rate | 5/25 (20%) | 18/43 (42%) | 26/56 (46%) | 17/43 (40%)
First incidence (days) | 212 | 550 | 393 | 153
Rao-Scott adjusted Poly-3 test | P = 0.034 | P = 0.509 | P = 0.031 | P = 0.076
Litter C-A/Fisher’s test | P = 0.030 | P = 0.405 | P = 0.011 | P = 0.070
All Organs: Benign or Malignant Neoplasms
Overall rate | 57/90 (63%) | 75/90 (83%) | 76/90 (84%) | 63/90 (70%)
Rate per litters | 29/35 (83%) | 35/35 (100%) | 35/35 (100%) | 33/35 (94%)
Adjusted rate | 72.8% | 89.2% | 88.0% | 79.7%
Terminal rate | 20/25 (80%) | 41/43 (95%) | 51/56 (91%) | 34/43 (79%)
First incidence (days) | 212 | 447 | 383 | 153
Rao-Scott adjusted Poly-3 test | P = 0.337 | P = 0.009 | P = 0.014 | P = 0.210
Litter C-A/Fisher’s test | P = 0.109 | P = 0.012 | P = 0.012 | P = 0.130

(T) = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, heart, pancreas, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Number of litters with tumor-bearing animals/number of litters examined at site.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ The Litter Cochran-Armitage and Fishers exact tests directly compare the litter incidence rates.

^g^ Not applicable; no neoplasms in animal group.

Table C-3 Historical Incidence of Malignant Schwannoma of the Heart in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 1/50
Indole-3-carbinol (March 2007) | 1/50
Radiofrequency radiation (September 2012) | 0/90
Overall Historical Incidence
Total (%) | 2/240 (0.8%)
Mean ± standard deviation | 1.0% ± 1.2%
Range | 0%–2%

^a^ Data as of November 2017.

Table C-4 Historical Incidence of Malignant Glioma of the Brain in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 2/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50
Radiofrequency radiation (September 2012) | 0/90
Overall Historical Incidence
Total (%) | 2/190 (1.1%)
Mean ± standard deviation | 1.3% ± 2.3%
Range | 0%–4%

^a^ Data as of November 2017; due to differences in sectioning method, indole-3-carbinol was excluded from evaluation of brain lesions.

Table C-5 Historical Incidence of Pituitary Gland (Pars Distalis) Adenoma in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 11/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 14/50
Indole-3-carbinol (March 2007) | 5/50
Radiofrequency radiation (September 2012) | 17/89
Overall Historical Incidence
Total (%) | 47/239 (19.7%)
Mean ± standard deviation | 19.8% ± 7.5%
Range | 10%-28%

^a^ Data as of November 2017.

Table C-6 Historical Incidence of Hepatocellular Neoplasms in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50 | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50 | 0/50 | 0/50
Indole-3-carbinol (March 2007) | 1/50 | 0/50 | 1/50
Radiofrequency radiation (September 2012) | 0/90 | 0/90 | 0/90
Overall Historical Incidence
Total (%) | 1/240 (0.4%) | 0/240 | 1/240 (0.4%)
Mean ± standard deviation | 0.5% ± 1.0% | – | 0.5% ± 1.0%
Range | 0%-2% | – | 0%-2%

^a^ Data as of November 2017.

Table C-7 Summary of the Incidence of Non-neoplastic Lesions in Male Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1 | – | – | –
Moribund | 44 | 24 | 13 | 6
Natural deaths | 20 | 23 | 21 | 41
Survivors
Died last week of study | – | – | 1 | –
Terminal euthanasia | 25 | 43 | 55 | 43
Animals examined microscopically | 100 | 100 | 100 | 100
Fourteen-week Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (9) | (10)
Intestine large, cecum | (10) | (10) | (9) | (10)
Intestine large, colon | (10) | (10) | (9) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Lymphoid tissue, hyperplasia | 1 (10%) | 1 (10%) | – | 1 (10%)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (9) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Hepatodiaphragmatic nodule | – | – | 1 (10%) | –
Infiltration cellular, mixed cell | 1 (10%) | 1 (10%) | 1 (10%) | 3 (30%)
Hepatocyte, necrosis | – | – | 1 (10%) | –
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (9) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Cardiovascular System
Aorta | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | 2 (20%) | – | 3(30%) | 6 (60%)
Artery, inflammation, chronic active | – | 1 (10%) | 1 (10%) | –
Ventricle right, cardiomyopathy | 1 (10%) | 5 (50%) | 4 (40%) | 4 (40%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (9) | (9) | (9) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Pars intermedia, cyst | – | 1 (10%) | – | 2 (20%)
Rathke’s cleft, cyst | – | 1 (10%) | 1 (10%) | –
Thyroid gland | (10) | (10) | (9) | (10)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Granuloma sperm | – | – | 1 (10%) | –
Hypospermia | – | – | – | 1 (10%)
Preputial gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 7 (70%) | 3 (30%) | 6 (60%) | 3 (30%)
Prostate | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Seminal vesicle | (10) | (10) | (10) | (10)
Testis | (10) | (10) | (10) | (10)
Germ cell, degeneration | – | – | – | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (10) | (9) | (10)
Lymph node | (0) | (0) | (1) | (0)
Inguinal, pigment | – | – | 1 (100%) | –
Lymph node, mandibular | (10) | (10) | (9) | (10)
Hemorrhage | 2 (20%) | 1 (10%) | – | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (9) | (10)
Hemorrhage | – | – | – | 1 (10%)
Spleen | (10) | (10) | (9) | (10)
Thymus | (10) | (10) | (10) | (10)
Hemorrhage | 5 (50%) | 3 (30%) | 4 (40%) | 2 (20%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | – | 1 (10%) | – | 1 (10%)
Inflammation, chronic active | 1 (10%) | – | 1 (10%) | 1 (10%)
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (9) | (10)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Retina, developmental malformation | – | 1 (10%) | – | –
Harderian gland | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | 1 (10%) | – | –
Inflammation, chronic active | – | 1 (10%) | 3 (30%) | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Congestion | – | – | 2 (20%) | –
Nephropathy, chronic progressive | 9 (90%) | 7 (70%) | 8 (80%) | 9 (90%)
Pelvis, dilation | – | – | – | 1 (10%)
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined with No Lesions Observed
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Dilation | 2 (2%) | – | – | –
Hyperplasia | 1 (1%) | – | – | –
Intestine large, cecum | (75) | (76) | (74) | (68)
Edema | 11 (15%) | – | – | –
Erosion | 10 (13%) | 1 (1%) | 1 (1%) | 1 (1%)
Hemorrhage | – | 1 (1%) | – | –
Inflammation, acute | 10 (13%) | 1 (1%) | – | 1 (1%)
Inflammation, chronic active | 1 (1%) | 1 (1%) | – | –
Necrosis | – | – | 1 (1%) | –
Ulcer | 6 (8%) | – | – | –
Artery, inflammation, chronic active | 20 (27%) | 8 (11%) | 7 (9%) | 2 (3%)
Artery, mineral | 1 (1%) | – | – | –
Artery, thrombus | – | – | 1 (1%) | –
Epithelium, regeneration | 14 (19%) | 1 (1%) | – | 1 (1%)
Intestine large, colon | (81) | (83) | (82) | (76)
Cyst | – | 1 (1%) | – | –
Erosion | 1 (1%) | 1 (1%) | – | –
Inflammation, acute | 1 (1%) | – | – | –
Ulcer | 1 (1%) | – | – | –
Artery, inflammation, chronic active | 12 (15%) | 4 (5%) | 5 (6%) | 1 (1%)
Artery, mineral | 2 (2%) | – | – | –
Epithelium, regeneration | 5 (6%) | – | – | –
Intestine large, rectum | (83) | (81) | (80) | (76)
Edema | 1 (1%) | – | – | –
Erosion | 1 (1%) | – | – | –
Hyperplasia, lymphocyte | 1 (1%) | – | – | –
Inflammation, acute | 2 (2%) | – | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Artery, inflammation, chronic active | 4 (5%) | 1 (1%) | 1 (1%) | 1 (1%)
Epithelium, regeneration | 3 (4%) | – | – | –
Intestine small, duodenum | (81) | (84) | (83) | (66)
Dilation | – | 1 (1%) | – | –
Ectopic tissue | – | 1 (1%) | – | –
Erosion | 1 (1%) | – | – | –
Ulcer | 1 (1%) | 1 (1%) | – | –
Artery, inflammation, chronic active | – | – | 3 (4%) | –
Intestine small, ileum | (78) | (76) | (77) | (63)
Congestion | – | 1 (1%) | – | –
Hemorrhage | – | – | 1 (1%) | –
Inflammation, acute | – | 1 (1%) | – | –
Artery, inflammation, chronic active | 2 (3%) | – | 1 (1%) | –
Epithelium, regeneration | 1 (1%) | – | – | –
Intestine small, jejunum | (73) | (73) | (75) | (62)
Artery, inflammation, chronic active | – | – | 1 (1%) | –
Liver | (90) | (90) | (89) | (88)
Angiectasis | 1 (1%) | 1 (1%) | – | 1 (1%)
Basophilic focus | 1 (1%) | – | 2 (2%) | –
Clear cell focus | 8 (9%) | 4 (4%) | 5 (6%) | 5 (6%)
Eosinophilic focus | 12 (13%) | 5 (6%) | 11 (12%) | 4 (5%)
Extramedullary hematopoiesis | 5 (6%) | 4 (4%) | 3 (3%) | 1 (1%)
Hepatodiaphragmatic nodule | 1 (1%) | 1 (1%) | – | 1 (1%)
Infiltration cellular, mixed cell | 3 (3%) | 1 (1%) | 3 (3%) | 2 (2%)
Mixed cell focus | 32 (36%) | 51 (57%) | 47 (53%) | 37 (42%)
Artery, inflammation, chronic active | 2 (2%) | 1 (1%) | – | –
Artery, mineral | 1 (1%) | 1 (1%) | – | –
Bile duct, cyst | 3 (3%) | 5 (6%) | 2 (2%) | 1 (1%)
Bile duct, fibrosis | – | – | – | 1 (1%)
Bile duct, hyperplasia | 41 (46%) | 33 (37%) | 26 (29%) | 14 (16%)
Hepatocyte, degeneration | 1 (1%) | – | 1 (1%) | 1 (1%)
Hepatocyte, necrosis | 5 (6%) | 6 (7%) | 6 (7%) | 6 (7%)
Hepatocyte, vacuolation, cytoplasmic | 6 (7%) | 6 (7%) | 7 (8%) | 7 (8%)
Kupffer cell, pigment | 1 (1%) | – | – | –
Periductal, cholangiofibrosis | 2 (2%) | 2 (2%) | 2 (2%) | –
Mesentery | (39) | (19) | (17) | (6)
Fibrosis | – | 1 (5%) | –
Hemorrhage | 1 (3%) | – | – | 1 (17%)
Inflammation, chronic | 2 (5%) | – | – | –
Necrosis | 2 (5%) | 1 (5%) | 1 (6%) | 1 (17%)
Neovascularization | 1 (3%) | 2 (11%) | 3 (18%) | –
Artery, inflammation, chronic active | 32 (82%) | 16 (84%) | 13 (76%) | 3 (50%)
Artery, mineral | 21 (54%) | 5 (26%) | 2 (12%) | –
Vein, degeneration | 1 (3%) | – | – | –
Vein, inflammation, chronic active | 1 (3%) | 2 (11%) | 1 (6%) | –
Oral mucosa | (0) | (1) | (1) | (0)
Ulcer | – | 1 (100%) | – | –
Pancreas | (90) | (88) | (87) | (78)
Cyst | 1 (1%) | – | – | 1 (1%)
Inflammation, chronic active | – | 1 (1%) | – | –
Thrombus | 1 (1%) | 1 (1%) | – | –
Acinus, atrophy | 13 (14%) | 9 (10%) | 10 (11%) | 8 (10%)
Acinus, hyperplasia | 63 (70%) | 55 (63%) | 49 (56%) | 28 (36%)
Artery, inflammation, chronic active | 48 (53%) | 28 (32%) | 23 (26%) | 5 (6%)
Artery, mineral | 11 (12%) | 2 (2%) | – | –
Duct, crystals | – | – | 1 (1%) | –
Duct, inflammation, acute | – | – | 1 (1%) | –
Salivary glands | (90) | (90) | (90) | (86)
Artery, inflammation, chronic active | 11 (12%) | 6 (7%) | 2 (2%) | 1 (1%)
Artery, mineral | 2 (2%) | 1 (1%) | 1 (1%) | –
Duct, parotid gland, dilation | 5 (6%) | 1 (1%) | 1 (1%) | –
Duct, parotid gland, inflammation, acute | 1 (1%) | 1 (1%) | – | –
Parotid gland, atrophy | 18 (20%) | 15 (17%) | 8 (9%) | 3 (3%)
Parotid gland, inflammation, acute | 2 (2%) | 4 (4%) | 2 (2%)
Parotid gland, vacuolation, cytoplasmic | 1 (1%) | 2 (2%) | – | –
Sublingual gland, atrophy | – | – | 1 (1%) | 1 (1%)
Sublingual gland, mineral | – | – | – | 1 (1%)
Submandibular gland, atrophy | – | 2 (2%) | – | –
Stomach, forestomach | (90) | (90) | (89) | (90)
Cyst | – | 1 (1%) | – | –
Edema | 5 (6%) | 5 (6%) | 1 (1%) | 1 (1%)
Erosion | – | 1 (1%) | – | –
Inflammation, acute | 1 (1%) | 1 (1%) | 1 (1%) | –
Inflammation, chronic | – | – | – | 1 (1%)
Inflammation, chronic active | 7 (8%) | 4 (4%) | 10 (11%) | 1 (1%)
Mineral | 1 (1%) | 1 (1%) | – | –
Ulcer | 6 (7%) | 8 (9%) | 4 (4%) | 1 (1%)
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Epithelium, hyperplasia | 11 (12%) | 17 (19%) | 11 (12%) | 6 (7%)
Epithelium, hyperplasia, atypical | 1 (1%) | – | – | –
Epithelium, hyperplasia, basal cell | – | – | 1 (1%) | 1 (1%)
Erosion | 3(3%) | 2 (2%) | 3 (4%) | –
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic active | 1 (1%) | – | – | –
Mineral | 31 (36%) | 9 (10%) | 6 (7%) | 1 (1%)
Necrosis | – | – | 3 (4%) | –
Artery, inflammation, chronic active | 3 (3%) | – | – | –
Artery, mineral | – | – | 1 (1%) | –
Epithelium, hyperplasia, focal | – | – | – | 1 (1%)
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Dilation | – | 5 (6%) | 1 (1%) | –
Mineral | 30 (33%) | 8 (9%) | 6 (7%) | 2 (2%)
Blood vessel | (1) | (2) | (1) | (0)
Inflammation, chronic active | – | – | 1 (100%) | –
Mineral | 1 (100%) | – | – | –
Pulmonary artery, mineral | – | 1 (50%) | – | –
Pulmonary artery, necrosis | – | 1 (50%) | – | –
Heart | (90) | (90) | (90) | (90)
Cardiomyopathy | 79 (88%) | 84 (93%) | 83 (92%) | 85 (94%)
Congestion | 1 (1%) | – | – | –
Hemorrhage | – | – | – | 1 (1%)
Inflammation, suppurative | – | – | 1 (1%) | –
Thrombus | 1 (1%) | – | 3 (3%) | –
Artery, degeneration | – | 1 (1%) | – | –
Artery, inflammation, chronic active | – | – | 2 (2%) | –
Artery, mineral | 20 (22%) | 7 (8%) | 2 (2%) | 1 (1%)
Artery, pericardium, inflammation, chronic active | – | – | – | 1 (1%)
Artery, pericardium, pigment | – | 1 (1%) | – | –
Atrium, dilation | 3 (3%) | 1 (1%) | – | 4 (4%)
Atrium, thrombus | 1 (1%) | 5 (6%) | – | 1 (1%)
Atrium, myocardium, hypertrophy | 1 (1%) | 1 (1%) | – | 1 (1%)
Atrium, myocardium, necrosis | – | 1 (1%) | – | –
Atrium left, mineral | – | – | 1 (1%) | –
Endocardium, hyperplasia, Schwann cell | – | – | – | 3 (3%)
Myocardium, mineral | 9 (10%) | 2 (2%) | 1 (1%) | –
Myocardium, necrosis | 1 (1%) | 1 (1%) | – | 1 (1%)
Pericardium, hemorrhage | – | – | 1 (1%) | –
Valve, inflammation, chronic active | 1 (1%) | – | – | –
Ventricle right, cardiomyopathy | 54 (60%) | 45 (50%) | 62 (69%) | 74 (82%)
Ventricle right, dilation | – | – | 1 (1%) | –
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (89)
Accessory adrenal cortical nodule | 6 (7%) | 4 (4%) | 7 (8%) | 7 (8%)
Angiectasis | – | 1 (1%) | – | –
Atrophy | – | 1 (1%) | – | 1 (1%)
Degeneration | 3 (3%) | 1 (1%) | 1 (1%) | 2 (2%)
Degeneration, cystic | – | 3 (3%) | – | 1 (1%)
Extramedullary hematopoiesis | – | – | 1 (1%) | –
Hyperplasia | 47 (52%) | 42 (47%) | 45 (50%) | 44 (49%)
Hypertrophy | 35 (39%) | 42 (47%) | 55 (61%) | 44 (49%)
Necrosis | 5 (6%) | 5 (6%) | 1 (1%) | 1 (1%)
Pigment | – | – | – | 1 (1%)
Thrombus | 2 (2%) | 2 (2%) | 1 (1%) | –
Vacuolation, cytoplasmic | 20 (22%) | 18 (20%) | 21 (23%) | 12 (13%)
Adrenal medulla | (88) | (90) | (90) | (90)
Hyperplasia | 42 (48%) | 34 (38%) | 32 (36%) | 21 (23%)
Thrombus | 1 (1%) | – | – | –
Islets, pancreatic | (90) | (88) | (87) | (79)
Hyperplasia | 12 (13%) | 15 (17%) | 13 (15%) | 12 (15%)
Parathyroid gland | (83) | (83) | (83) | (82)
Fibrosis | – | – | 3 (4%) | –
Hyperplasia | 51 (61%) | 35 (42%) | 32 (39%) | 17 (21%)
Hyperplasia, focal | – | 1 (1%) | – | –
Pituitary gland | (89) | (90) | (90) | (90)
Craniopharyngeal duct, cyst | 1 (1%) | – | – | 1 (1%)
Pars distalis, angiectasis | – | – | – | 1 (1%)
Pars distalis, atrophy | – | – | – | 1 (1%)
Pars distalis, cyst | 5 (6%) | 15 (17%) | 7 (8%) | 6 (7%)
Pars distalis, hyperplasia | 32 (36%) | 32 (36%) | 34 (38%) | 27 (30%)
Pars distalis, necrosis | – | 1 (1%) | – | –
Pars intermedia, angiectasis | 1 (1%) | 1 (1%) | – | –
Pars intermedia, cyst | 6 (7%) | 1 (1%) | 5 (6%) | 7 (8%)
Pars intermedia, hyperplasia | 1 (1%) | 3 (3%) | – | 2 (2%)
Pars nervosa, cyst | – | 1 (1%) | – | –
Thyroid gland | (89) | (87) | (86) | (85)
C-cell, hyperplasia | 16 (18%) | 17 (20%) | 17 (20%) | 22 (26%)
Follicle, cyst | – | 2 (2%) | – | 1 (1%)
Follicle, hyperplasia, cystic | 1 (1%) | – | – | –
General Body System
Tissue NOS | (3) | (1) | (3) | (3)
Abdominal, fat, hemorrhage | 1 (33%) | – | – | –
Fat, hemorrhage | – | – | 1 (33%) | –
Fat, necrosis | 2 (67%) | – | 1 (33%) | 1 (33%)
Genital System
Bulbourethral gland | (1) | (1) | (0) | (0)
Coagulating gland | (0) | (2) | (3) | (0)
Inflammation, suppurative | – | – | 1 (33%) | –
Inflammation, chronic active | – | 2 (100%) | 2 (67%) | –
Ductus deferens | (1) | (0) | (1) | (0)
Granuloma | 1 (100%) | – | – | –
Epididymis | (90) | (90) | (90) | (90)
Exfoliated germ cell | 51 (57%) | 33 (37%) | 33 (37%) | 17 (19%)
Granuloma sperm | 1 (1%) | 1 (1%) | – | –
Hypospermia | 28 (31%) | 24 (27%) | 13 (14%) | 13 (14%)
Inflammation, chronic | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | 1 (1%) | –
Artery, inflammation, chronic active | 2 (2%) | 3 (3%) | 3 (3%) | 3 (3%)
Artery, thrombus | – | – | – | 1 (1%)
Tail, developmental malformation | – | 1 (1%) | – | –
Penis | (0) | (4) | (2) | (1)
Concretion | – | 3 (75%) | 2 (100%) | 1 (100%)
Prolapse | – | 1 (25%) | – | –
Preputial gland | (88) | (88) | (89) | (89)
Atrophy | 1 (1%) | 1 (1%) | – | –
Fibrosis | – | – | 2 (2%) | –
Hyperplasia | 1 (1%) | – | – | –
Inflammation, suppurative | | 1 (1%) | – | –
Inflammation, granulomatous | 1 (1%) | – | – | –
Inflammation, acute | 1 (1%) | – | – | 1 (1%)
Inflammation, chronic active | 46 (52%) | 53 (60%) | 46 (52%) | 49 (55%)
Metaplasia, squamous | – | – | 1 (1%) | –
Artery, inflammation, chronic active | 1 (1%) | – | – | –
Duct, dilation | 51 (58%) | 54 (61%) | 50 (56%) | 48 (54%)
Duct, hyperplasia | – | 1 (1%) | – | 1 (1%)
Prostate | (90) | (90) | (90) | (85)
Decreased secretory fluid | 4 (4%) | 5 (6%) | 7 (8%) | 3 (4%)
Hemorrhage | 1 (1%) | – | 1 (1%) | –
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | 1 (1%)
Inflammation, acute | 7 (8%) | 9 (10%) | 4 (4%) | 2 (2%)
Inflammation, chronic active | 6 (7%) | 10 (11%) | 10 (11%) | 5 (6%)
Artery, inflammation, chronic active | 1 (1%) | – | 3 (3%) | –
Artery, thrombus | – | 1 (1%) | – | –
Epithelium, hyperplasia | 5 (6%) | 11 (12%) | 9 (10%) | 15 (18%)
Seminal vesicle | (90) | (90) | (90) | (90)
Decreased secretory fluid | 35 (39%) | 34 (38%) | 18 (20%) | 7 (8%)
Developmental malformation | – | – | 1 (1%) | –
Dilation | – | – | 1 (1%) | –
Hemorrhage | 1 (1%) | – | 1 (1%) | –
Hyperplasia, atypical | – | – | – | 1 (1%)
Inflammation, acute | 4 (4%) | 1 (1%) | 3 (3%) | 1 (1%)
Inflammation, chronic active | 1 (1%) | 4 (4%) | – | –
Artery, inflammation, chronic active | 1 (1%) | – | – | –
Epithelium, hyperplasia | 1 (1%) | – | – | –
Lumen, hemorrhage | – | – | 1 (1%)
Testis | (90) | (89) | (90) | (90)
Cyst | 1 (1%) | – | – | –
Edema | – | 2 (2%) | – | –
Inflammation, chronic active | 2 (2%) | – | – | –
Pigment | 1 (1%) | – | – | –
Artery, inflammation, chronic active | 52 (58%) | 37 (42%) | 30 (33%) | 12 (13%)
Germ cell, degeneration | 51 (57%) | 37 (42%) | 31 (34%) | 24 (27%)
Germinal epithelium, mineral | – | 1 (1%) | – | –
Interstitial cell, hyperplasia | 1 (1%) | 2 (2%) | – | 1 (1%)
Rete testis, dilation | 1 (1%) | – | – | –
Seminiferous tubule, dilation | 1 (1%) | 1 (1%) | 1 (1%) | –
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Hemorrhage | – | 5 (6%) | 3 (3%) | –
Hypercellularity | 15 (17%) | 25 (28%) | 18 (20%) | 13 (14%)
Hypocellularity | – | – | 1 (1%) | 1 (1%)
Lymph node | (25) | (23) | (24) | (16)
Bronchial, erythrophagocytosis | – | 2 (9%) | – | –
Bronchial, hyperplasia, lymphocyte | – | 1 (4%) | – | –
Iliac, erythrophagocytosis | 2 (8%) | 2 (9%) | 1 (4%) | –
Iliac, hyperplasia, lymphocyte | 2 (8%) | – | 2 (8%) | –
Iliac, infiltration cellular, histiocyte | 2 (8%) | 1 (4%) | – | –
Iliac, pigment | – | – | 1 (4%) | –
Iliac, proliferation, plasma cell | 3 (12%) | – | 1 (4%) | –
Iliac, lymphatic sinus, ectasia | 5 (20%) | 3 (13%) | 1 (4%) | –
Inguinal, hyperplasia, lymphocyte | – | – | 1 (4%) | –
Inguinal, lymphatic sinus, ectasia | – | – | 1 (4%) | –
Lumbar, erythrophagocytosis | 2 (8%) | 2 (9%) | 1 (4%) | 1 (6%)
Lumbar, proliferation, plasma cell | – | 1 (4%) | – | –
Lumbar, lymphatic sinus, ectasia | – | 2 (9%) | 1 (4%) | 2 (13%)
Lymphatic sinus, mediastinal, ectasia | 1 (4%) | 1 (4%) | 1 (4%) | 1 (6%)
Lymphatic sinus, popliteal, ectasia | – | 1 (4%) | – | –
Lymphatic sinus, renal, ectasia | – | 4 (17%) | 3 (13%) | –
Mediastinal, erythrophagocytosis | 6 (24%) | 7 (30%) | 7 (29%) | 3 (19%)
Mediastinal, extramedullary hematopoiesis | – | – | 1 (4%) | –
Mediastinal, hemorrhage | 1 (4%) | 1 (4%) | 1 (4%) | 1 (6%)
Mediastinal, hyperplasia, lymphocyte | – | – | 1 (4%) | –
Mediastinal, infiltration cellular, histiocyte | – | 1 (4%) | 1 (4%) | –
Mediastinal, inflammation, acute | – | 1 (4%) | – | –
Mediastinal, pigment | – | 1 (4%) | – | –
Mediastinal, proliferation, plasma cell | – | – | 1 (4%) | –
Pancreatic, erythrophagocytosis | 3 (12%) | 1 (4%) | 4 (17%) | 3 (19%)
Pancreatic, hemorrhage | 1 (4%) | – | – | –
Pancreatic, hyperplasia, lymphocyte | 1 (4%) | – | – | –
Pancreatic, infiltration cellular, mixed cell | – | – | – | 1 (6%)
Renal, erythrophagocytosis | 8 (32%) | 6 (26%) | 4 (17%)
Renal, hyperplasia, lymphocyte | – | 1 (4%) | – | –
Renal, infiltration cellular, mixed cell | – | – | – | 1 (6%)
Renal, proliferation, plasma cell | 2 (8%) | – | – | –
Lymph node, mandibular | (89) | (90) | (90) | (88)
Congestion | – | 1 (1%) | 2 (2%) | –
Erythrophagocytosis | – | 3 (3%) | 2 (2%) | 1 (1%)
Hemorrhage | – | – | 1 (1%) | –
Hyperplasia, lymphocyte | 41 (46%) | 50 (56%) | 52 (58%) | 40 (45%)
Infiltration cellular, histiocyte | – | 2 (2%) | – | 1 (1%)
Infiltration cellular, polymorphonuclear | 2 (2%) | – | – | –
Necrosis, lymphocyte | – | 1 (1%) | – | –
Proliferation, plasma cell | 49 (55%) | 61 (68%) | 62 (69%) | 57 (65%)
Lymphatic sinus, ectasia | 16 (18%) | 24 (27%) | 29 (32%) | 14 (16%)
Lymph node, mesenteric | (90) | (89) | (88) | (88)
Erythrophagocytosis | 17 (19%) | 5 (6%) | 5 (6%) | 9 (10%)
Hyperplasia, lymphocyte | 2 (2%) | 3 (3%) | 3 (3%) | 3 (3%)
Infiltration cellular, histiocyte | 1 (1%) | – | – | –
Infiltration cellular, polymorphonuclear | 2 (2%) | – | – | 1 (1%)
Proliferation, plasma cell | – | 1 (1%) | – | –
Lymphatic sinus, ectasia | – | 2 (2%) | 3 (3%) | 1 (1%)
Lymphocyte, depletion | 2 (2%) | – | – | –
Spleen | (90) | (90) | (90) | (85)
Congestion | – | – | 1 (1%) | –
Developmental malformation | 1 (1%) | – | – | –
Extramedullary hematopoiesis | 45 (50%) | 60 (67%) | 56 (62%) | 48 (56%)
Hemorrhage | – | 1 (1%) | 1 (1%) | –
Hyperplasia, lymphocyte | 5 (6%) | – | – | –
Necrosis | – | – | 2 (2%) | –
Pigment | 57 (63%) | 54 (60%) | 64 (71%) | 63 (74%)
Thrombus | – | 1 (1%) | – | –
Arteriole, mineral | 1 (1%) | – | – | –
Red pulp, atrophy | 26 (29%) | 14 (16%) | 12 (13%) | 13 (15%)
White pulp, atrophy | 30 (33%) | 11 (12%) | 10 (11%) | 24 (28%)
Thymus | (88) | (85) | (87) | (82)
Atrophy | 79 (90%) | 76 (89%) | 80 (92%) | 65 (79%)
Cyst | 10 (11%) | 10 (12%) | 10 (11%) | 17 (21%)
Ectopic parathyroid gland | 6 (7%) | 6 (7%) | 7 (8%) | 5 (6%)
Ectopic thyroid | 1 (1%) | – | – | –
Hemorrhage | 2 (2%) | 2 (2%) | 2 (2%) | 20 (24%)
Hyperplasia, epithelial | 2 (2%) | 2 (2%) | 4 (5%) | 4 (5%)
Artery, inflammation, chronic active | 6 (7%) | 3 (4%) | 2 (2%) | 1 (1%)
Integumentary System
Mammary gland | (82) | (77) | (80) | (80)
Atrophy | 1 (1%) | 2 (3%) | 3 (4%) | –
Galactocele | 1 (1%) | 1 (1%) | 2 (3%) | –
Duct, dilation | 3 (4%) | 8 (10%) | 9 (11%) | 3 (4%)
Skin | (90) | (90) | (90) | (90)
Cyst epithelial inclusion | 3 (3%) | 12 (13%) | 3 (3%) | 2 (2%)
Inflammation, suppurative | – | 2 (2%) | – | –
Inflammation, chronic active | 1 (1%) | 2 (2%) | 2 (2%) | 1 (1%)
Ulcer | 2 (2%) | 2 (2%) | 4 (4%) | –
Adnexa, atrophy | – | – | – | 1 (1%)
Artery, subcutaneous tissue, inflammation, chronic active | 1 (1%) | – | – | –
Dermis, fibrosis | – | – | – | 1 (1%)
Epidermis, hyperplasia | 1 (1%) | 1 (1%) | – | 1 (1%)
Hair follicle, congestion | – | – | – | 1 (1%)
Hair follicle, degeneration | – | – | 1 (1%) | –
Prepuce, hyperplasia | – | 2 (2%) | – | 1 (1%)
Prepuce, inflammation, acute | – | – | – | 1 (1%)
Prepuce, inflammation, chronic active | – | 1 (1%) | – | –
Prepuce, ulcer | – | 2 (2%) | – | 1 (1%)
Subcutaneous tissue, hemorrhage | – | 1 (1%) | – | –
Subcutaneous tissue, inflammation, suppurative | 1 (1%) | – | 1 (1%) | 2 (2%)
Subcutaneous tissue, inflammation, chronic | 1 (1%) | – | 1 (1%) | –
Subcutaneous tissue, inflammation, chronic active | – | – | 2 (2%) | –
Subcutaneous tissue, necrosis | – | – | 1 (1%) | –
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Fibrous osteodystrophy | 46 (51%) | 20 (22%) | 15 (17%) | 5 (6%)
Cranium, inflammation, chronic active | – | – | 1 (1%) | –
Bone, vertebra | (0) | (0) | (1) | (0)
Developmental malformation | – | – | 1 (100%) | –
Skeletal muscle | (90) | (90) | (90) | (90)
Degeneration | 34 (38%) | 35 (39%) | 30 (33%) | 26 (29%)
Inflammation, chronic active | – | – | 1 (1%) | –
Mineral | 2 (2%) | – | 1 (1%) | –
Diaphragm, hernia | – | 1 (1%) | – | –
Nervous System
Brain | (90) | (90) | (90) | (90)
Compression | 7 (8%) | 12 (13%) | 6 (7%) | 3 (3%)
Edema | – | 1 (1%) | – | –
Hemorrhage | 2 (2%) | 3 (3%) | – | –
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Inflammation, suppurative | – | – | 1 (1%) | –
Mineral | 5 (6%) | 3 (3%) | 4 (4%) | 4 (4%)
Necrosis | 7 (8%) | 7 (8%) | 3 (3%) | –
Choroid plexus, degeneration | 1 (1%) | – | – | –
Choroid plexus, mineral | 3 (3%) | 1 (1%) | – | –
Glial cell, hyperplasia | – | 2 (2%) | – | 2 (2%)
Hypothalamus, cyst | – | 3 (3%) | – | –
Meninges, fibrosis | – | 1 (1%) | – | –
Meninges, hyperplasia | 1 (1%) | – | 1 (1%) | –
Meninges, hyperplasia, granular cell | 1 (1%) | 1 (1%) | – | –
Meninges, mineral | – | 1 (1%) | – | –
Pineal gland, mineral | 3 (3%) | 3 (3%) | 2(2%) | –
Pineal gland, vacuolation, cytoplasmic | 12 (13%) | 6 (7%) | 9 (10%) | 4 (4%)
Nerve trigeminal | (84) | (90) | (88) | (90)
Degeneration | 63 (75%) | 66 (73%) | 67 (76%) | 49 (54%)
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Degeneration | 86 (96%) | 90 (100%) | 88 (98%) | 84 (93%)
Infiltration cellular, histiocyte | – | – | 1 (1%) | –
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Peripheral nerve, tibial | (88) | (90) | (90) | (89)
Degeneration | 84 (95%) | 90 (100%) | 89 (99%) | 81 (91%)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Degeneration | 30 (33%) | 36 (40%) | 42 (47%) | 35 (39%)
Meninges, inflammation, suppurative | – | – | 1 (1%) | –
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Degeneration | 21 (23%) | 15 (17%) | 21 (23%) | 24 (27%)
Nerve, degeneration | 79 (88%) | 85 (94%) | 83 (92%) | 76 (84%)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Degeneration | 58 (64%) | 69 (77%) | 74 (82%) | 62 (69%)
Hemorrhage, focal | 1 (1%) | – | – | –
Meninges, inflammation, suppurative | – | – | 1 (1%) | –
Trigeminal ganglion | (75) | (77) | (79) | (83)
Degeneration | 23 (31%) | 22 (29%) | 21 (27%) | 16 (19%)
Respiratory System
Lung | (90) | (90) | (90) | (90)
Congestion | 13 (14%) | 13 (14%) | 11 (12%) | 33 (37%)
Foreign body | 4 (4%) | 2 (2%) | 1 (1%) | 1 (1%)
Hemorrhage | 3 (3%) | 5 (6%) | 2 (2%) | 4 (4%)
Inflammation, suppurative | 3 (3%) | – | 1 (1%) | 2 (2%)
Inflammation, granulomatous | – | 6 (7%) | 1 (1%) | –
Inflammation, chronic | – | 1 (1%) | 1 (1%) | –
Inflammation, chronic active | 2 (2%) | 1 (1%) | 1 (1%) | –
Inflammation, subacute | 2 (2%) | – | – | –
Metaplasia, osseous | – | – | 1 (1%) | –
Alveolus, infiltration cellular, histiocyte | 37 (41%) | 38 (42%) | 42 (47%) | 47 (52%)
Artery, inflammation, chronic active | 3 (3%) | 3 (3%) | 1 (1%) | –
Artery, mineral | 1 (1%) | – | – | –
Artery, mediastinum, inflammation, chronic active | 2 (2%) | – | – | –
Epithelium alveolus, hyperplasia | 3 (3%) | 2 (2%) | 1 (1%) | 1 (1%)
Interstitium, inflammation, chronic | – | 5 (6%) | – | –
Interstitium, inflammation, chronic active | – | 1 (1%) | – | –
Interstitium, mineral | 1 (1%) | 1 (1%) | 1 (1%) | –
Mediastinum, inflammation, suppurative | – | – | 1 (1%) | –
Perivascular, infiltration cellular, lymphocyte | – | – | 1 (1%) | –
Perivascular, inflammation, chronic active | 1 (1%) | – | – | –
Nose | (89) | (90) | (90) | (87)
Foreign body | 5 (6%) | 2 (2%) | 3 (3%) | 8 (9%)
Hyperplasia, lymphocyte | – | 1 (1%) | – | –
Inflammation, suppurative | 10 (11%) | 6 (7%) | 10 (11%) | 17 (20%)
Inflammation, chronic active | – | – | – | 2 (2%)
Mineral | – | – | – | 1 (1%)
Nasopharyngeal duct, respiratory epithelium, hyperplasia | 1 (1%) | – | – | –
Olfactory epithelium, accumulation, hyaline droplet | 79 (89%) | 88 (98%) | 90 (100%) | 76 (87%)
Olfactory epithelium, hyperplasia | – | 1 (1%) | – | –
Olfactory epithelium, metaplasia, respiratory | 3 (3%) | 2 (2%) | 1 (1%) | 4 (5%)
Respiratory epithelium, accumulation, hyaline droplet | 3 (3%) | 1 (1%) | 2 (2%) | 3 (3%)
Respiratory epithelium, hyperplasia | 3 (3%) | 4 (4%) | 8 (9%) | 7 (8%)
Respiratory epithelium, hyperplasia, goblet cell | 1 (1%) | – | – | –
Respiratory epithelium, mineral | 1 (1%) | – | – | –
Trachea | (90) | (88) | (88) | (72)
Artery, inflammation, chronic active | | 1 (1%) | – | –
Artery, mineral | 1 (1%) | – | – | –
Epithelium, hyperplasia | 1 (1%) | – | – | –
Epithelium, metaplasia, squamous | 1 (1%) | – | – | –
Special Senses System
Eye | (85) | (83) | (81) | (72)
Phthisis bulbi | – | – | 1 (1%) | –
Retinal detachment | 1 (1%) | – | 1 (1%) | –
Anterior chamber, inflammation, acute | 4 (5%) | 8 (10%) | 5 (6%) | 1 (1%)
Cornea, fibrosis | 1 (1%) | 2 (2%) | 2 (2%) | 4 (6%)
Cornea, inflammation, acute | 28 (33%) | 18 (22%) | 19 (23%) | 17 (24%)
Cornea, neovascularization | 10 (12%) | 14 (17%) | 14 (17%) | 21 (29%)
Cornea, ulcer | 6 (7%) | 1 (1%) | – | –
Cornea, epithelium, degeneration | – | – | 1 (1%) | 2 (3%)
Cornea, epithelium, hyperplasia | 13 (15%) | 15 (18%) | 17 (21%) | 20 (28%)
Lens, cataract | – | 1 (1%) | – | –
Retina, atrophy | 6 (7%) | 17 (20%) | 17 (21%) | 8 (11%)
Retina, degeneration | 1 (1%) | – | – | –
Retina, dysplasia | – | – | – | 1 (1%)
Harderian gland | (90) | (90) | (90) | (89)
Atrophy | 1 (1%) | 4 (4%) | 2 (2%) | 3 (3%)
Degeneration | – | – | 1 (1%) | 1 (1%)
Degeneration, cystic | 2 (2%) | 4 (4%) | 1 (1%) | –
Hyperplasia | – | – | – | 2 (2%)
Infiltration cellular, lymphocyte | – | 3 (3%) | – | 3 (3%)
Inflammation, suppurative | – | 1 (1%) | – | –
Inflammation, granulomatous | – | 5 (6%) | 2 (2%) | –
Inflammation, acute | 2 (2%) | 1 (1%) | – | –
Inflammation, chronic | – | 1 (1%) | – | 1 (1%)
Inflammation, chronic active | 2 (2%) | 2 (2%) | 1 (1%) | 1 (1%)
Lacrimal gland | (2) | (1) | (1) | (1)
Metaplasia, harderian gland | 2 (100%) | 1 (100%) | 1 (100%) | 1 (100%)
Zymbal’s gland | (0) | (0) | (1) | (1)
Urinary System
Kidney | (90) | (90) | (90) | (87)
Mineral | 1 (1%) | – | 2 (2%) | –
Necrosis | – | – | 1 (1%) | –
Nephropathy, chronic progressive | 88 (98%) | 90 (100%) | 90 (100%) | 86 (99%)
Thrombus | 1 (1%) | 1 (1%) | 1 (1%) | –
Artery, inflammation, chronic active | – | – | 1 (1%) | –
Artery, mineral | 2 (2%) | – | – | –
Pelvis, dilation | 1 (1%) | – | 1 (1%) | 1 (1%)
Pelvis, inflammation, suppurative | – | 1 (1%) | 1 (1%) | –
Pelvis, urothelium, hyperplasia | – | 3 (3%) | 1 (1%) | –
Perirenal tissue, hemorrhage | – | – | – | 1 (1%)
Perirenal tissue, thrombus | – | – | 1 (1%)
Renal tubule, accumulation, hyaline droplet | – | – | – | 1 (1%)
Renal tubule, cyst | 18 (20%) | 17 (19%) | 9 (10%) | 6 (7%)
Renal tubule, hyperplasia, atypical | 2 (2%) | 1 (1%) | 3 (3%) | –
Renal tubule, hyperplasia, oncocytic | 2 (2%) | – | – | –
Renal tubule, inflammation, suppurative | – | – | 1 (1%) | –
Renal tubule, necrosis | – | – | – | 1 (1%)
Urothelium, hyperplasia | 1 (1%) | – | 1 (1%) | –
Urinary bladder | (89) | (83) | (83) | (78)
Dilation | – | 1 (1%) | – | –
Hemorrhage | 2 (2%) | 1 (1%) | 2 (2%) | 1 (1%)
Inflammation, acute | 2 (2%) | 1 (1%) | 1 (1%) | –
Inflammation, chronic active | – | 2 (2%) | – | –
Necrosis | 1 (1%) | – | 1 (1%) | –
Artery, inflammation, chronic active | – | 1 (1%) | – | 1 (1%)
Muscularis, degeneration | 1 (1%) | – | – | –
Serosa, inflammation, chronic active | – | – | 1 (1%) | –
Urothelium, hyperplasia | 1 (1%) | 4 (5%) | 2 (2%) | 1 (1%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.