# Appendix B Summary of Lesions in Female Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

Table B-1 Summary of the Incidence of Neoplasms in Female Rats Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1 | – | – | –
Moribund | 30 | 25 | 31 | 22
Natural deaths | 11 | 10 | 11 | 11
Survivors
Died last week of study | 1 | 3 | 1 | –
Terminal euthanasia | 47 | 52 | 47 | 57
Animals examined microscopically | 100 | 100 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Intestine large, cecum | (84) | (83) | (83) | (84)
Serosa, adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Intestine large, colon | (89) | (88) | (89) | (89)
Intestine large, rectum | (90) | (89) | (89) | (89)
Granular cell tumor benign | 1 (1%) | – | – | –
Serosa, sarcoma, metastatic, uterus | – | 1 (1%) | – | –
Intestine small, duodenum | (88) | (85) | (83) | (85)
Adenocarcinoma | – | 1 (1%) | – | –
Intestine small, ileum | (86) | (82) | (81) | (83)
Intestine small, jejunum | (83) | (82) | (81) | (84)
Leiomyosarcoma | 1 (1%) | 1 (1%) | – | –
Serosa, sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Liver | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Carcinoma, metastatic, kidney | – | 1 (1%) | – | –
Carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Hepatocellular adenoma | 7(8%) | 1 (1%) | 1 (1%) | 3(3%)
Hepatocellular adenoma, multiple | – | 1 (1%) | – | –
Hepatocellular carcinoma | – | 1 (1%) | – | –
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Serosa, adenocarcinoma, metastatic, uterus | – | 1 (1%) | – | –
Mesentery | (4) | (5) | (5) | (5)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (20%) | – | –
Adenocarcinoma, metastatic, pancreas | – | – | 1 (20%) | –
Adenocarcinoma, metastatic, uterus | 1 (25%) | – | – | –
Sarcoma stromal, metastatic, uterus | – | 1 (20%) | – | –
Schwannoma malignant, metastatic, ovary | – | – | 1 (20%)
Oral mucosa | (1) | (0) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Pancreas | (90) | (90) | (90) | (87)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Adenocarcinoma, metastatic, uterus | – | 1 (1%) | – | –
Carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Sarcoma stromal metastatic, uterus | – | 1 (1%) | – | –
Schwannoma malignant, metastatic, ovary | – | – | 1 (1%) | –
Acinus, adenocarcinoma | – | – | 2 (2%) | –
Salivary glands | (90) | (89) | (90) | (90)
Myoepithelioma | – | – | 1 (1%) | –
Schwannoma malignant | – | – | – | 1 (1%)
Parotid gland, adenoma | – | – | 1 (1%) | –
Stomach, forestomach | (90) | (90) | (90) | (90)
Sarcoma | 1 (1%) | – | – | –
Squamous cell papilloma | | | 1 (1%)
Stomach, glandular | (90) | (89) | (90) | (89)
Sarcoma, metastatic, stomach, forestomach | 1 (1%) | – | – | –
Serosa, adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Tongue | (1) | (0) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Tooth | (0) | (0) | (1) | (0)
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Heart | (90) | (90) | (90) | (90)
Endocardium, schwannoma malignant | – | – | 1 (1%) | –
Epicardium, paraganglioma | – | – | 1 (1%) | –
Myocardium, schwannoma malignant | – | – | 1 (1%) | –
Endocrine System
Adrenal cortex | (90) | (90) | (89) | (90)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Adenoma, metastatic, pancreas | – | – | 1 (1%) | –
Adenoma | 1 (1%) | 5 (6%) | 1 (1%) | 5 (6%)
Carcinoma | 1 (1%) | – | – | –
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Adrenal medulla | (86) | (90) | (90) | (86)
Adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Pheochromocytoma benign | 1 (1%) | 3 (3%) | 3 (3%) | 1 (1%)
Pheochromocytoma complex | – | 1 (1%) | 1 (1%) | –
Bilateral, pheochromocytoma benign | – | – | – | 1 (1%)
Islets, pancreatic | (90) | (89) | (90) | (87)
Adenoma | 5 (6%) | 4 (4%) | 3 (3%) | 4 (5%)
Carcinoma | 2 (2%) | 1 (1%) | 4 (4%) | 4 (5%)
Parathyroid gland | (87) | (79) | (82) | (79)
Pituitary gland | (90) | (90) | (90) | (90)
Schwannoma malignant, metastatic, trigeminal ganglion | – | 1 (1%) | – | –
Pars distalis, adenoma | 42 (47%) | 30 (33%) | 35 (39%) | 32 (36%)
Pars distalis, adenoma, multiple | 1 (1%) | 3 (3%) | 3 (3%) | –
Pars distalis, carcinoma | 1 (1%) | 1 (1%) | – | 1 (1%)
Thyroid gland | (90) | (88) | (90) | (88)
Carcinoma, metastatic, kidney | – | 2 (2%) | – | –
Bilateral, C-cell, adenoma | – | 1 (1%) | – | 1 (1%)
Bilateral C-cell, adenoma, multiple | – | 1 (1%) | – | –
C-cell, adenoma | 6 (7%) | 9 (10%) | 8 (9%) | 12 (14%)
C-cell, carcinoma | – | – | 1 (1%) | 1 (1%)
Follicular cell, carcinoma | 1 (1%) | – | – | –
General Body System
Tissue NOS | (8) | (10) | (8) | (10)
Chemodectoma benign | – | – | 1 (13%) | –
Abdominal, schwannoma malignant | 1 (13%) | – | – | –
Fat, adenocarcinoma, metastatic, uterus | – | – | 1 (13%) | –
Mediastinum, paraganglioma | – | 1 (10%) | – | –
Genital System
Clitoral gland | (87) | (85) | (86) | (87)
Squamous cell carcinoma | – | – | – | 1 (1%)
Ovary | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Cystadenoma | 1 (1%) | – | 1 (1%) | –
Granulosa cell tumor benign | 1 (1%) | – | – | –
Granulosa cell tumor malignant | 2(2%) | – | 1 (1%) | –
Lymphangiosarcoma | – | 1 (1%) | – | –
Schwannoma malignant | – | – | 1 (1%) | –
Sertoli cell tumor benign | 1 (1%) | – | – | –
Sex cord stromal tumor, benign | – | 1 (1%) | 1 (1%) | –
Tubulostromal carcinoma | – | – | – | 1 (1%)
Bilateral, rete ovarii, adenoma | – | – | – | 1 (1%)
Periovarian tissue, sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Oviduct | (1) | (0) | (0) | (0)
Uterus | (90) | (89) | (90) | (90)
Adenocarcinoma | 3 (3%) | 1 (1%) | 2 (2%) | 5 (6%)
Adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Adenoma | – | – | – | 1 (1%)
Hemangioma | – | 1 (1%) | – | –
Hemangiosarcoma | 2 (2%) | – | – | –
Leiomyosarcoma | – | – | 1 (1%) | –
Polyp stromal | 15 (17%) | 11 (12%) | 10 (11%) | 16 (18%)
Polyp stromal, multiple | 1 (1%) | 6 (7%) | 1 (1%) | 1 (1%)
Sarcoma stromal | – | 1 (1%) | 2 (2%) | –
Schwannoma malignant | 1 (1%) | – | 1 (1%) | –
Squamous cell carcinoma | – | – | 2 (2%) | –
Cervix, leiomyosarcoma | 1 (1%) | – | – | –
Cervix, malignant mixed mullerian tumor | – | – | – | 1 (1%)
Cervix, polyp stromal | – | 1 (1%) | – | –
Cervix, sarcoma | – | 1 (1%) | – | –
Cervix, schwannoma malignant | 1 (1%) | – | – | 1 (1%)
Vagina | (2) | (3) | (1) | (1)
Granular cell tumor benign | – | 1 (33%) | – | –
Sarcoma, metastatic, uterus | – | 1 (33%) | – | –
Schwannoma malignant | 1 (50%) | – | – | –
Schwannoma malignant, metastatic, uterus | 1 (50%) | – | – | –
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Lymph node | (13) | (14) | (21) | (14)
Bronchial, adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (7%) | – | –
Lumbar, basal cell carcinoma, metastatic, skin | – | 1 (7%) | – | –
Mediastinal, adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (7%) | – | –
Mediastinal, adenocarcinoma, metastatic, pancreas | – | – | 1 (5%) | –
Lymph node, mandibular | (90) | (89) | (89) | (90)
Lymph node, mesenteric | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Hemangiosarcoma | – | – | 1 (1%) | –
Spleen | (90) | (90) | (90) | (90)
Hemangiosarcoma | 1 (1%) | – | – | 1 (1%)
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | | –
Capsule, adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Thymus | (87) | (86) | (88) | (86)
Schwannoma malignant | – | – | 1 (1%) | –
Thymoma benign | 1 (1%) | 1 (1%) | – | –
Thymoma malignant | 1 (1%) | 1 (1%) | – | –
Integumentary System
Mammary gland | (90) | (89) | (89) | (90)
Adenocarcinoma | 9 (10%) | 5 (6%) | 8 (9%) | 6 (7%)
Adenocarcinoma, multiple | 1 (1%) | 1 (1%) | – | –
Adenoma | 4 (4%) | 5 (6%) | 2 (2%) | 2 (2%)
Adenoma, multiple | 4 (4%) | – | – | –
Fibroadenoma | 34 (38%) | 43 (48%) | 38 (43%) | 32 (36%)
Fibroadenoma, multiple | 29 (32%) | 25 (28%) | 22 (25%) | 30 (33%)
Myoepithelioma | – | – | – | 1 (1%)
Skin | (90) | (90) | (90) | (90)
Basal cell carcinoma | – | 1 (1%) | – | –
Keratoacanthoma | – | – | – | 1 (1%)
Pilomatrixoma | – | – | 1 (1%) | –
Squamous cell carcinoma | – | – | 1 (1%) | 1 (1%)
Squamous cell papilloma | – | – | 1 (1%) | –
Subcutaneous tissue, fibroma | 2 (2%) | 3 (3%) | 2 (2%) | 4 (4%)
Subcutaneous tissue, fibrosarcoma | – | 1 (1%) | | 1 (1%)
Subcutaneous tissue, lipoma | – | – | 1 (1%) | –
Subcutaneous tissue, malignant fibrous histiocytoma | 1 (1%) | – | – | –
Subcutaneous tissue, sarcoma | 2 (2%) | – | – | –
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Skeletal muscle | (90) | (90) | (90) | (90)
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Diaphragm, adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Diaphragm, adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Diaphragm, carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Nervous System
Brain | (90) | (90) | (90) | (90)
Carcinoma, metastatic, pituitary gland | 1 (1%) | 1 (1%) | – | 1 (1%)
Glioma malignant | – | – | – | 1 (1%)
Schwannoma malignant, metastatic, trigeminal ganglion | – | 1 (1%) | – | –
Meninges, carcinoma, metastatic, kidney | – | 2 (2%) | – | –
Meninges, granular cell tumor benign | 1 (1%) | 1 (1%) | 2 (2%) | –
Meninges, granular cell tumor malignant | – | – | – | 1 (1%)
Nerve trigeminal | (84) | (88) | (89) | (90)
Schwannoma malignant, metastatic, trigeminal ganglion | – | 1 (1%) | – | –
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Peripheral nerve, tibial | (90) | (90) | (90) | (89)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Meninges, carcinoma, metastatic, kidney | – | 1 (1%) | – | –
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Trigeminal ganglion | (81) | (79) | (80) | (79)
Schwannoma malignant | – | 1 (1%) | – | –
Respiratory System
Lung | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, uterus | – | – | 1 (1%) | –
Alveolar/bronchiolar carcinoma | – | 1 (1%) | – | –
Basal cell carcinoma, metastatic, skin | – | 1 (1%) | – | –
Carcinoma, metastatic, thyroid gland | – | – | 1 (1%) | 1 (1%)
Carcinoma, metastatic, uncertain primary site | – | 2 (2%) | – | –
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Squamous cell carcinoma, metastatic, skin | – | – | 1 (1%) | –
Nose | (90) | (90) | (90) | (90)
Trachea | (89) | (90) | (89) | (87)
Special Senses System
Eye | (88) | (85) | (87) | (87)
Retrobulbar, schwannoma malignant, metastatic, trigeminal ganglion | – | 1 (1%) | – | –
Harderian gland | (90) | (90) | (90) | (90)
Zymbal’s gland | (0) | (0) | (0) | (1)
Squamous cell papilloma | – | – | – | 1 (100%)
Urinary System
Kidney | (90) | (90) | (90) | (89)
Adenocarcinoma, metastatic, intestine small, duodenum | – | 1 (1%) | – | –
Carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Sarcoma stromal, metastatic, uterus | – | 1 (1%) | – | –
Bilateral, renal tubule, carcinoma | 1 (1%) | 1 (1%) | – | –
Bilateral, renal tubule, carcinoma, multiple | – | 1 (1%) | – | –
Renal tubule, adenoma | 1 (1%) | 1 (1%) | – | –
Renal tubule, adenoma, multiple | – | – | – | 1 (1%)
Renal tubule, carcinoma, multiple | – | – | – | 1 (1%)
Urinary bladder | (88) | (88) | (90) | (87)
Leiomyosarcoma | 1 (1%) | – | – | –
Schwannoma malignant, metastatic, ovary | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, tissue NOS | 1 (1%) | – | – | –
Serosa, adenocarcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Urothelium, carcinoma | – | 1 (1%) | – | –
Systemic Lesions
Multiple organs^b^ | (90) | (90) | (90) | (90)
Histiocytic sarcoma | – | 1 (1%) | – | 1 (1%)
Leukemia mononuclear | – | 1 (1%) | 1 (1%) | –
Lymphoma malignant | 5 (6%) | 4 (4%) | 2 (2%) | 5 (6%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 89 | 87 | 82 | 86
Total primary neoplasms
Two-year study | 202 | 189 | 175 | 184
Total animals with benign neoplasms
Two-year study | 82 | 83 | 75 | 80
Total benign neoplasms
Two-year study | 159 | 159 | 140 | 150
Total animals with malignant neoplasms
Two-year study | 37 | 28 | 30 | 28
Total malignant neoplasms
Two-year study | 43 | 30 | 34 | 34
Total animals with metastatic neoplasms
Two-year study | 5 | 11 | 5 | 2
Total metastatic neoplasms
Two-year study | 5 | 44 | 18 | 2
Total animals with malignant neoplasms- uncertain primary site
Two-year study | – | 2 | – | –
Total animals with uncertain neoplasms- benign or malignant
Two-year study | – | – | 1 | –
Total uncertain neoplasms
Two-year study | – | – | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adrenal Cortex: Adenoma
Overall rate^a^ | 1/90 (1%) | 5/90 (6%) | 1/89 (1%) | 5/90 (6%)
Rate per litters^b^ | 1/35 (3%) | 5/35 (14%) | 1/35 (3%) | 4/35 (11%)
Adjusted rate^c^ | 1.4% | 6.5% | 1.4% | 6.7%
Terminal rate^d^ | 1/48 (2%) | 2/53 (4%) | 1/48 (2%) | 4/57 (7%)
First incidence (days) | 737 (T) | 464 | 737 (T) | 651
Rao-Scott adjusted Poly-3 test^e^ | P = 0.222 | P = 0.182 | P = 0.742N | P = 0.174
Litter C-A/Fisher’s test^f^ | P = 0.280 | P = 0.099 | P = 0.754 | P = 0.178
Liver: Hepatocellular Adenoma
Overall rate | 7/90 (8%) | 2/90 (2%) | 1/90 (1%) | 3/90 (3%)
Rate per litters | 6/35 (17%) | 2/35 (6%) | 1/35 (3%) | 3/35 (9%)
Adjusted rate | 10.1% | 2.6% | 1.4% | 4.0%
Terminal rate | 6/48 (13%) | 2/53 (4%) | 1/48 (2%) | 3/57 (5%)
First incidence (days) | 707 | 737 (T) | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.168N | P = 0.106N | P = 0.061N | P = 0.183N
Litter C-A/Fisher’s test | P = 0.207N | P = 0.130N | P = 0.053N | P = 0.239N
Liver: Hepatocellular Adenoma or Hepatocellular Carcinoma
Overall rate | 7/90 (8%) | 3/90 (3%) | 1/90 (1%) | 3/90 (3%)
Rate per litters | 6/35 (17%) | 3/35 (9%) | 1/35 (3%) | 3/35 (9%)
Adjusted rate | 10.1% | 4.0% | 1.4% | 4.0%
Terminal rate | 6/48 (13%) | 2/53 (4%) | 1/48 (2%) | 3/57 (5%)
First incidence (days) | 707 | 696 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.141N | P = 0.171N | P = 0.057N | P = 0.176N
Litter C-A/Fisher’s test | P = 0.175N | P = 0.239N | P = 0.053N | P = 0.239N
Mammary Gland: Fibroadenoma
Overall rate | 63/90 (70%) | 68/90 (76%) | 60/90 (67%) | 62/90 (69%)
Rate per litters | 31/35 (89%) | 33/35 (94%) | 33/35 (94%) | 34/35 (97%)
Adjusted rate | 77.0% | 79.2% | 71.7% | 72.7%
Terminal rate | 36/48 (75%) | 39/53 (74%) | 32/48 (67%) | 38/57 (67%)
First incidence (days) | 464 | 464 | 383 | 283
Rao-Scott adjusted Poly-3 test | P = 0.219N | P = 0.445 | P = 0.287N | P = 0.334N
Litter C-A/Fisher’s test | P = 0.134 | P = 0.337 | P = 0.337 | P = 0.178
Mammary Gland: Adenoma
Overall rate | 8/90 (9%) | 5/90 (6%) | 2/90 (2%) | 2/90 (2%)
Rate per litters | 7/35 (20%) | 5/35 (14%) | 2/35 (6%) | 2/35 (6%)
Adjusted rate | 11.3% | 6.6% | 2.8% | 2.7%
Terminal rate | 5/48 (10%) | 4/53 (8%) | 2/48 (4%) | 1/57 (2%)
First incidence (days) | 524 | 718 | 737 (T) | 669
Rao-Scott adjusted Poly-3 test | P = 0.038N | P = 0.271N | P = 0.075N | P = 0.065N
Litter C-A/Fisher’s test | P = 0.036N | P = 0.376N | P = 0.075N | P = 0.075N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 64/90 (71%) | 69/90 (77%) | 60/90 (67%) | 62/90 (69%)
Rate per litters | 31/35 (89%) | 33/35 (94%) | 33/35 (94%) | 34/35 (97%)
Adjusted rate | 77.7% | 80.4% | 71.7% | 72.7%
Terminal rate | 36/48 (75%) | 40/53 (76%) | 32/48 (67%) | 38/57 (67%)
First incidence (days) | 464 | 464 | 383 | 283
Rao-Scott adjusted Poly-3 test | P = 0.182N | P = 0.413 | P = 0.260N | P = 0.304N
Litter C-A/Fisher’s test | P = 0.134 | P = 0.337 | P = 0.337 | P = 0.178
Mammary Gland: Adenocarcinoma
Overall rate | 10/90 (11%) | 6/90 (7%) | 8/90 (9%) | 6/90 (7%)
Rate per litters | 9/35 (26%) | 6/35 (17%) | 7/35 (20%) | 6/35 (17%)
Adjusted rate | 14.2% | 7.8% | 11.1% | 7.9%
Terminal rate | 6/48 (13%) | 4/53 (8%) | 5/48 (10%) | 3/57 (5%)
First incidence (days) | 622 | 332 | 489 | 489
Rao-Scott adjusted Poly-3 test | P = 0.218N | P = 0.171N | P = 0.379N | P = 0.177N
Litter C-A/Fisher’s test | P = 0.284N | P = 0.281N | P = 0.388N | P = 0.281N
Mammary Gland: Adenoma or Adenocarcinoma
Overall rate | 16/90 (18%) | 11/90 (12%) | 10/90 (11%) | 8/90 (9%)
Rate per litters | 13/35 (37%) | 11/35 (31%) | 9/35 (26%) | 7/35 (20%)
Adjusted rate | 22.2% | 14.2% | 13.9% | 10.5%
Terminal rate | 9/48 (19%) | 8/53 (15%) | 7/48 (15%) | 4/57 (7%)
First incidence (days) | 524 | 332 | 489 | 489
Rao-Scott adjusted Poly-3 test | P = 0.052N | P = 0.153N | P = 0.146N | P = 0.049N
Litter C-A/Fisher’s test | P = 0.065N | P = 0.401N | P = 0.220N | P = 0.093N
Mammary Gland: Fibroadenoma, Adenoma, or Adenocarcinoma
Overall rate | 66/90 (73%) | 72/90 (80%) | 64/90 (71%) | 64/90 (71%)
Rate per litters | 31/35 (89%) | 34/35 (97%) | 35/35 (100%) | 34/35 (97%)
Adjusted rate | 79.6% | 82.3% | 75.3% | 74.4%
Terminal rate | 36/48 (75%) | 41/53 (77%) | 33/48 (69%) | 39/57 (68%)
First incidence (days) | 464 | 332 | 383 | 283
Rao-Scott adjusted Poly-3 test | P = 0.166N | P = 0.410 | P = 0.326N | P = 0.282N
Litter C-A/Fisher’s test | P = 0.102 | P = 0.178 | P = 0.057 | P = 0.178
Pancreatic Islets: Adenoma
Overall rate | 5/90 (6%) | 4/89 (4%) | 3/90 (3%) | 4/87 (5%)
Rate per litters | 4/35 (11%) | 4/35 (11%) | 3/35 (9%) | 4/35 (11%)
Adjusted rate | 7.2% | 5.3% | 4.2% | 5.5%
Terminal rate | 5/48 (10%) | 2/53 (4%) | 2/48 (4%) | 3/57 (5%)
First incidence (days) | 737 (T) | 699 | 621 | 669
Rao-Scott adjusted Poly-3 test | P = 0.422N | P = 0.451N | P = 0.346N | P = 0.466N
Litter C-A/Fisher’s test | P = 0.555N | P = 0.645 | P = 0.500N | P = 0.645
Pancreatic Islets: Carcinoma
Overall rate | 2/90 (2%) | 1/89 (1%) | 4/90 (4%) | 4/87 (5%)
Rate per litters | 2/35 (6%) | 1/35 (3%) | 4/35 (11%) | 4/35 (11%)
Adjusted rate | 2.9% | 1.3% | 5.6% | 5.5%
Terminal rate | 1/48 (2%) | 1/53 (2%) | 2/48 (4%) | 4/57 (7%)
First incidence (days) | 711 | 737 (T) | 699 | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.188 | P = 0.467N | P = 0.349 | P = 0.362
Litter C-A/Fisher’s test | P = 0.157 | P = 0.500N | P = 0.337 | P = 0.337
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 7/90 (8%) | 5/89 (6%) | 7/90 (8%) | 7/87 (8%)
Rate per litters | 6/35 (17%) | 5/35 (14%) | 7/35 (20%) | 7/35 (20%)
Adjusted rate | 10.1% | 6.7% | 9.8% | 9.6%
Terminal rate | 6/48 (13%) | 3/53 (6%) | 4/48 (8%) | 6/57 (11%)
First incidence (days) | 711 | 699 | 621 | 669
Rao-Scott adjusted Poly-3 test | P = 0.487 | P = 0.323N | P = 0.571N | P = 0.558N
Litter C-A/Fisher’s test | P = 0.369 | P = 0.500N | P = 0.500 | P = 0.500
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 43/90 (48%) | 33/90 (37%) | 38/90 (42%) | 32/90 (36%)
Rate per litters | 28/35 (80%) | 24/35 (69%) | 26/35 (74%) | 23/35 (66%)
Adjusted rate | 57.1% | 42.5% | 51.2% | 41.6%
Terminal rate | 28/48 (58%) | 23/53 (43%) | 24/48 (50%) | 24/57 (42%)
First incidence (days) | 464 | 578 | 545 | 565
Rao-Scott adjusted Poly-3 test | P = 0.077N | P = 0.049N | P = 0.283N | P = 0.038N
Litter C-A/Fisher’s test | P = 0.162N | P = 0.206N | P = 0.388N | P = 0.141N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 44/90 (49%) | 34/90 (38%) | 38/90 (42%) | 33/90 (37%)
Rate per litters | 29/35 (83%) | 24/35 (69%) | 26/35 (74%) | 23/35 (66%)
Adjusted rate | 57.9% | 43.8% | 51.2% | 42.8%
Terminal rate | 28/48 (58%) | 24/53 (45%) | 24/48 (50%) | 25/57 (44%)
First incidence (days) | 464 | 578 | 545 | 565
Rao-Scott adjusted Poly-3 test | P = 0.082N | P = 0.056N | P = 0.250N | P = 0.044N
Litter C-A/Fisher’s test | P = 0.111N | P = 0.132N | P = 0.281N | P = 0.085N
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 5/90 (6%) | 4/90 (4%) | 2/90 (2%) | 5/90 (6%)
Rate per litters | 5/35 (14%) | 4/35 (11%) | 2/35 (6%) | 5/35 (14%)
Adjusted rate | 7.0% | 5.2% | 2.8% | 6.7%
Terminal rate | 1/48 (2%) | 3/53 (6%) | 2/48 (4%) | 4/57 (7%)
First incidence (days) | 268 | 123 | 737 (T) | 669
Rao-Scott adjusted Poly-3 test | P = 0.551N | P = 0.449N | P = 0.220N | P = 0.586N
Litter C-A/Fisher’s test | P = 0.571 | P = 0.500N | P = 0.214N | P = 0.633
Thyroid Gland (C-cell): Adenoma
Overall rate | 6/90 (7%) | 11/88 (13%) | 8/90 (9%) | 13/88 (15%)
Rate per litters | 6/35 (17%) | 10/35 (29%) | 8/35 (23%) | 12/35 (34%)
Adjusted rate | 8.5% | 14.7% | 11.3% | 17.6%
Terminal rate | 3/48 (6%) | 8/53 (15%) | 6/48 (13%) | 12/57 (21%)
First incidence (days) | 608 | 699 | 695 | 656
Rao-Scott adjusted Poly-3 test | P = 0.108 | P = 0.188 | P = 0.383 | P = 0.091
Litter C-A/Fisher’s test | P = 0.096 | P = 0.197 | P = 0.383 | P = 0.085
Thyroid Gland (C-cell): Adenoma or Carcinoma
Overall rate | 6/90 (7%) | 11/88 (13%) | 9/90 (10%) | 14/88 (16%)
Rate per litters | 6/35 (17%) | 10/35 (29%) | 9/35 (26%) | 13/35 (37%)
Adjusted rate | 8.5% | 14.7% | 12.7% | 18.9%
Terminal rate | 3/48 (6%) | 8/53 (15%) | 7/48 (15%) | 13/57 (23%)
First incidence (days) | 608 | 699 | 695 | 656
Rao-Scott adjusted Poly-3 test | P = 0.068 | P = 0.186 | P = 0.290 | P = 0.061
Litter C-A/Fisher’s test | P = 0.054 | P = 0.197 | P = 0.281 | P = 0.053
Uterus: Stromal Polyp
Overall rate | 16/90 (18%) | 18/90 (20%) | 11/90 (12%) | 17/90 (19%)
Rate per litters | 11/35 (31%) | 14/35 (40%) | 10/35 (29%) | 13/35 (37%)
Adjusted rate | 22.7% | 23.5% | 15.4% | 22.3%
Terminal rate | 14/48 (29%) | 14/53 (26%) | 6/48 (13%) | 11/57 (19%)
First incidence (days) | 531 | 602 | 656 | 594
Rao-Scott adjusted Poly-3 test | P = 0.461N | P = 0.530 | P = 0.216N | P = 0.554N
Litter C-A/Fisher’s test | P = 0.452 | P = 0.309 | P = 0.500N | P = 0.401
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 16/90 (18%) | 19/90 (21%) | 13/90 (14%) | 17/90 (19%)
Rate per litters | 11/35 (31%) | 15/35 (43%) | 11/35 (31%) | 13/35 (37%)
Adjusted rate | 22.7% | 24.7% | 18.2% | 22.3%
Terminal rate | 14/48 (29%) | 14/53 (26%) | 8/48 (17%) | 11/57 (19%)
First incidence (days) | 531 | 602 | 656 | 594
Rao-Scott adjusted Poly-3 test | P = 0.451N | P = 0.465 | P = 0.341N | P = 0.553N
Litter C-A/Fisher’s test | P = 0.476 | P = 0.229 | P = 0.601 | P = 0.401
Uterus: Adenocarcinoma
Overall rate | 3/90 (3%) | 1/90 (1%) | 2/90 (2%) | 5/90 (6%)
Rate per litters | 2/35 (6%) | 1/35 (3%) | 2/35 (6%) | 5/35 (14%)
Adjusted rate | 4.3% | 1.3% | 2.8% | 6.7%
Terminal rate | 3/48 (6%) | 1/53 (2%) | 2/48 (4%) | 5/57 (9%)
First incidence (days) | 737 (T) | 737 (T) | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.217 | P = 0.316N | P = 0.500N | P = 0.420
Litter C-A/Fisher’s test | P = 0.075 | P = 0.500N | P = 0.693 | P = 0.214
All Organs: Malignant Schwannoma
Overall rate | 4/90 (4%) | 1/90 (1%) | 5/90 (6%) | 2/90 (2%)
Rate per litters | 3/35 (9%) | 1/35 (3%) | 5/35 (14%) | 2/35 (6%)
Adjusted rate | 5.7% | 1.3% | 7.0% | 2.7%
Terminal rate | 2/48 (4%) | 0/53 (0%) | 2/48 (4%) | 1/57 (2%)
First incidence (days) | 489 | 480 | 578 | 622
Rao-Scott adjusted Poly-3 test | P = 0.428N | P = 0.212N | P = 0.519 | P = 0.354N
Litter C-A/Fisher’s test | P = 0.563N | P = 0.307N | P = 0.355 | P = 0.500N
All Organs: Malignant Lymphoma
Overall rate | 5/90 (6%) | 4/90 (4%) | 2/90 (2%) | 5/90 (6%)
Rate per litters | 5/35 (14%) | 3/35 (9%) | 2/35 (6%) | 5/35 (14%)
Adjusted rate | 7.0% | 5.2% | 2.8% | 6.5%
Terminal rate | 0/48 (0%) | 0/53 (0%) | 0/48 (0%) | 1/57 (2%)
First incidence (days) | 268 | 545 | 450 | 299
Rao-Scott adjusted Poly-3 test | P = 0.537N | P = 0.454N | P = 0.229N | P = 0.572N
Litter C-A/Fisher’s test | P = 0.518 | P = 0.355N | P = 0.214N | P = 0.633
All Organs: Benign Neoplasms
Overall rate | 82/90 (91%) | 83/90 (92%) | 75/90 (83%) | 80/90 (89%)
Rate per litters | 35/35 (100%) | 33/35 (94%) | 35/35 (100%) | 35/35 (100%)
Adjusted rate | 97.1% | 95.7% | 88.3% | 93.0%
Terminal rate | 48/48 (100%) | 51/53 (96%) | 41/48 (85%) | 53/57 (93%)
First incidence (days) | 464 | 464 | 383 | 283
Rao-Scott adjusted Poly-3 test | P = 0.129N | P = 0.469N | P = 0.031N | P = 0.196N
Litter C-A/Fisher’s test | P = 0.405 | P = 0.246N | –^g^ | –
All Organs: Malignant Neoplasms
Overall rate | 37/90 (41%) | 30/90 (33%) | 30/90 (33%) | 28/90 (31%)
Rate per litters | 25/35 (71%) | 21/35 (60%) | 23/35 (66%) | 22/35 (63%)
Adjusted rate | 48.1% | 36.6% | 39.1% | 35.3%
Terminal rate | 21/48 (44%) | 15/53 (28%) | 14/48 (29%) | 18/57 (32%)
First incidence (days) | 268 | 123 | 439 | 299
Rao-Scott adjusted Poly-3 test | P = 0.100N | P = 0.093N | P = 0.165N | P = 0.070N
Litter C-A/Fisher’s test | P = 0.349N | P = 0.225N | P = 0.399N | P = 0.306N
All Organs: Benign or Malignant Neoplasms
Overall rate | 89/90 (99%) | 87/90 (97%) | 82/90 (91%) | 86/90 (96%)
Rate per litters | 35/35 (100%) | 34/35 (97%) | 35/35 (100%) | 35/35 (100%)
Adjusted rate | 100% | 97.2% | 92.9% | 97.2%
Terminal rate | 48/48 (100%) | 51/53 (96%) | 42/48 (88%) | 55/57 (97%)
First incidence (days) | 268 | 123 | 383 | 283
Rao-Scott adjusted Poly-3 test | P = 0.220N | P = 0.226N | P = 0.028N | P = 0.226N
Litter C-A/Fisher’s test | P = 0.567 | P = 0.500N | – | –

(T) = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Number of litters with tumor-bearing animals/number of litters examined at site.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ The Litter Cochran-Armitage and Fishers exact tests directly compare the litter incidence rates.

^g^ Value of statistic cannot be computed.

Table B-3 Historical Incidence of Malignant Schwannoma in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Heart: Malignant Schwannoma | All Organs: Malignant Schwannoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/49 | 2/50
Indole-3-carbinol (March 2007) | 0/50 | 2/50
Radiofrequency radiation (September 2012) | 0/90 | 4/90
Overall Historical Incidence
Total (%) | 0/239 | 8/240 (3.3%)
Mean ± standard deviation | – | 3.1% ± 2.1%
Range | – | 0%–4%

^a^ Data as of November 2017.

Table B-4 Historical Incidence of Brain Neoplasms in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Malignant Glioma | Benign Granular Cell Tumor | Malignant Granular Cell Tumor | Benign or Malignant Granular Cell Tumor
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 1/50 | 0/50 | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50 | 1/50 | 0/50 | 1/50
Radiofrequency radiation (September 2012) | 0/90 | 1/90 | 0/90 | 1/90
Overall Historical Incidence:
Total (%) | 1/190 (0.5%) | 2/190 (1.1%) | 0/190 | 2/190 (1.1%)
Mean ± standard deviation | 0.7% ± 1.2% | 1.0% ± 1.0% | – | 1.0% ± 1.0%
Range | 0%–2% | 0%–2% | – | 0%–2%

^a^ Data as of November 2017; due to differences in sectioning method, indole-3-carbinol was excluded from evaluation of brain lesions.

Table B-5 Historical Incidence of Adrenal Medulla Neoplasms in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Benign Pheochromocytoma | Malignant Pheochromocytoma | Complex Pheochromocytoma | Benign, Malignant, or Complex Pheochromocytoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/49 | 0/49 | 0/49 | 0/49
2-Hydroxy-4-methoxybenzophenone (November 2010) | 3/50 | 2/50 | 0/50 | 5/50
Indole-3-carbinol (March 2007) | 0/50 | 0/50 | 0/50 | 0/50
Radiofrequency radiation (September 2012) | 1/86 | 0/86 | 0/86 | 1/86
Overall Historical Incidence
Total (%) | 4/235 (1.7%) | 2/235 (0.9%) | 0/235 | 6/235 (2.6%)
Mean ± standard deviation | 1.8% ± 2.9% | 1.0% ± 2.0% | – | 2.8% ± 4.8%
Range | 0%–6% | 0%–4% | – | 0%–10%

^a^ Data as of November 2017.

Table B-6 Historical Incidence of Pituitary Gland (Pars Distalis) Adenoma in Control Female Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 18/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 19/50
Indole-3-carbinol (March 2007) | 18/50
Radiofrequency radiation (September 2012) | 43/90
Overall Historical Incidence
Total (%) | 98/240 (40.8%)
Mean ± standard deviation | 39.4% ± 5.6%
Range | 36%–48%

^a^ Data as of November 2017.

Table B-7 Summary of the Incidence of Non-neoplastic Lesions in Female Rats Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1
Moribund | 30 | 25 | 31 | 22
Natural deaths | 11 | 10 | 11 | 11
Survivors
Died last week of study | 1 | 3 | 1 | –
Terminal euthanasia | 47 | 52 | 47 | 57
Animals examined microscopically | 100 | 100 | 100 | 100
Fourteen-week Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Lymphoid tissue, hyperplasia | 1 (10%) | 1 (10%) | – | –
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, mixed cell | 1 (10%) | 1 (10%) | 2 (20%) | 1 (10%)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Degeneration, cystic | – | – | – | 1 (10%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Cardiovascular System
Aorta | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | – | 2 (20%) | 1 (10%) | 2 (20%)
Ventricle right, cardiomyopathy | – | – | 1 (10%) | –
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (10) | (8) | (9) | (9)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | 2 (20%) | – | – | –
Pars intermedia, cyst | 1 (10%) | 1 (10%) | – | –
Thyroid gland | (10) | (10) | (10) | (10)
Genital System
Clitoral gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 4 (40%) | 5 (50%) | 6 (60%) | 4 (40%)
Ovary | (10) | (10) | (10) | (10)
Cyst | – | – | – | 1 (10%)
Follicle, cyst | 1 (10%) | – | – | –
Uterus | (10) | (10) | (10) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hemorrhage | – | 2 (20%) | | –
Hyperplasia, lymphocyte | – | – | – | 2 (20%)
Proliferation, plasma cell | – | – | – | 3 (30%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%) | | 1 (10%) | –
Musculoskeletal System
Bone | (10) | (10) | (10) | (10)
Skeletal muscle | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | – | – | 1 (10%) | –
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | – | – | 1 (10%) | –
Inflammation, chronic active | – | – | 1 (10%) | –
Alveolus, infiltration cellular, histiocyte | 2 (20%) | – | – | –
Epithelium alveolus, hyperplasia | – | – | 1 (10%) | –
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Harderian gland | (10) | (10) | (10) | (10)
Inflammation cellular, lymphocyte | 1 (10%) | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy, chronic progressive | 3 (30%) | 4 (40%) | 3 (30%) | 2 (20%)
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined with No Lesions Observed
General Body System
Integumentary System
Nervous System
Two-year Study
Alimentary System
Esophagus | (90) | (90) | (90) | (90)
Dilation | – | – | 1 (1%) | –
Intestine large, cecum | (84) | (83) | (83) | (84)
Serosa, inflammation, acute | – | 1 (1%) | – | –
Intestine large, colon | (89) | (88) | (89) | (89)
Intestine large, rectum | (90) | (89) | (89) | (89)
Hyperplasia, lymphocyte | – | 1 (1%) | – | 1 (1%)
Inflammation, acute | – | – | – | 1 (1%)
Necrosis | – | – | – | 1 (1%)
Epithelium, hyperplasia | – | – | – | 1 (1%)
Epithelium, metaplasia, squamous | – | – | 1 (1%) | –
Intestine small, duodenum | (88) | (85) | (83) | (85)
Ectopic tissue | – | – | – | 1 (1%)
Ulcer | – | 1 (1%) | – | –
Intestine small, ileum | (86) | (82) | (81) | (83)
Hyperplasia, lymphocyte | 1 (1%) | – | – | –
Necrosis, lymphoid | – | – | – | 1 (1%)
Serosa, inflammation, acute | – | 1 (1%) | – | –
Intestine small, jejunum | (83) | (82) | (81) | (84)
Liver | (90) | (90) | (90) | (90)
Angiectasis | 6 (7%) | 4 (4%) | 6 (7%) | 6 (7%)
Basophilic focus | 11 (12%) | 17 (19%) | 11 (12%) | 8 (9%)
Clear cell focus | 2 (2%) | 3 (3%) | 6 (7%) | 6 (7%)
Congestion | – | 1 (1%) | 2 (2%) | –
Eosinophilic focus | 9 (10%) | 26 (29%) | 23 (26%) | 23 (26%)
Extramedullary hematopoiesis | 15 (17%) | 19 (21%) | 17 (19%) | 12 (13%)
Fibrosis | – | 1 (1%) | – | –
Hepatodiaphragmatic nodule | 1 (1%) | – | 1 (1%) | –
Infiltration cellular, histiocyte | – | – | 2 (2%) | –
Infiltration cellular, mixed cell | 1 (1%) | 4 (4%) | 1 (1%) | 2 (2%)
Infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Inflammation, acute | – | 1 (1%) | – | 1 (1%)
Inflammation, chronic | – | 1 (1%) | – | –
Inflammation, chronic active | – | – | 2 (2%) | –
Mixed cell focus | 29 (32%) | 23 (26%) | 33 (37%) | 28 (31%)
Pigment | – | 1 (1%) | – | –
Bile duct, cyst | 11 (12%) | 6 (7%) | 5 (6%) | 8 (9%)
Bile duct, fibrosis | 1 (1%) | – | – | –
Bile duct, hyperplasia | 9 (10%) | 5 (6%) | 10 (11%) | 9 (10%)
Bile duct, inflammation, chronic active | – | – | 1 (1%) | –
Centrilobular, hepatocyte, necrosis | – | 3 (3%) | – | 2 (2%)
Centrilobular, hepatocyte, vacuolation, cytoplasmic | – | 1 (1%) | – | –
Hepatocyte, degeneration | – | – | 1 (1%) | –
Hepatocyte, hypertrophy | 2 (2%) | 5 (6%) | 2 (2%) | 6 (7%)
Hepatocyte, increased mitoses | 2 (2%) | – | – | –
Hepatocyte, necrosis | 4 (4%) | 2 (2%) | 5 (6%) | 8 (9%)
Hepatocyte, vacuolation, cytoplasmic | 1 (1%) | 1 (1%) | 1 (1%) | 3 (3%)
Kupffer cell, hyperplasia | 3 (3%) | – | – | –
Kupffer cell, hypertrophy | 2 (2%) | – | – | –
Periductal, cholangiofibrosis | 1 (1%) | – | – | 1 (1%)
Serosa, inflammation, suppurative | – | 1 (1%) | – | –
Serosa, inflammation, chronic active | 1 (1%) | – | – | –
Sinusoid, dilation | – | 1 (1%) | 1 (1%) | –
Mesentery | (4) | (5) | (5) | (5)
Inflammation, chronic active | 1 (25%) | – | 1 (20%) | –
Necrosis | 1 (25%) | 3 (60%) | 2 (40%) | 3 (60%)
Artery, inflammation, chronic active | – | – | – | 1 (20%)
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (90) | (90) | (90) | (87)
Ectopic liver | 1 (1%) | – | – | –
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | 1 (1%) | – | 2 (2%) | –
Acinus, atrophy | 5 (6%) | 4 (4%) | 4 (4%) | 5 (6%)
Acinus, hyperplasia | 1 (1%) | 2 (2%) | 5 (6%) | 2 (2%)
Artery, inflammation, chronic active | – | 2 (2%) | 1 (1%) | 1 (1%)
Periductal, cholangiofibrosis | – | – | 7 (8%) | 4 (5%)
Salivary glands | (90) | (89) | (90) | (90)
Duct, parotid gland, dilation | 1 (1%) | – | – | 1 (1%)
Parotid gland, atrophy | 4 (4%) | 11 (12%) | 8 (9%) | 4 (4%)
Parotid gland, inflammation, acute | – | – | – | 1 (1%)
Parotid gland, vacuolation, cytoplasmic | – | – | – | 1 (1%)
Sublingual gland, atrophy | – | – | – | 2 (2%)
Sublingual gland, metaplasia | – | – | 1 (1%) | –
Submandibular gland, atrophy | – | 1 (1%) | 1 (1%) | –
Stomach, forestomach | (90) | (90) | (90) | (90)
Edema | 2 (2%) | 2 (2%) | 1 (1%) | –
Erosion | 2 (2%) | – | – | –
Fibrosis | 1 (1%) | – | – | –
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | 4 (4%) | 5 (6%) | – | –
Ulcer | 1 (1%) | 7 (8%) | 2 (2%) | 2 (2%)
Epithelium, hyperplasia | 10 (11%) | 14 (16%) | 8 (9%) | 8 (9%)
Epithelium, hyperplasia, basal cell | 1 (1%) | – | – | 1 (1%)
Stomach, glandular | (90) | (89) | (90) | (89)
Erosion | 1 (1%) | 1 (1%) | – | –
Tongue | (1) | (0) | (0) | (0)
Tooth | (0) | (0) | (1) | (0)
Dysplasia | – | – | 1 (100%) | –
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Dilation | – | – | 1 (1%) | –
Mineral | – | 2 (2%) | 1 (1%) | –
Heart | (90) | (90) | (90) | (90)
Cardiomyopathy | 40 (44%) | 30 (33%) | 39 (43%) | 27 (30%)
Atrium, myocardium, hypertrophy | – | 1 (1%) | – | –
Myocardium, hypertrophy | – | 1 (1%) | – | –
Myocardium, mineral | – | 1 (1%) | – | –
Myocardium, necrosis | – | – | – | 1 (1%)
Myocardium, Schwann cell, hyperplasia | – | – | – | 1 (1%)
Myocardium, ventricle right, degeneration | – | – | 1 (1%) | –
Vein, mineral | – | 1 (1%) | – | –
Ventricle right, cardiomyopathy | 4 (4%) | 9 (10%) | 14 (16%) | 15 (17%)
Endocrine System
Adrenal cortex | (90) | (90) | (89) | (90)
Accessory adrenal cortical nodule | 5(6%) | 7 (8%) | 6 (7%) | 6 (7%)
Angiectasis | – | 1 (1%) | – | –
Atrophy | 1 (1%) | 1 (1%) | – | –
Cyst | – | – | 1 (1%) | –
Degeneration, cystic | 22 (24%) | 26 (29%) | 36 (40%) | 29 (32%)
Extramedullary hematopoiesis | – | 1 (1%) | 1 (1%) | –
Hemorrhage | – | 1 (1%) | 1 (1%) | –
Hyperplasia | 14 (16%) | 26 (29%) | 40 (45%) | 26 (29%)
Hypertrophy | 52 (58%) | 54 (60%) | 51 (57%) | 56 (62%)
Mineral | – | – | 1 (1%) | –
Necrosis | 2 (2%) | 4 (4%) | 1 (1%) | 2 (2%)
Pigment | 1 (1%) | – | – | –
Thrombus | – | 3 (3%) | 1 (1%) | –
Vacuolation, cytoplasmic | 18 (20%) | 21 (23%) | 11 (12%) | 8 (9%)
Adrenal medulla | (86) | (90) | (90) | (86)
Hyperplasia | 13 (15%) | 19 (21%) | 14 (16%) | 25 (29%)
Necrosis | 1 (1%) | – | – | –
Islets, pancreatic | (90) | (89) | (90) | (87)
Ectopic tissue | – | – | 1 (1%) | –
Hyperplasia | 15 (17%) | 6 (7%) | 11 (12%) | 12 (14%)
Parathyroid gland | (87) | (79) | (82) | (79)
Cyst | – | 1 (1%) | – | –
Fibrosis | 13 (15%) | 4 (5%) | 9 (11%) | 6 (8%)
Hyperplasia | – | 1 (1%) | 2 (2%) | 1 (1%)
Hyperplasia, focal | 3 (3%) | – | 2 (2%) | –
Hypertrophy | – | 1 (1%) | – | –
Pituitary gland | (90) | (90) | (90) | (90)
Cyst | 1 (1%) | – | – | –
Pars distalis, angiectasis | 2 (2%) | – | – | –
Pars distalis, atrophy | – | 1 (1%) | – | –
Pars distalis, cyst | 7 (8%) | 3 (3%) | 4 (4%) | 4 (4%)
Pars distalis, hyperplasia | 20 (22%) | 26 (29%) | 22 (24%) | 22 (24%)
Pars distalis, vacuolation, cytoplasmic | – | – | 1 (1%) | –
Pars intermedia, cyst | 3 (3%) | 3 (3%) | 2 (2%) | 2 (2%)
Pars intermedia, hyperplasia | 1 (1%) | – | 1 (1%) | –
Pars intermedia, vacuolation, cytoplasmic | – | – | 1 (1%) | –
Pars nervosa, cyst | – | 1 (1%) | – | –
Thyroid gland | (90) | (88) | (90) | (88)
C-cell, hyperplasia | 28 (31%) | 49 (56%) | 45 (50%) | 43 (49%)
Follicle, cyst | 1 (1%) | 2 (2%) | – | 1 (1%)
General Body System
Tissue NOS | (8) | (10) | (8) | (10)
Inflammation, chronic active | 1 (13%) | – | – | –
Abdominal, necrosis | – | 1 (10%) | – | –
Fat, necrosis | 6 (75%) | 8 (80%) | 7 (88%) | 9 (90%)
Genital System
Clitoral gland | (87) | (85) | (86) | (87)
Hyperplasia, focal | – | 3 (4%) | – | –
Inflammation, suppurative | 1 (1%) | 1 (1%) | – | –
Inflammation, granulomatous | – | 1 (1%) | – | 1 (1%)
Inflammation, acute | – | – | 1 (1%) | 1 (1%)
Inflammation, chronic active | 28 (32%) | 24 (28%) | 32 (37%) | 40 (46%)
Metaplasia, squamous | – | 1 (1%) | – | –
Duct, dilation | 47 (54%) | 47 (55%) | 44 (51%) | 40 (46%)
Ovary | (90) | (90) | (90) | (90)
Atrophy | 72 (80%) | 63 (70%) | 66 (73%) | 71 (79%)
Congestion | 1 (1%) | – | – | –
Cyst | 22 (24%) | 24 (27%) | 23 (26%) | 27 (30%)
Fibrosis | – | 1 (1%) | – | –
Inflammation, suppurative | – | 1 (1%) | – | –
Inflammation, chronic | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | – | 2 (2%)
Necrosis | – | – | – | 1 (1%)
Bursa, dilation | 4 (4%) | 5 (6%) | 6 (7%) | 6 (7%)
Interstitial cell, hyperplasia | – | 2 (2%) | – | –
Periovarian tissue, cyst | – | – | 1 (1%) | –
Periovarian tissue, hemorrhage | – | – | 1 (1%) | –
Periovarian tissue, inflammation, chronic active | – | – | – | 1 (1%)
Rete ovarii, hyperplasia | 15 (17%) | 25 (28%) | 13 (14%) | 12 (13%)
Oviduct | (1) | (0) | (0) | (0)
Cyst | 1 (100%) | – | – | –
Uterus | (90) | (89) | (90) | (90)
Adenomyosis | – | – | – | 1 (1%)
Angiectasis | 1 (1%) | 1 (1%) | – | –
Cyst | 5 (6%) | 3 (3%) | 11 (12%) | 7 (8%)
Dilation | 8 (9%) | 7 (8%) | 12 (13%) | 4 (4%)
Fibrosis | 1 (1%) | 1 (1%) | 1 (1%) | –
Hemorrhage | – | 3 (3%) | 4 (4%) | 1 (1%)
Hyperplasia, stromal | – | 3 (3%) | 1 (1%) | 4 (4%)
Inflammation cellular, mononuclear cell | – | – | 1 (1%) | –
Inflammation, suppurative | 4 (4%) | 11 (12%) | 6 (7%) | 10 (11%)
Inflammation, acute | 1 (1%) | – | – | 2 (2%)
Inflammation, chronic active | – | 2 (2%) | 6 (7%) | 1 (1%)
Pigment | – | 1 (1%) | – | 1 (1%)
Thrombus | 1 (1%) | 2 (2%) | – | 1 (1%)
Artery, inflammation, chronic active | – | – | – | 1 (1%)
Cervix, cyst | – | – | 1 (1%) | –
Cervix, hyperplasia, stromal | 2 (2%) | – | – | 1 (1%)
Cervix, serosa, fibrosis | 1 (1%) | – | – | –
Endometrium, hyperplasia, cystic | 37 (41%) | 33 (37%) | 28 (31%) | 39 (43%)
Epithelium, metaplasia, squamous | 48 (53%) | 38 (43%) | 39 (43%) | 45 (50%)
Serosa, fibrosis | – | – | 1 (1%) | –
Serosa, inflammation, suppurative | – | 1 (1%) | – | –
Vein, thrombus | – | 1 (1%) | –
Vagina | (2) | (3) | (1) | (1)
Exudate | – | 1 (33%) | – | –
Inflammation, chronic active | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Hypercellularity | 56 (62%) | 57 (63%) | 55 (61%) | 56 (62%)
Myelofibrosis | – | – | – | 1 (1%)
Lymph node | (13) | (14) | (21) | (14)
Axillary, hyperplasia, lymphocyte | – | – | – | 1 (7%)
Axillary, proliferation, plasma cell | 1 (8%) | – | – | 1 (7%)
Deep cervical, fibrosis | – | – | – | 1 (7%)
Deep cervical, inflammation, chronic active | – | – | – | 1 (7%)
Iliac, congestion | – | – | – | 1 (7%)
Iliac, erythrophagocytosis | 3 (23%) | 1 (7%) | 3 (14%) | 2 (14%)
Iliac, hyperplasia, lymphocyte | 1 (8%) | – | 2 (10%) | 2 (14%)
Iliac, infiltration cellular, histiocyte | – | – | 1 (5%) | –
Iliac, inflammation, acute | 1 (8%) | – | – | –
Iliac, pigment | 1 (8%) | – | 1 (5%) | 1 (7%)
Iliac, proliferation, plasma cell | 6 (46%) | 1 (7%) | 2 (10%) | –
Iliac, lymphatic sinus, ectasia | – | 1 (7%) | 3 (14%) | –
Inguinal, erythrophagocytosis | 1 (8%) | – | – | –
Inguinal, hyperplasia, lymphocyte | – | 1 (7%) | – | –
Inguinal, infiltration cellular, plasma cell | – | 1 (7%) | – | –
Inguinal, pigment | – | – | 1 (5%) | –
Inguinal, proliferation, plasma cell | 1 (8%) | – | – | –
Inguinal, lymphatic sinus, ectasia | 1 (8%) | – | – | –
Lumbar, erythrophagocytosis | 1 (8%) | 1 (7%) | 1 (5%) | 1 (7%)
Lumbar, hyperplasia, lymphocyte | – | 2 (14%) | – | –
Lumbar, infiltration cellular, histiocyte | – | – | 1 (5%) | –
Lumbar, inflammation, chronic active | – | 1 (7%) | – | –
Lumbar, proliferation, plasma cell | – | 2 (14%) | 1 (5%) | –
Lumbar, lymphatic sinus, ectasia | – | 1 (7%) | – | –
Lymphatic sinus, mediastinal, ectasia | – | – | 1 (5%) | –
Lymphatic sinus, renal, ectasia | – | 1 (7%) | – | –
Mediastinal, congestion | 1 (8%) | – | 1 (5%) | –
Mediastinal, erythrophagocytosis | – | 3 (21%) | 5 (24%) | 3 (21%)
Mediastinal, hyperplasia, lymphocyte | – | – | 2 (10%) | 1 (7%)
Mediastinal, proliferation, plasma cell | 1 (8%) | – | 3 (14%) | –
Pancreatic, erythrophagocytosis | 1 (8%) | 1 (7%) | 1 (5%)
Renal, erythrophagocytosis | – | 2 (14%) | 1 (5%) | 2 (14%)
Renal, inflammation, chronic active | – | 1 (7%) | – | –
Lymph node, mandibular | (90) | (89) | (89) | (90)
Congestion | – | – | – | 1 (1%)
Erythrophagocytosis | – | 2 (2%) | 4 (4%) | 3 (3%)
Hemorrhage | 1 (1%) | – | – | –
Hyperplasia, lymphocyte | 46 (51%) | 40 (45%) | 44 (49%) | 51 (57%)
Hyperplasia, reticulum cell | – | – | – | 1 (1%)
Infiltration cellular, histiocyte | – | 1 (1%) | – | –
Inflammation, chronic active | – | – | 1 (1%) | –
Proliferation, plasma cell | 68 (76%) | 57 (64%) | 65 (73%) | 56 (62%)
Lymphatic sinus, ectasia | 1 (1%) | 3 (3%) | 7 (8%) | 1 (1%)
Lymph node, mesenteric | (90) | (90) | (90) | (90)
Atrophy | 1 (1%) | 1 (1%) | – | –
Erythrophagocytosis | 1 (1%) | 3 (3%) | 3 (3%) | 5 (6%)
Hemorrhage | – | 1 (1%) | – | –
Hyperplasia, lymphocyte | – | 1 (1%) | – | 1 (1%)
Infiltration cellular, histiocyte | 2 (2%) | 3 (3%) | 2 (2%) | 1 (1%)
Necrosis, lymphocyte | – | – | – | 1 (1%)
Pigment | – | – | – | 1 (1%)
Proliferation, plasma cell | – | 1 (1%) | 1 (1%) | –
Lymphatic sinus, ectasia | – | 1 (1%) | – | –
Spleen | (90) | (90) | (90) | (90)
Accessory spleen | – | – | 1 (1%) | –
Congestion | – | 2 (2%) | 1 (1%) | –
Developmental malformation | – | – | 1 (1%) | –
Extramedullary hematopoiesis | 80 (89%) | 77 (86%) | 78 (87%) | 78 (87%)
Hemorrhage | – | – | 1 (1%) | –
Hyperplasia, stromal | 1 (1%) | – | – | –
Pigment | 74 (82%) | 40 (44%) | 47 (52%) | 46 (51%)
Red pulp, atrophy | 7 (8%) | 5 (6%) | 2 (2%) | 1 (1%)
Red pulp, hyperplasia | – | 2 (2%) | – | –
White pulp, atrophy | 3 (3%) | 6 (7%) | 6 (7%) | 2 (2%)
Thymus | (87) | (86) | (88) | (86)
Atrophy | 75 (86%) | 70 (81%) | 62 (70%) | 61 (71%)
Cyst | 39 (45%) | 30 (35%) | 33 (38%) | 28 (33%)
Ectopic parathyroid gland | 1 (1%) | 1 (1%) | 2 (2%) | –
Ectopic thyroid | – | 1 (1%) | – | 1 (1%)
Hemorrhage | 2 (2%) | 2 (2%) | 2 (2%) | 3 (3%)
Hyperplasia, epithelial | 55 (63%) | 19 (22%) | 19 (22%) | 20 (23%)
Necrosis, lymphocyte | – | – | – | 1 (1%)
Integumentary System
Mammary gland | (90) | (89) | (89) | (90)
Galactocele | 24 (27%) | 18 (20%) | 14 (16%) | 10 (11%)
Hyperplasia | 49 (54%) | 41 (46%) | 51 (57%) | 28 (31%)
Hyperplasia, atypical | – | – | – | 3 (3%)
Inflammation, granulomatous | – | – | 1 (1%) | –
Duct, dilation | 56 (62%) | 52 (58%) | 55 (62%) | 58 (64%)
Lymphatic, dilation | – | – | 1 (1%) | –
Skin | (90) | (90) | (90) | (90)
Cyst epithelial inclusion | 1 (1%) | 2 (2%) | – | –
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | 1 (1%) | – | – | –
Ulcer | – | – | 1 (1%) | –
Dermis, fibrosis | – | 1 (1%) | – | –
Epidermis, hyperplasia | 2 (2%) | – | – | –
Subcutaneous tissue, edema | – | – | 1 (1%) | 1 (1%)
Subcutaneous tissue, inflammation, chronic active | – | – | 1 (1%) | 1 (1%)
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Fibrosis | – | 1 (1%) | 1 (1%) | –
Fibrous osteodystrophy | – | 1 (1%) | 2 (2%) | –
Increased bone | – | 1 (1%) | 1 (1%) | –
Cranium, fracture | 1 (1%) | – | – | –
Mandible, fracture | 1 (1%) | – | – | –
Maxilla, fracture | 1 (1%) | – | – | –
Vertebra, increased bone | – | 1 (1%) | – | –
Vertebra, inflammation, chronic active | – | 1 (1%) | – | –
Skeletal muscle | (90) | (90) | (90) | (90)
Degeneration | 3 (3%) | 7 (8%) | 4 (4%) | 3 (3%)
Mineral | – | – | – | 1 (1%)
Nervous System
Brain | (90) | (90) | (90) | (90)
Compression | 26 (29%) | 16 (18%) | 18 (20%) | 11 (12%)
Congestion | 1 (1%) | 1 (1%) | – | –
Cyst | – | – | – | 1 (1%)
Edema | 2 (2%) | – | – | 2 (2%)
Hemorrhage | – | 1 (1%) | – | 1 (1%)
Mineral | – | – | 1 (1%) | –
Necrosis | – | – | – | 1 (1%)
Pigment | – | 1 (1%) | – | –
Cerebellum, hemorrhage | – | 1 (1%) | – | –
Glial cell, hyperplasia | – | – | 1 (1%) | –
Hypothalamus, cyst | – | 1 (1%) | – | –
Meninges, hyperplasia | 1 (1%) | – | – | –
Meninges, hyperplasia, granular cell | 1 (1%) | – | 1 (1%) | –
Pineal gland, mineral | 1 (1%) | 1 (1%) | 3 (3%) | 1 (1%)
Pineal gland, vacuolation, cytoplasmic | 1 (1%) | 3 (3%) | 2 (2%) | 1 (1%)
Nerve trigeminal | (84) | (88) | (89) | (90)
Degeneration | 64 (76%) | 71 (81%) | 65 (73%) | 74 (82%)
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Degeneration | 80 (89%) | 84 (93%) | 81 (90%) | 84 (93%)
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Peripheral nerve, tibial | (90) | (90) | (90) | (89)
Degeneration | 77 (86%) | 83 (92%) | 80 (89%) | 80 (90%)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Degeneration | 24 (27%) | 29 (32%) | 43 (48%) | 23 (26%)
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Cyst | – | 1 (1%) | – | 1 (1%)
Degeneration | 10 (11%) | 7 (8%) | 13 (14%) | 12 (13%)
Nerve, degeneration | 74 (82%) | 81 (90%) | 70 (78%) | 78 (87%)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Degeneration | 59 (66%) | 64 (71%) | 61 (68%) | 65 (72%)
Trigeminal ganglion | (81) | (79) | (80) | (79)
Degeneration | 33 (41%) | 31 (39%) | 28 (35%) | 17 (22%)
Respiratory System
Lung | (90) | (90) | (90) | (90)
Congestion | 3 (3%) | 5 (6%) | 5 (6%) | 3 (3%)
Foreign body | – | 2 (2%) | – | –
Hemorrhage | 1 (1%) | 1 (1%) | 4 (4%) | 2 (2%)
Inflammation, suppurative | 2 (2%) | 1 (1%) | – | –
Inflammation, granulomatous | 1 (1%) | 2 (2%) | 3 (3%) | –
Inflammation, chronic active | 6 (7%) | 8 (9%) | 9 (10%) | 8 (9%)
Pigment | – | – | – | 1 (1%)
Alveolar epithelium, metaplasia, squamous | – | – | 1 (1%) | 1 (1%)
Alveolus, infiltration cellular, histiocyte | 71 (79%) | 75 (83%) | 83 (92%) | 82 (91%)
Alveolus, pigment | – | – | 2 (2%) | 1 (1%)
Artery, inflammation, chronic active | 1 (1%) | – | – | –
Bronchiole, hyperplasia | – | – | 1 (1%) | –
Epithelium alveolus, hyperplasia | 2 (2%) | 2 (2%) | 6 (7%) | 2 (2%)
Interstitium, fibrosis | – | 1 (1%) | – | –
Nose | (90) | (90) | (90) | (90)
Foreign body | – | – | 1 (1%) | –
Inflammation, suppurative | 1 (1%) | 2 (2%) | 3 (3%) | 1 (1%)
Inflammation, acute | – | – | 1 (1%) | 1 (1%)
Inflammation, chronic active | – | – | 1 (1%) | –
Nasopharyngeal duct, inflammation, chronic active | – | 1 (1%) | – | –
Nerve, olfactory epithelium, degeneration | – | 1 (1%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 89 (99%) | 86 (96%) | 88 (98%) | 87 (97%)
Olfactory epithelium, atrophy | – | 1 (1%) | 1 (1%) | –
Olfactory epithelium, degeneration | – | 1 (1%) | – | –
Olfactory epithelium, metaplasia, respiratory | 1 (1%) | – | 1 (1%) | –
Respiratory epithelium, accumulation, hyaline droplet | 12 (13%) | 8 (9%) | 10 (11%) | 10 (11%)
Respiratory epithelium, hyperplasia | – | – | 1 (1%) | –
Respiratory epithelium, metaplasia, squamous | – | – | 2 (2%) | –
Trachea | (89) | (90) | (89) | (87)
Inflammation, chronic active | 1 (1%) | – | – | –
Artery, inflammation, chronic active | – | – | – | 1 (1%)
Epithelium, hyperplasia | – | 1 (1%) | – | –
Glands, cyst | 1 (1%) | – | – | –
Special Senses System
Eye | (88) | (85) | (87) | (87)
Cornea, inflammation, acute | 1 (1%) | – | – | –
Cornea, epithelium, hyperplasia | 1 (1%) | – | – | –
Lens, cataract | 1 (1%) | – | – | –
Retina, atrophy | 18 (20%) | 15 (18%) | 16 (18%) | 13 (15%)
Retina, dysplasia | 1 (1%) | – | – | –
Sclera, inflammation, acute | – | – | 1 (1%) | –
Harderian gland | (90) | (90) | (90) | (90)
Atrophy | 13 (14%) | 12 (13%) | 15 (17%) | 24 (27%)
Hyperplasia | – | – | 1 (1%) | –
Infiltration cellular, lymphocyte | 2 (2%) | – | – | –
Inflammation, granulomatous | 7 (8%) | 9 (10%) | 9 (10%) | 10 (11%)
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic | 7 (8%) | 4 (4%) | 1 (1%) | 2 (2%)
Inflammation, chronic active | 1 (1%) | 1 (1%) | 2 (2%) | 2 (2%)
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (90) | (90) | (90) | (89)
Ectopic tissue | – | 1 (1%) | – | –
Infarct | – | 1 (1%) | – | –
Inflammation, granulomatous | – | – | – | 1 (1%)
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic active | – | 1 (1%) | 1 (1%) | –
Mineral | – | – | – | 1 (1%)
Necrosis | – | 1 (1%) | – | –
Nephropathy, chronic progressive | 74 (82%) | 61 (68%) | 68 (76%) | 59 (66%)
Artery, inflammation, chronic active | 1 (1%) | – | – | 1 (1%)
Pelvis, dilation | 3 (3%) | 2 (2%) | 1 (1%) | –
Renal tubule, accumulation, hyaline droplet | – | 2 (2%) | 1 (1%) | –
Renal tubule, cyst | 3 (3%) | 2 (2%) | 1 (1%) | 1 (1%)
Renal tubule, hyperplasia, atypical | – | 1 (1%) | – | 1 (1%)
Renal tubule, hypertrophy | – | 1 (1%) | – | –
Renal tubule, necrosis | – | 2 (2%) | – | –
Renal tubule, pigment | – | 1 (1%) | – | –
Urothelium, hyperplasia | – | – | – | 1 (1%)
Urinary bladder | (88) | (88) | (90) | (87)
Dilation | 1 (1%) | – | – | –
Edema | – | 1 (1%) | – | –
Hemorrhage | – | 1 (1%) | 1 (1%) | –
Infiltration cellular, histiocyte | – | – | – | 1 (1%)
Infiltration cellular, mononuclear cell | – | – | – | 1 (1%)
Inflammation, acute | 3 (3%) | – | 1 (1%) | –
Necrosis | 1 (1%) | – | – | –
Urothelium, hyperplasia | 1 (1%) | 1 (1%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.