# Appendix A Summary of Lesions in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

Table A-1 Summary of the Incidence of Neoplasms in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 1 | – | – | 1
Moribund | 44 | 24 | 19 | 13
Natural deaths | 20 | 21 | 21 | 16
Survivors
Terminal euthanasia | 25 | 45 | 50 | 60
Animals examined microscopically | 100 | 100 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (90) | (89) | (90) | (90)
Intestine large, cecum | (75) | (75) | (79) | (80)
Intestine large, colon | (81) | (83) | (81) | (82)
Serosa, pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (1%) | –
Intestine large, rectum | (83) | (81) | (85) | (87)
Intestine small, duodenum | (81) | (82) | (79) | (79)
Adenocarcinoma | – | 1 (1%) | – | 1 (1%)
Intestine small, ileum | (78) | (76) | (78) | (76)
Intestine small, jejunum | (73) | (76) | (70) | (76)
Adenocarcinoma | 2 (3%) | 1 (1%) | 1 (1%) | 1 (1%)
Liver | (90) | (90) | (90) | (90)
Cholangioma | – | 1 (1%) | – | –
Hepatocellular adenoma | – | 1 (1%) | – | 2 (2%)
Hepatocellular carcinoma | – | – | 1 (1%) | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (1%) | –
Serosa, carcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (1%)
Mesentery | (39) | (19) | (17) | (7)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (6%) | –
Oral mucosa | (0) | (2) | (0) | (2)
Squamous cell carcinoma | – | 1 (50%) | – | 1 (50%)
Pancreas | (90) | (89) | (88) | (86)
Adenoma | 13 (14%) | 17 (19%) | 14 (16%) | 12 (14%)
vAdenoma, multiple | 5 (6%) | 4 (4%) | 4 (5%) | 4 (5%)
Carcinoma | 1 (1%) | 1 (1%) | 2 (2%) | –
Carcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (1%)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (1%) | –
Salivary glands | (90) | (90) | (90) | (90)
Schwannoma malignant | – | 1 (1%) | – | –
Sublingual gland, schwannoma malignant, metastatic, uncertain primary site | 1 (1%) | – | – | –
Stomach, forestomach | (90) | (90) | (90) | (90)
Sarcoma | – | – | – | 1 (1%)
Squamous cell carcinoma | – | – | – | 1 (1%)
Squamous cell papilloma | 1 (1%) | – | – | –
Stomach, glandular | (86) | (88) | (87) | (86)
Tooth | (0) | (1) | (1) | (0)
Odontoma | – | – | 1 (100%) | –
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Chemodectoma malignant | – | 1 (1%) | – | –
Blood vessel | (1) | (2) | (1) | (0)
Heart | (90) | (90) | (90) | (90)
Carcinoma, metastatic, adrenal cortex | – | – | – | 1 (1%)
Chemodectoma malignant | – | 1 (1%) | – | –
Endocardium, schwannoma malignant | – | 1 (1%) | 1 (1%) | 2 (2%)
Myocardium, schwannoma malignant | – | 1 (1%) | – | 3 (3%)
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (88)
Adenoma | 1 (1%) | 4 (4%) | 2 (2%) | 1 (1%)
Carcinoma | – | 1 (1%) | – | 1 (1%)
Adrenal medulla | (88) | (90) | (89) | (87)
Pheochromocytoma benign | 8 (9%) | 21 (23%) | 19 (21%) | 14 (16%)
Pheochromocytoma benign, multiple | 1 (1%) | – | 2 (2%) | –
Pheochromocytoma, complex | 1 (1%) | – | – | –
Pheochromocytoma, malignant | 1 (1%) | 1 (1%) | 4 (4%) | –
Bilateral, pheochromocytoma benign | 1 (1%) | 2 (2%) | 4 (4%) | –
Bilateral, pheochromocytoma malignant | – | 1 (1%) | – | –
Islets, pancreatic | (90) | (89) | (86) | (85)
Adenoma | 5 (6%) | 12 (13%) | 9 (10%) | 10 (12%)
Adenoma, multiple | – | 2 (2%) | 1 (1%) | 1 (1%)
Carcinoma | 8 (9%) | 13 (15%) | 10 (12%) | 5 (6%)
Carcinoma, multiple | – | 2 (2%) | – | –
Parathyroid gland | (83) | (87) | (87) | (81)
Adenoma | 1 (1%) | 1 (1%) | – | 1 (1%)
Pituitary gland | (89) | (90) | (90) | (90)
Sarcoma, metastatic, eye | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, Harderian gland | – | – | – | 1 (1%)
Schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Pars distalis, adenoma | 17 (19%) | 28 (31%) | 25 (28%) | 26 (29%)
Pars distalis, adenoma, multiple | – | – | 1 (1%) | –
Thyroid gland | (89) | (89) | (89) | (87)
Chemodectoma malignant, metastatic, tissue NOS | – | 1 (1%) | –
Bilateral, C-cell, adenoma | – | – | 1 (1%) | 1 (1%)
C-cell, adenoma | 8 (9%) | 9 (10%) | 7 (8%) | 7 (8%)
C-cell, carcinoma | 2 (2%) | 2 (2%) | 2 (2%) | 3 (3%)
Follicular cell, adenoma | – | 1 (1%) | 1 (1%) | –
Follicular cell, adenoma, multiple | – | 1 (1%) | – | –
Follicular cell, carcinoma | – | – | – | 1 (1%)
General Body System
Tissue NOS | (3) | (4) | (4) | (5)
Chemodectoma malignant | – | 1 (25%) | – | –
Abdominal, fat, hemangiosarcoma | – | 1 (25%) | – | –
Abdominal, fat, pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (25%) | –
Mediastinum, chemodectoma benign | – | – | – | 1 (20%)
Mediastinum, schwannoma malignant | 1 (33%) | – | – | –
Genital System
Bulbourethral gland | (1) | (0) | (0) | (0)
Coagulating gland | (0) | (0) | (0) | (1)
Ductus deferens | (1) | (0) | (0) | (0)
Epididymis | (90) | (90) | (90) | (90)
Penis | (0) | (0) | (0) | (1)
Preputial gland | (88) | (90) | (90) | (90)
Squamous cell carcinoma | – | – | – | 1 (1%)
Prostate | (90) | (90) | (90) | (90)
Adenoma | 2 (2%) | 2 (2%) | 6 (7%) | 3 (3%)
Carcinoma | – | – | 1 (1%) | –
Seminal vesicle | (90) | (89) | (89) | (90)
Testis | (90) | (90) | (90) | (90)
Interstitial cell, adenoma | 2 (2%) | 2 (2%) | 3 (3%) | 2 (2%)
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Hemangioma | – | – | – | 1 (1%)
Lymph node | (25) | (22) | (18) | (12)
Mediastinal, pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (6%) | –
Pancreatic, pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (6%) | –
Lymph node, mandibular | (89) | (90) | (89) | (90)
Schwannoma malignant, metastatic, salivary glands | – | 1 (1%) | – | –
Lymph node, mesenteric | (90) | (89) | (86) | (89)
Carcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (1%)
Hemangiosarcoma | – | – | – | 1 (1%)
Spleen | (90) | (90) | (89) | (90)
Hemangiosarcoma | 3 (3%) | – | – | 1 (1%)
Capsule, carcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (1%)
Thymus | (88) | (86) | (88) | (86)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (1%) | – | –
Thymoma benign | – | 2 (2%) | 1 (1%) | –
Thymoma malignant | – | – | – | 1 (1%)
Integumentary System
Mammary gland | (82) | (76) | (82) | (82)
Adenocarcinoma | – | – | 1 (1%) | –
Fibroadenoma | 2 (2%) | 3 (4%) | 4 (5%) | 2 (2%)
Skin | (90) | (90) | (90) | (90)
Basal cell adenoma | 1 (1%) | 1 (1%) | – | 1 (1%)
Basal cell carcinoma | – | – | 1 (1%) | –
Keratoacanthoma | 5 (6%) | 3 (3%) | 9 (10%) | 2 (2%)
Neural crest tumor | – | – | 1 (1%) | –
Sarcoma | – | – | 1 (1%) | –
Squamous cell papilloma | 2 (2%) | – | – | –
Sebaceous gland, adenoma | 1 (1%) | – | – | –
Subcutaneous tissue, fibroma | 2 (2%) | 5 (6%) | 7 (8%) | 5 (6%)
Subcutaneous tissue, fibrosarcoma | 1 (1%) | 3 (3%) | 1 (1%) | 2 (2%)
Subcutaneous tissue, hemangiopericytoma | – | – | 1 (1%) | –
Subcutaneous tissue, hibernoma | – | – | – | 1 (1%)
Subcutaneous tissue, lipoma | 2 (2%) | 3 (3%) | 1 (1%) | 2 (2%)
Subcutaneous tissue, malignant fibrous histiocytoma | – | – | 1 (1%) | –
Subcutaneous tissue, myxosarcoma | – | – | 1 (1%) | –
Subcutaneous tissue, sarcoma | 2 (2%) | 1 (1%) | – | 1 (1%)
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Skeletal muscle | (90) | (90) | (90) | (90)
Diaphragm, carcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (1%)
Nervous System
Brain | (90) | (90) | (90) | (90)
Glioma malignant | – | 3 (3%) | 3 (3%) | 2 (2%)
Sarcoma, metastatic, eye | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Meninges, granular cell tumor benign | 1 (1%) | 3 (3%) | 3 (3%) | 3 (3%)
Meninges, granular cell tumor malignant | – | – | 1 (1%) | –
Nerve trigeminal | (84) | (88) | (87) | (88)
Schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Peripheral nerve, tibial | (88) | (89) | (90) | (88)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Trigeminal ganglion | (75) | (73) | (77) | (77)
Sarcoma, metastatic, eye | – | – | 1 (1%) | –
Schwannoma malignant | – | – | 1 (1%) | –
Respiratory System
Lung | (90) | (90) | (90) | (90)
Alveolar/bronchiolar adenoma | 1 (1%) | 1 (1%) | – | –
Alveolar/bronchiolar carcinoma | – | 1 (1%) | – | –
Carcinoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Sarcoma, metastatic, kidney | – | – | – | 1 (1%)
Schwannoma malignant, metastatic, salivary glands | – | 1 (1%) | – | –
Nose | (89) | (90) | (90) | (89)
Sarcoma, metastatic, eye | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, uncertain primary site | 1 (1%) | – | – | –
Trachea | (90) | (88) | (87) | (86)
Chemodectoma malignant, metastatic, tissue NOS | – | 1 (1%) | – | –
Special Senses System
Eye | (85) | (86) | (87) | (83)
Choroid, schwannoma malignant | – | – | 1 (1%) | –
Retrobulbar, sarcoma | – | – | 1 (1%) | –
Retrobulbar, schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Retrobulbar, schwannoma malignant, metastatic, uncertain primary site | 2 (2%) | – | 1 (1%) | –
Harderian gland | (90) | (90) | (90) | (90)
Schwannoma malignant | – | – | 1 (1%) | 2 (2%)
Schwannoma malignant, metastatic, trigeminal ganglion | – | – | 1 (1%) | –
Schwannoma malignant, metastatic, uncertain primary site | 2 (2%) | – | 1 (1%) | –
Lacrimal gland | (2) | (1) | (2) | (2)
Urinary System
Kidney | (90) | (90) | (90) | (90)
Hemangioma | – | 1 (1%) | – | –
Lipoma | 1 (1%) | 1 (1%) | – | –
Oncocytoma benign | 1 (1%) | – | 1 (1%) | –
Sarcoma | – | – | 1 (1%) | 1 (1%)
Bilateral, renal tubule, adenoma | – | – | – | 1 (1%)
Bilateral, renal tubule, adenoma, multiple | 1 (1%) | – | – | –
Bilateral, renal tubule, carcinoma | 1 (1%) | – | – | 1 (1%)
Renal tubule, adenoma | 1 (1%) | 1 (1%) | 3 (3%) | 1 (1%)
Renal tubule, adenoma, multiple | 1 (1%) | – | – | –
Ureter | (0) | (1) | (0) | (0)
Urethra | (0) | (0) | (1) | (0)
Transitional epithelium, papilloma | – | – | 1 (100%) | –
Urinary bladder | (89) | (89) | (86) | (85)
Carcinoma, metastatic, prostate | – | – | 1 (1%) | –
Systemic Lesions
Multiple organs^b^ | (90) | (90) | (90) | (90)
Leukemia mononuclear | – | – | – | 1 (1%)
Lymphoma malignant | 2 (2%) | 4 (4%) | 4 (4%) | 2 (2%)
Mesothelioma malignant | 2 (2%) | 1 (1%) | 6 (7%) | 1 (1%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 56 | 73 | 78 | 71
Total primary neoplasms
Two-year study | 114 | 176 | 179 | 141
Total animals with benign neoplasms
Two-year study | 49 | 68 | 71 | 57
Total benign neoplasms
Two-year study | 87 | 132 | 131 | 104
Total animals with malignant neoplasms
Two-year study | 24^d^ | 36 | 38 | 34
Total malignant neoplasms
Two-year study | 27 | 44 | 47 | 37
Total animals with metastatic neoplasms
Two-year study | 2 | 4 | 5 | 3
Total metastatic neoplasms
Two-year study | 6 | 6 | 20 | 8
Total animals with malignant neoplasms, uncertain primary site
Two-year study | 2 | 1 | 1 | –
Total animals with uncertain neoplasms- benign or malignant
Two-year study | – | – | 1 | –
Total uncertain neoplasms
Two-year study | – | – | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

^d^ Includes one animal that had a neoplasm of unknown primary origin.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 10/88 (11%) | 23/90 (26%) | 25/89 (28%) | 14/87 (16%)
Rate per litters^b^ | 8/35 (23%) | 19/35 (54%) | 21/35 (60%) | 12/35 (34%)
Adjusted rate^c^ | 15.2% | 29.9% | 31.7% | 18.3%
Terminal rate^d^ | 3/23 (13%) | 13/45 (29%) | 14/49 (29%) | 11/59 (19%)
First incidence (days) | 510 | 599 | 526 | 631
Rao-Scott adjusted Poly-3 test^e^ | P = 0.472N | P = 0.030 | P = 0.017 | P = 0.384
Litter C-A/Fisher’s test^f^ | P = 0.365 | P = 0.007 | P = 0.002 | P = 0.214
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 11/88 (13%) | 24/90 (27%) | 28/89 (31%) | 14/87 (16%)
Rate per litters | 9/35 (26%) | 19/35 (54%) | 23/35 (66%) | 12/35 (34%)
Adjusted rate | 16.7% | 31.1% | 35.3% | 18.3%
Terminal rate | 3/23 (13%) | 13/45 (29%) | 15/49 (31%) | 11/59 (19%)
First incidence (days) | 510 | 599 | 526 | 631
Rao-Scott adjusted Poly-3 test | P = 0.409N | P = 0.035 | P = 0.010 | P = 0.472
Litter C-A/Fisher’s test | P = 0.420 | P = 0.014 | P < 0.001 | P = 0.301
Heart: Malignant Schwannoma
Overall rate | 0/90 (0%) | 2/90 (2%) | 1/90 (1%) | 5/90 (6%)
Rate per litters | 0/35 (0%) | 2/35 (6%) | 1/35 (3%) | 5/35 (14%)
Adjusted rate | 0% | 2.7% | 1.3% | 6.4%
Terminal rate | 0/25 (0%) | 2/45 (4%) | 1/50 (2%) | 3/60 (5%)
First incidence (days) | –^g^ | 730 (T) | 730 (T) | 582
Rao-Scott adjusted Poly-3 test | P = 0.041 | P = 0.297 | P = 0.540 | P = 0.080
Litter C-A/Fisher’s test | P = 0.013 | P = 0.246 | P = 0.500 | P = 0.027
Mammary Gland: Fibroma, Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 2/90 (2%) | 3/90 (3%) | 5/90 (6%) | 2/90 (2%)
Rate per litters | 2/35 (6%) | 3/35 (9%) | 5/35 (14%) | 2/35 (6%)
Adjusted rate | 3.0% | 4.0% | 6.3% | 2.6%
Terminal rate | 1/25 (4%) | 0/45 (0%) | 3/50 (6%) | 1/60 (2%)
First incidence (days) | 440 | 320 | 454 | 544
Rao-Scott adjusted Poly-3 test | P = 0.504N | P = 0.536 | P = 0.289 | P = 0.604N
Litter C-A/Fisher’s test | P = 0.581 | P = 0.500 | P = 0.214 | P = 0.693
Pancreas: Adenoma
Overall rate | 18/90 (20%) | 21/89 (24%) | 18/88 (20%) | 16/86 (19%)
Rate per litters | 16/35 (46%) | 17/35 (49%) | 13/34 (38%) | 13/35 (37%)
Adjusted rate | 26.8% | 27.6% | 23.5% | 21.3%
Terminal rate | 9/25 (36%) | 13/45 (29%) | 15/50 (30%) | 14/60 (23%)
First incidence (days) | 580 | 614 | 716 | 674
Rao-Scott adjusted Poly-3 test | P = 0.216N | P = 0.523 | P = 0.396N | P = 0.292N
Litter C-A/Fisher’s test | P = 0.204N | P = 0.500 | P = 0.350N | P = 0.314N
Pancreas: Adenoma or Carcinoma
Overall rate | 18/90 (20%) | 22/89 (25%) | 19/88 (22%) | 16/86 (19%)
Rate per litters | 16/35 (46%) | 18/35 (51%) | 14/34 (41%) | 13/35 (37%)
Adjusted rate | 26.8% | 28.9% | 24.7% | 21.3%
Terminal rate | 9/25 (36%) | 13/45 (29%) | 15/50 (30%) | 14/60 (23%)
First incidence (days) | 580 | 614 | 677 | 674
Rao-Scott adjusted Poly-3 test | P = 0.201N | P = 0.459 | P = 0.457N | P = 0.288N
Litter C-A/Fisher’s test | P = 0.189N | P = 0.406 | P = 0.446N | P = 0.314N
Pancreatic Islets: Adenoma
Overall rate | 5/90 (6%) | 14/89 (16%) | 10/86 (12%) | 11/85 (13%)
Rate per litters | 5/35 (14%) | 12/35 (34%) | 9/34 (26%) | 11/35 (31%)
Adjusted rate | 7.6% | 18.5% | 13.2% | 14.8%
Terminal rate | 2/25 (8%) | 10/45 (22%) | 9/50 (18%) | 11/60 (18%)
First incidence (days) | 624 | 531 | 677 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.282 | P = 0.051 | P = 0.204 | P = 0.140
Litter C-A/Fisher’s test | P = 0.141 | P = 0.046 | P = 0.169 | P = 0.077
Pancreatic Islets: Carcinoma
Overall rate | 8/90 (9%) | 15/89 (17%) | 10/86 (12%) | 5/85 (6%)
Rate per litters | 8/35 (23%) | 12/35 (34%) | 10/34 (29%) | 4/35 (11%)
Adjusted rate | 12.0% | 19.7% | 13.1% | 6.7%
Terminal rate | 3/25 (12%) | 7/45 (16%) | 8/50 (16%) | 4/60 (7%)
First incidence (days) | 663 | 531 | 537 | 544
Rao-Scott adjusted Poly-3 test | P = 0.088N | P = 0.173 | P = 0.517 | P = 0.220N
Litter C-A/Fisher’s test | P = 0.083N | P = 0.214 | P = 0.365 | P = 0.171N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 13/90 (14%) | 27/89 (30%) | 19/86 (22%) | 16/85 (19%)
Rate per litters | 12/35 (34%) | 19/35 (54%) | 17/34 (50%) | 14/35 (40%)
Adjusted rate | 19.4% | 35.2% | 24.8% | 21.3%
Terminal rate | 5/25 (20%) | 16/45 (36%) | 16/50 (32%) | 15/60 (25%)
First incidence (days) | 624 | 531 | 537 | 544
Rao-Scott adjusted Poly-3 test | P = 0.344N | P = 0.032 | P = 0.282 | P = 0.462
Litter C-A/Fisher’s test | P = 0.518 | P = 0.074 | P = 0.140 | P = 0.402
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 17/89 (19%) | 28/90 (31%) | 26/90 (29%) | 26/90 (29%)
Rate per litters | 13/35 (37%) | 23/35 (66%) | 19/35 (54%) | 22/35 (63%)
Adjusted rate | 24.9% | 35.2% | 32.2% | 32.4%
Terminal rate | 5/25 (20%) | 15/45 (33%) | 17/50 (34%) | 19/60 (32%)
First incidence (days) | 527 | 309 | 537 | 384
Rao-Scott adjusted Poly-3 test | P = 0.301 | P = 0.126 | P = 0.216 | P = 0.210
Litter C-A/Fisher’s test | P = 0.064 | P = 0.015 | P = 0.115 | P = 0.028
Prostate Gland: Adenoma
Overall rate | 2/90 (2%) | 2/90 (2%) | 6/90 (7%) | 3/90 (3%)
Rate per litters | 2/35 (6%) | 2/35 (6%) | 5/35 (14%) | 3/35 (9%)
Adjusted rate | 3.0% | 2.7% | 7.7% | 3.9%
Terminal rate | 1/25 (4%) | 0/45 (0%) | 6/50 (12%) | 3/60 (5%)
First incidence (days) | 642 | 591 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.419 | P = 0.625N | P = 0.224 | P = 0.566
Litter C-A/Fisher’s test | P = 0.342 | P = 0.693 | P = 0.214 | P = 0.500
Prostate Gland: Adenoma or Carcinoma
Overall rate | 2/90 (2%) | 2/90 (2%) | 7/90 (8%) | 3/90 (3%)
Rate per litters | 2/35 (6%) | 2/35 (6%) | 6/35 (17%) | 3/35 (9%)
Adjusted rate | 3.0% | 2.7% | 9.0% | 3.9%
Terminal rate | 1/25 (4%) | 0/45 (0%) | 6/50 (12%) | 3/60 (5%)
First incidence (days) | 642 | 591 | 717 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.412 | P = 0.626N | P = 0.161 | P = 0.566
Litter C-A/Fisher’s test | P = 0.329 | P = 0.693 | P = 0.130 | P = 0.500
Skin: Keratoacanthoma
Overall rate | 5/90 (6%) | 3/90 (3%) | 9/90 (10%) | 2/90 (2%)
Rate per litters | 5/35 (14%) | 3/35 (9%) | 7/35 (20%) | 2/35 (6%)
Adjusted rate | 7.4% | 4.0% | 11.6% | 2.6%
Terminal rate | 0/25 (0%) | 2/45 (4%) | 9/50 (18%) | 2/60 (3%)
First incidence (days) | 552 | 694 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.271N | P = 0.332N | P = 0.322 | P = 0.208N
Litter C-A/Fisher’s test | P = 0.256N | P = 0.355N | P = 0.376 | P = 0.214N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 7/90 (8%) | 3/90 (3%) | 9/90 (10%) | 2/90 (2%)
Rate per litters | 7/35 (20%) | 3/35 (9%) | 7/35 (20%) | 2/35 (6%)
Adjusted rate | 10.4% | 4.0% | 11.6% | 2.6%
Terminal rate | 1/25 (4%) | 2/45 (4%) | 9/50 (18%) | 2/60 (3%)
First incidence (days) | 552 | 694 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.145N | P = 0.164N | P = 0.520 | P = 0.088N
Litter C-A/Fisher’s test | P = 0.113N | P = 0.153N | P = 0.617 | P = 0.075N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 8/90 (9%) | 4/90 (4%) | 10/90 (11%) | 3/90 (3%)
Rate per litters | 8/35 (23%) | 4/35 (11%) | 8/35 (23%) | 3/35 (9%)
Adjusted rate | 11.9% | 5.3% | 12.8% | 3.9%
Terminal rate | 2/25 (8%) | 3/45 (7%) | 10/50 (20%) | 2/60 (3%)
First incidence (days) | 552 | 694 | 730 (T) | 694
Rao-Scott adjusted Poly-3 test | P = 0.145N | P = 0.163N | P = 0.526 | P = 0.090N
Litter C-A/Fisher’s test | P = 0.132N | P = 0.171N | P = 0.612 | P = 0.094N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 2/90 (2%) | 5/90 (6%) | 7/90 (8%) | 5/90 (6%)
Rate per litters | 2/35 (6%) | 5/35 (14%) | 7/35 (20%) | 5/35 (14%)
Adjusted rate | 3.1% | 6.7% | 8.9% | 6.4%
Terminal rate | 2/25 (8%) | 3/45 (7%) | 4/50 (8%) | 2/60 (3%)
First incidence (days) | 730 (T) | 673 | 501 | 443
Rao-Scott adjusted Poly-3 test | P = 0.306 | P = 0.256 | P = 0.129 | P = 0.277
Litter C-A/Fisher’s test | P = 0.214 | P = 0.214 | P = 0.075 | P = 0.214
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, Sarcoma, Myxosarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 5/90 (6%) | 9/90 (10%) | 10/90 (11%) | 8/90 (9%)
Rate per litters | 5/35 (14%) | 9/35 (26%) | 10/35 (29%) | 8/35 (23%)
Adjusted rate | 7.5% | 11.7% | 12.6% | 10.0%
Terminal rate | 2/25 (8%) | 4/45 (9%) | 5/50 (10%) | 2/60 (3%)
First incidence (days) | 567 | 291 | 501 | 443
Rao-Scott adjusted Poly-3 test | P = 0.428 | P = 0.268 | P = 0.218 | P = 0.383
Litter C-A/Fisher’s test | P = 0.293 | P = 0.185 | P = 0.122 | P = 0.270
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, Sarcoma, Myxosarcoma, Malignant Fibrous Histiocytoma, or Hemangiopericytoma
Overall rate | 5/90 (6%) | 9/90 (10%) | 11/90 (12%) | 8/90 (9%)
Rate per litters | 5/35 (14%) | 9/35 (26%) | 11/35 (31%) | 8/35 (23%)
Adjusted rate | 7.5% | 11.7% | 13.8% | 10.0%
Terminal rate | 2/25 (8%) | 4/45 (9%) | 6/50 (12%) | 2/60 (3%)
First incidence (days) | 567 | 291 | 501 | 443
Rao-Scott adjusted Poly-3 test | P = 0.421 | P = 0.268 | P = 0.159 | P = 0.383
Litter C-A/Fisher’s test | P = 0.284 | P = 0.185 | P = 0.077 | P = 0.270
Thyroid Gland (C-cell): Adenoma
Overall rate | 8/89 (9%) | 9/89 (10%) | 8/89 (9%) | 8/87 (9%)
Rate per litters | 7/35 (20%) | 8/35 (23%) | 8/34 (24%) | 8/35 (23%)
Adjusted rate | 12.1% | 12.0% | 10.3% | 10.6%
Terminal rate | 6/25 (24%) | 8/45 (18%) | 6/50 (12%) | 8/60 (13%)
First incidence (days) | 498 | 576 | 636 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.416N | P = 0.581N | P = 0.460N | P = 0.481N
Litter C-A/Fisher’s test | P = 0.456 | P = 0.500 | P = 0.474 | P = 0.500
Thyroid Gland (C-cell): Adenoma or Carcinoma
Overall rate | 10/89 (11%) | 11/89 (12%) | 10/89 (11%) | 11/87 (13%)
Rate per litters | 8/35 (23%) | 8/35 (23%) | 9/34 (26%) | 11/35 (31%)
Adjusted rate | 14.9% | 14.6% | 12.9% | 14.5%
Terminal rate | 6/25 (24%) | 8/45 (18%) | 8/50 (16%) | 11/60 (18%)
First incidence (days) | 498 | 576 | 636 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.512N | P = 0.566N | P = 0.457N | P = 0.561N
Litter C-A/Fisher’s test | P = 0.214 | P = 0.612 | P = 0.472 | P = 0.296
All Organs: Malignant Schwannoma
Overall rate | 3/90 (3%) | 3/90 (3%) | 5/90 (6%) | 7/90 (8%)
Rate per litters | 3/35 (9%) | 3/35 (9%) | 5/35 (14%) | 7/35 (20%)
Adjusted rate | 4.5% | 4.0% | 6.4% | 8.9%
Terminal rate | 1/25 (4%) | 2/45 (4%) | 3/50 (6%) | 4/60 (7%)
First incidence (days) | 555 | 720 | 661 | 582
Rao-Scott adjusted Poly-3 test | P = 0.133 | P = 0.577N | P = 0.435 | P = 0.238
Litter C-A/Fisher’s test | P = 0.073 | P = 0.663 | P = 0.355 | P = 0.153
All Organs: Malignant Mesothelioma
Overall rate | 2/90 (2%) | 1/90 (1%) | 6/90 (7%) | 1/90 (1%)
Rate per litters | 2/35 (6%) | 1/35 (3%) | 6/35 (17%) | 1/35 (3%)
Adjusted rate | 3.0% | 1.3% | 7.6% | 1.3%
Terminal rate | 1/25 (4%) | 0/45 (0%) | 1/50 (2%) | 1/60 (2%)
First incidence (days) | 645 | 705 | 550 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.485N | P = 0.454N | P = 0.228 | P = 0.446N
Litter C-A/Fisher’s test | P = 0.544N | P = 0.500N | P = 0.130 | P = 0.500N
All Organs: Benign Neoplasms
Overall rate | 49/90 (54%) | 68/90 (76%) | 71/90 (79%) | 57/90 (63%)
Rate per litters | 26/35 (74%) | 33/35 (94%) | 35/35 (100%) | 32/35 (91%)
Adjusted rate | 65.3% | 80.3% | 83.5% | 69.2%
Terminal rate | 18/25 (72%) | 35/45 (78%) | 44/50 (88%) | 43/60 (72%)
First incidence (days) | 440 | 309 | 454 | 384
Rao-Scott adjusted Poly-3 test | P = 0.519 | P = 0.032 | P = 0.010 | P = 0.370
Litter C-A/Fisher’s test | P = 0.035 | P = 0.023 | P < 0.001 | P = 0.055
All Organs: Malignant Neoplasms
Overall rate | 24/90 (27%) | 36/90 (40%) | 38/90 (42%) | 35/90 (38%)
Rate per litters | 18/35 (51%) | 24/35 (69%) | 25/35 (71%) | 26/35 (74%)
Adjusted rate | 33.2% | 44.9% | 45.8% | 41.3%
Terminal rate | 5/25 (20%) | 15/45 (33%) | 17/50 (34%) | 23/60 (38%)
First incidence (days) | 212 | 291 | 537 | 472
Rao-Scott adjusted Poly-3 test | P = 0.276 | P = 0.100 | P = 0.081 | P = 0.197
Litter C-A/Fisher’s test | P = 0.042 | P = 0.111 | P = 0.070 | P = 0.041
All Organs: Benign or Malignant Neoplasms
Overall rate | 57/90 (63%) | 73/90 (81%) | 78/90 (87%) | 71/90 (79%)
Rate per litters | 29/35 (83%) | 33/35 (94%) | 35/35 (100%) | 35/35 (100%)
Adjusted rate | 72.8% | 84.5% | 89.3% | 83.0%
Terminal rate | 20/25 (80%) | 36/45 (80%) | 44/50 (88%) | 50/60 (83%)
First incidence (days) | 212 | 291 | 454 | 384
Rao-Scott adjusted Poly-3 test | P = 0.108 | P = 0.061 | P = 0.009 | P = 0.096
Litter C-A/Fisher’s test | P = 0.003 | P = 0.130 | P = 0.012 | P = 0.012

(T) = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, heart, pancreas, pancreatic islets, pituitary gland, prostate gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Number of litters with tumor-bearing animals/number of litters examined at site.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ The Litter Cochran-Armitage and Fishers exact tests directly compare the litter incidence rates.

^g^ Not applicable; no neoplasms in animal group.

Table A-3 Historical Incidence of Malignant Schwannoma in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Heart: Malignant Schwannoma | All Organs: Malignant Schwannoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50 | 1/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 1/50 | 2/50
Indole-3-carbinol (March 2007) | 1/50 | 0/50
Radiofrequency radiation (September 2012) | 0/90 | 3/90
Overall Historical Incidence
Total (%) | 2/240 (0.8%) | 6/240 (2.5%)
Mean ± standard deviation | 0.6% ± 1.1% | 2.3% ± 1.8%
Range | 0%–2% | 0%–4%

^a^ Data as of November 2017.

Table A-4 Historical Incidence of Brain Neoplasms in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Malignant Glioma | Benign Granular Cell Tumor | Malignant Granular Cell Tumor | Benign or Malignant Granular Cell Tumor
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 2/50 | 0/50 | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50 | 2/50 | 0/50 | 2/50
Radiofrequency radiation (September 2012) | 0/90 | 1/90 | 0/90 | 1/90
Overall Historical Incidence:
Total (%) | 2/190 (1.1%) | 3/190 (1.6%) | 0/190 | 3/190 (1.6%)
Mean ± standard deviation | 1.3% ± 2.3% | 1.7% ± 2.1% | – | 1.7% ± 2.1%
Range | 0%–4% | 0%–4% | – | 0%–4%

^a^ Data as of November 2017; due to differences in sectioning method, indole-3-carbinol was excluded from evaluation of brain lesions.

Table A-5 Historical Incidence of Adrenal Medulla Neoplasms in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Benign Pheochromocytoma | Malignant Pheochromocytoma | Complex Pheochromocytoma | Benign, Malignant, or Complex Pheochromocytoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 12/50 | 2/50 | 0/50 | 14/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 9/50 | 3/50 | 0/50 | 12/50
Indole-3-carbinol (March 2007) | 5/50 | 2/50 | 1/50 | 8/50
Radiofrequency radiation (September 2012) | 10/88 | 1/88 | 1/88 | 11/88
Overall Historical Incidence
Total (%) | 36/238 (15.1%) | 8/238 (3.4%) | 2/238 (0.8%) | 45/238 (18.9%)
Mean ± standard deviation | 15.8% ± 6.5% | 3.8% ± 2.0% | 0.8% ± 1.0% | 20.1% ± 7.1%
Range | 10%–24% | 1%–6% | 0%–2% | 13%–28%

^a^ Data as of November 2017.

Table A-6 Historical Incidence of Prostate Gland Neoplasms in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 0/50 | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 0/50 | 0/50 | 0/50
Indole-3-carbinol (March 2007) | 0/50 | 0/50 | 0/50
Radiofrequency radiation (September 2012) | 2/90 | 0/90 | 2/90
Overall Historical Incidence
Total (%) | 2/240 (0.8%) | 0/240 | 2/240 (0.8%)
Mean ± standard deviation | 0.6% ± 1.1% | – | 0.6% ± 1.1%
Range | 0%–2% | – | 0%–2%

^a^ Data as of November 2017.

Table A-7 Historical Incidence of Pituitary Gland (Pars Distalis) Adenoma in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 11/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 14/50
Indole-3-carbinol (March 2007) | 5/50
Radiofrequency radiation (September 2012) | 17/89
Overall Historical Incidence
Total (%) | 47/239 (19.7%)
Mean ± standard deviation | 19.8% ± 7.5%
Range | 10%–28%

^a^ Data as of November 2017.

Table A-8 Historical Incidence of Pancreatic Islet Neoplasms in Control Male Hsd:Sprague Dawley^®^ SD^®^ Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 8/50 | 0/50 | 8/50
2-Hydroxy-4-methoxybenzophenone (November 2010) | 3/50 | 0/50 | 3/50
Indole-3-carbinol (March 2007) | 2/50 | 0/50 | 2/50
Radiofrequency radiation (September 2012) | 5/90 | 8/90 | 13/90
Overall Historical Incidence
Total (%) | 18/240 (7.5%) | 8/240 (3.3%) | 26/240 (10.8%)
Mean ± standard deviation | 7.9% ± 5.5% | 2.2% ± 4.4% | 10.1% ± 6.0%
Range | 4%–16% | 0%–9% | 4%–16%

^a^ Data as of November 2017.

Table A-9 Summary of the Incidence of Non-neoplastic Lesions in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 1 | – | – | 1
Moribund | 44 | 24 | 19 | 13
Natural deaths | 20 | 21 | 21 | 16
Survivors
Terminal euthanasia | 25 | 45 | 50 | 60
Animals examined microscopically | 100 | 100 | 100 | 100
Fourteen-week Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Lymphoid tissue, hyperplasia | 1 (10%) | 1 (10%) | – | –
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, mixed cell | 1 (10%) | – | 3 (30%) | 3 (30%)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Cardiovascular System
Aorta | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | 2 (20%) | 4 (40%) | 3 (30%) | 4 (40%)
Ventricle right, cardiomyopathy | 1 (10%) | 1 (10%) | 5 (50%) | 5 (50%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (9) | (10) | (10) | (8)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | – | 1 (10%) | 2 (20%) | 2 (20%)
Rathke’s cleft, cyst | – | 1 (10%) | 3 (30%) | 3 (30%)
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | – | 1 (10%) | 1 (10%) | 2 (20%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Preputial gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 7 (70%) | 3 (30%) | 1 (10%) | 4 (40%)
Prostate | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | 1 (10%) | 1 (10%) | –
Seminal vesicle | (10) | (10) | (10) | (10)
Testis | (10) | (10) | (10) | (10)
Germ cell, degeneration | – | – | – | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hemorrhage | 2 (20%) | 2 (20%) | 2 (20%) | 1 (10%)
Hyperplasia, lymphocyte | – | – | – | 4 (40%)
Proliferation, plasma cell | – | – | – | 2 (20%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Hemorrhage | – | 2 (20%) | – | –
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Hemorrhage | 5 (50%) | 1 (10%) | 2 (20%) | –
Musculoskeletal System
Bone | (10) | (10) | (10) | (10)
Tibia, fracture, chronic | – | – | – | 1 (10%)
Skeletal muscle | (10) | (10) | (10) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | – | – | 1 (10%) | –
Inflammation, chronic active | 1 (10%) | 1 (10%) | – | –
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Retina, developmental malformation | – | – | – | 1 (10%)
Harderian gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | 3 (30%) | 2 (20%) | 2 (20%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Congestion | – | – | 1 (10%) | –
Nephropathy, chronic progressive | 9 (90%) | 8 (80%) | 8 (80%) | 7 (70%)
Pelvis, dilation | – | – | 1 (10%) | –
Renal tubule, dilation | – | 1 (10%) | – | –
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined with No Lesions Observed
General Body System
Integumentary System
Nervous System
Two-year Study
Alimentary System
Esophagus | (90) | (89) | (90) | (90)
Dilation | 2 (2%) | – | – | –
Hyperplasia | 1 (1%) | – | – | –
Arteriole, inflammation, chronic active | – | 1 (1%) | – | –
Artery, inflammation, chronic active | – | – | 1 (1%) | –
Intestine large, cecum | (75) | (75) | (79) | (80)
Edema | 11 (15%) | 1 (1%) | – | 4 (5%)
Erosion | 10 (13%) | | – | 3 (4%)
Inflammation, acute | 10 (13%) | 1 (1%) | – | 2 (3%)
Inflammation, chronic active | 1 (1%) | – | – | –
Ulcer | 6 (8%) | – | – | –
Artery, inflammation, chronic active | 20 (27%) | 9 (12%) | 5 (6%) | 6 (8%)
Artery, mineral | 1 (1%) | – | – | –
Epithelium, erosion | – | – | – | 1 (1%)
Epithelium, regeneration | 14 (19%) | – | – | 2 (3%)
Intestine large, colon | (81) | (83) | (81) | (82)
Edema | – | 1 (1%) | | 1 (1%)
Erosion | 1 (1%) | – | – | 1 (1%)
Inflammation, acute | 1 (1%) | – | – | –
Ulcer | 1 (1%) | – | – | –
Artery, inflammation, chronic active | 12 (15%) | 5 (6%) | 5 (6%) | 5 (6%)
Artery, mineral | 2 (2%) | – | – | –
vEpithelium, regeneration | 5 (6%) | – | – | 2 (2%)
Intestine large, rectum | (83) | (81) | (85) | (87)
Cyst | – | – | 1 (1%) | –
Edema | 1 (1%) | – | – | 1 (1%)
Erosion | 1 (1%) | – | – | –
Hyperplasia, lymphocyte | 1 (1%) | 1 (1%) | – | –
Inflammation, acute | 2 (2%) | – | – | –
vArtery, inflammation, chronic active | 4 (5%) | 7 (9%) | 4 (5%) | 2 (2%)
Epithelium, regeneration | 3 (4%) | – | – | –
Intestine small, duodenum | (81) | (82) | (79) | (79)
Dilation | – | – | 1 (1%) | –
Erosion | 1 (1%) | – | – | –
Ulcer | 1 (1%) | – | – | –
Intestine small, ileum | (78) | (76) | (78) | (76)
Artery, inflammation, chronic active | 2 (3%) | 1 (1%)
Epithelium, regeneration | 1 (1%) | – | – | –
Intestine small, jejunum | (73) | (76) | (70) | (76)
Dilation | – | – | 1 (1%) | –
Liver | (90) | (90) | (90) | (90)
Angiectasis | 1 (1%) | – | 1 (1%) | –
Basophilic focus | 1 (1%) | 1 (1%) | – | –
Clear cell focus | 8 (9%) | 7 (8%) | 22 (24%) | 16 (18%)
Eosinophilic focus | 12 (13%) | 5 (6%) | 2 (2%) | 8 (9%)
Extramedullary hematopoiesis | 5 (6%) | 4 (4%) | 1 (1%) | 4 (4%)
Hepatodiaphragmatic nodule | 1 (1%) | – | 2 (2%) | 2 (2%)
Infiltration cellular, mixed cell | 3 (3%) | 2 (2%) | – | 5 (6%)
Mixed cell focus | 32 (36%) | 45 (50%) | 50 (56%) | 58 (64%)
Artery, inflammation, chronic active | 2 (2%) | 5 (6%) | 1 (1%) | –
Artery, mineral | 1 (1%) | – | – | –
Artery, thrombus | – | 1 (1%) | – | –
Bile duct, cyst | 3 (3%) | 3 (3%) | 2 (2%) | –
Bile duct, fibrosis | – | – | – | 1 (1%)
Bile duct, hyperplasia | 41 (46%) | 35 (39%) | 37 (41%) | 33 (37%)
Centrilobular, hepatocyte, hypertrophy | | 1 (1%) | – | –
Hepatocyte, degeneration | 1 (1%) | – | – | –
Hepatocyte, degeneration, cystic | – | – | 1 (1%) | –
Hepatocyte, necrosis | 5 (6%) | 6 (7%) | 8 (9%) | 1 (1%)
Hepatocyte, vacuolation, cytoplasmic | 6 (7%) | 4 (4%) | 9 (10%) | 3 (3%)
Kupffer cell, pigment | 1 (1%) | 1 (1%) | | 1 (1%)
Periductal, cholangiofibrosis | 2 (2%) | 1 (1%) | 1 (1%) | 1 (1%)
Mesentery | (39) | (19) | (17) | (7)
Hemorrhage | 1 (3%) | – | – | –
Inflammation, chronic | 2 (5%) | – | – | –
Inflammation, chronic active | – | 1 (5%) | – | –
Necrosis | 2 (5%) | 3 (16%) | 1 (6%) | –
vNeovascularization | 1 (3%) | 1 (5%) | – | –
Arteriole, inflammation, chronic active | – | 1 (5%) | – | –
Artery, inflammation, chronic active | 32 (82%) | 12 (63%) | 14 (82%) | 5 (71%)
Artery, mineral | 21 (54%) | 4 (21%) | 5 (29%) | 2 (29%)
Vein, degeneration | 1 (3%) | – | – | –
Vein, inflammation, chronic active | 1 (3%) | 1 (5%) | – | 1 (14%)
Oral mucosa | (0) | (2) | (0) | (2)
Hyperplasia | – | – | – | 1 (50%)
Ulcer | – | 1 (50%) | – | –
Pancreas | (90) | (89) | (88) | (86)
Cyst | 1 (1%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (1%)
Thrombus | 1 (1%) | – | – | –
Acinus, atrophy | 13 (14%) | 16 (18%) | 10 (11%) | 11 (13%)
Acinus, hyperplasia | 63 (70%) | 58 (65%) | 44 (50%) | 32 (37%)
Artery, inflammation, chronic active | 48 (53%) | 28 (31%) | 26 (30%) | 14 (16%)
Artery, mineral | 11 (12%) | 3 (3%) | 3 (3%) | 1 (1%)
Salivary glands | (90) | (90) | (90) | (90)
Inflammation, chronic active | – | 1 (1%) | – | –
Artery, inflammation, chronic active | 11 (12%) | 7 (8%) | 3 (3%) | 1 (1%)
Artery, mineral | 2 (2%) | – | – | –
Duct, parotid gland, dilation | 5 (6%) | 3 (3%) | 1 (1%) | 4 (4%)
Duct, parotid gland, inflammation, acute | 1 (1%) | – | – | –
Parotid gland, atrophy | 18 (20%) | 16 (18%) | 14 (16%) | 14 (16%)
Parotid gland, inflammation, acute | 2 (2%) | 7 (8%) | 3 (3%) | 1 (1%)
Parotid gland, vacuolation, cytoplasmic | 1 (1%) | – | – | –
Sublingual gland, inflammation, acute | – | – | 1 (1%) | –
Submandibular gland, atrophy | – | 1 (1%) | 1 (1%) | –
Stomach, forestomach | (90) | (90) | (90) | (90)
Cyst | – | 1 (1%) | – | –
Edema | 5 (6%) | 11 (12%) | 3 (3%) | 2 (2%)
Erosion | – | 1 (1%) | 1 (1%)
Fibrosis | – | – | – | 1 (1%)
Inflammation, acute | 1 (1%) | 1 (1%) | – | –
Inflammation, chronic active | 7 (8%) | 14 (16%) | 5 (6%) | 6 (7%)
Mineral | 1 (1%) | – | 1 (1%) | –
Necrosis | – | – | – | 1 (1%)
Ulcer | 6 (7%) | 8 (9%) | 3 (3%) | 2 (2%)
Artery, inflammation, chronic active | | 4 (4%) | 3 (3%) | –
Epithelium, degeneration | – | 1 (1%) | – | –
Epithelium, hyperplasia | 11 (12%) | 21 (23%) | 12 (13%) | 11 (12%)
Epithelium, hyperplasia, atypical | 1 (1%) | – | – | –
Epithelium, hyperplasia, basal cell | – | – | 1 (1%) | –
Stomach, glandular | (86) | (88) | (87) | (86)
Erosion | 3 (3%) | – | 2 (2%) | 1 (1%)
Hemorrhage | – | – | 1 (1%) | –
Inflammation, granulomatous | – | 1 (1%) | – | –
Inflammation, acute | 1 (1%) | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | 3 (3%) | – | –
Mineral | 31 (36%) | 7 (8%) | 8 (9%) | 4 (5%)
Ulcer | – | – | 1 (1%) | –
Artery, inflammation, chronic active | 3 (3%) | 2 (2%) | 2 (2%) | 1 (1%)
Tooth | (0) | (1) | (1) | (0)
Dysplasia | – | 1 (100%) | – | –
Cardiovascular System
Aorta | (90) | (90) | (90) | (90)
Aneurysm | – | 1 (1%) | – | –
Dilation | – | 1 (1%) | 3 (3%) | –
Mineral | 30 (33%) | 7 (8%) | 12 (13%) | 6 (7%)
Blood vessel | (1) | (2) | (1) | (0)
Mineral | 1 (100%) | – | – | –
Pulmonary artery, inflammation, chronic active | – | 1 (50%) | 1 (100%) | –
Pulmonary artery, necrosis | – | 1 (50%) | 1 (100%) | –
Heart | (90) | (90) | (90) | (90)
Cardiomyopathy | 79 (88%) | 82 (91%) | 78 (87%) | 79 (88%)
Congestion | 1 (1%) | – | – | –
Hemorrhage | | – | – | 1 (1%)
Thrombus | 1 (1%) | – | – | –
Artery, infiltration cellular, histiocyte | – | – | 1 (1%) | –
Artery, inflammation, chronic active | – | 5 (6%) | 4 (4%) | 2 (2%)
Artery, mineral | 20 (22%) | 7 (8%) | 3 (3%) | 2 (2%)
Artery, necrosis | – | 1 (1%) | – | –
Atrium, dilation | 3 (3%) | – | 1 (1%) | –
Atrium, thrombus | 1 (1%) | 1 (1%) | – | –
Atrium, myocardium, hypertrophy | 1 (1%) | – | – | –
Endocardium, hyperplasia, Schwann cell | – | 1 (1%) | – | 2 (2%)
Myocardium, mineral | 9 (10%) | 2 (2%) | 4 (4%) | 1 (1%)
Myocardium, necrosis | 1 (1%) | – | – | –
Valve, inflammation, chronic active | 1 (1%) | – | – | –
Ventricle right, cardiomyopathy | 54 (60%) | 62 (69%) | 72 (80%) | 74 (82%)
Endocrine System
Adrenal cortex | (90) | (90) | (90) | (88)
Accessory adrenal cortical nodule | 6 (7%) | 7 (8%) | 6 (7%) | 4 (5%)
Angiectasis | – | – | 1 (1%) | 2 (2%)
Atrophy | – | – | 1 (1%) | 1 (1%)
Congestion | – | – | 1 (1%) | –
Degeneration | 3 (3%) | – | – | –
Degeneration, cystic | – | – | 2 (2%) | 2 (2%)
Hemorrhage | – | – | 1 (1%) | –
Hyperplasia | 47 (52%) | 46 (51%) | 46 (51%) | 45 (51%)
Hypertrophy | 35 (39%) | 43 (48%) | 50 (56%) | 54 (61%)
Necrosis | 5 (6%) | 3 (3%) | 4 (4%) | –
Thrombus | 2 (2%) | 1 (1%) | – | –
Vacuolation, cytoplasmic | 20 (22%) | 32 (36%) | 25 (28%) | 22 (25%)
Adrenal medulla | (88) | (90) | (89) | (87)
Degeneration, cystic | – | 1 (1%) | – | –
Hyperplasia | 42 (48%) | 24 (27%) | 26 (29%) | 35 (40%)
Thrombus | 1 (1%) | – | – | –
Islets, pancreatic | (90) | (89) | (86) | (85)
Hyperplasia | 12 (13%) | 5 (6%) | 5 (6%) | 7 (8%)
Parathyroid gland | (83) | (87) | (87) | (81)
Cyst | – | – | – | 1 (1%)
Hyperplasia | 51 (61%) | 35 (40%) | 46 (53%) | 28 (35%)
Hyperplasia, focal | – | – | 2 (2%) | 1 (1%)
Pituitary gland | (89) | (90) | (90) | (90)
Necrosis | – | – | 1 (1%) | –
Craniopharyngeal duct, cyst | 1 (1%) | – | – | –
Pars distalis, cyst | 5 (6%) | 9 (10%) | 15 (17%) | 16 (18%)
Pars distalis, hyperplasia | 32 (36%) | 34 (38%) | 35 (39%) | 32 (36%)
Pars distalis, necrosis | – | – | – | 1 (1%)
Pars intermedia, angiectasis | 1 (1%) | – | – | –
Pars intermedia, cyst | 6 (7%) | 5 (6%) | 9 (10%) | 6 (7%)
Pars intermedia, hyperplasia | 1 (1%) | 1 (1%) | 2 (2%) | 2 (2%)
Pars nervosa, cyst | – | 1 (1%) | – | –
Pars nervosa, developmental malformation | – | – | 1 (1%) | 1 (1%)
Pars nervosa, infiltration cellular, mixed cell | – | – | – | 1 (1%)
Thyroid gland | (89) | (89) | (89) | (87)
Congestion | – | – | – | 1 (1%)
Ectopic thymus | – | – | 1 (1%) | –
C-cell, hyperplasia | 16 (18%) | 24 (27%) | 18 (20%) | 14 (16%)
Follicle, cyst | – | 1 (1%) | 1 (1%) | 1 (1%)
Follicle, hyperplasia, cystic | 1 (1%) | – | – | –
Follicular cell, hyperplasia | – | 1 (1%) | – | –
Follicular cell, hypertrophy | – | 1 (1%) | – | 1 (1%)
General Body System
Tissues NOS | (3) | (4) | (4) | (5)
Inflammation, chronic active | – | 1 (25%) | – | –
Abdominal, fat, hemorrhage | 1 (33%) | – | – | –
Abdominal, fat, inflammation, chronic active | – | 1 (25%) | – | –
Fat, necrosis | 2 (67%) | – | 2 (50%) | 3 (60%)
Mediastinum, inflammation, chronic active | – | – | 1 (25%) | 1 (20%)
Genital System
Bulbourethral gland | (1) | (0) | (0) | (0)
Coagulating gland | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Ductus deferens | (1) | (0) | (0) | (0)
Granuloma | 1 (100%) | – | – | –
Epididymis | (90) | (90) | (90) | (90)
Exfoliated germ cell | 51 (57%) | 26 (29%) | 29 (32%) | 15 (17%)
Granuloma sperm | 1 (1%) | – | – | –
Hypospermia | 28 (31%) | 20 (22%) | 23 (26%) | 8 (9%)
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Artery, inflammation, chronic active | 2 (2%) | 2 (2%) | 1 (1%) | 2 (2%)
Penis | (0) | (0) | (0) | (1)
Preputial gland | (88) | (90) | (90) | (90)
Atrophy | 1 (1%) | – | – | –
Hyperplasia | 1 (1%) | – | – | –
Inflammation, suppurative | | 1 (1%) | 3 (3%) | –
Inflammation, granulomatous | 1 (1%) | – | – | –
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic active | 46 (52%) | 48 (53%) | 54 (60%) | 52 (58%)
Artery, inflammation, chronic active | 1 (1%) | – | – | 1 (1%)
Duct, dilation | 51 (58%) | 53 (59%) | 49 (54%) | 51 (57%)
Duct, hyperplasia | – | 1 (1%) | – | 1 (1%)
Duct, mineral | – | – | – | 1 (1%)
Prostate | (90) | (90) | (90) | (90)
Decreased secretory fluid | 4 (4%) | 6 (7%) | 6 (7%) | 2 (2%)
Hemorrhage | 1 (1%) | – | – | –
Inflammation cellular, mononuclear cell | 1 (1%) | – | – | 1 (1%)
Inflammation, suppurative | – | 1 (1%) | 1 (1%) | –
Inflammation, acute | 7 (8%) | 3 (3%) | 6 (7%) | 4 (4%)
Inflammation, chronic active | 6 (7%) | 15 (17%) | 9 (10%) | 13 (14%)
Artery, inflammation, chronic active | 1 (1%) | 1 (1%) | 1 (1%) | –
Epithelium, hyperplasia | 5 (6%) | 13 (14%) | 11 (12%) | 11 (12%)
Seminal vesicle | (90) | (89) | (89) | (90)
Decreased secretory fluid | 35 (39%) | 18 (20%) | 22 (25%) | 11 (12%)
Degeneration | – | – | – | 1 (1%)
Hemorrhage | 1 (1%) | – | – | –
Inflammation, acute | 4 (4%) | – | 3 (3%) | 1 (1%)
Inflammation, chronic | – | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | 4 (4%) | 1 (1%) | 1 (1%)
vArtery, inflammation, chronic active | 1 (1%) | 1 (1%) | – | –
Epithelium, hyperplasia | 1 (1%) | – | – | –
Testis | (90) | (90) | (90) | (90)
Cyst | 1 (1%) | – | – | –
vEdema | – | 2 (2%) | 3 (3%) | 2 (2%)
Inflammation, chronic active | 2 (2%) | – | – | –
Pigment | 1 (1%) | – | – | –
Artery, inflammation, chronic active | 52 (58%) | 40 (44%) | 37 (41%) | 20 (22%)
Germ cell, degeneration | 51 (57%) | 35 (39%) | 42 (47%) | 20 (22%)
Germinal epithelium, mineral | – | 1 (1%) | – | –
Interstitial cell, hyperplasia | 1 (1%) | 2 (2%) | – | 4 (4%)
Rete testis, dilation | 1 (1%) | – | – | –
Seminiferous tubule, dilation | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Tunic, hemorrhage | – | 1 (1%) | – | –
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Fibrosis | – | – | – | 1 (1%)
Hemorrhage | – | 1 (1%) | 3 (3%) | –
Hypercellularity | 15 (17%) | 42 (47%) | 32 (36%) | 23 (26%)
Lymph node | (25) | (22) | (18) | (12)
Artery, mediastinal, inflammation, chronic active | – | 1 (5%) | – | 1 (8%)
Artery, mediastinal, mineral | – | 1 (5%) | – | –
Bronchial, erythrophagocytosis | – | – | 3 (17%) | –
Iliac, erythrophagocytosis | 2 (8%) | 2 (9%) | 1 (6%) | –
Iliac, hyperplasia, lymphocyte | 2 (8%) | – | – | 1 (8%)
Iliac, infiltration cellular, histiocyte | 2 (8%) | – | 1 (6%)
Iliac, pigment | – | – | 1 (6%) | –
Iliac, proliferation, plasma cell | 3 (12%) | 1 (5%) | 1 (6%) | 2 (17%)
Iliac, lymphatic sinus, ectasia | 5 (20%) | 2 (9%) | – | 1 (8%)
Lumbar, erythrophagocytosis | 2 (8%) | 1 (5%) | 1 (6%) | 1 (8%)
Lumbar, hemorrhage | – | 1 (5%) | – | –
Lumbar, hyperplasia, lymphocyte | – | 1 (5%) | – | 1 (8%)
Lumbar, proliferation, plasma cell | – | 1 (5%) | – | 1 (8%)
Lumbar, lymphatic sinus, ectasia | – | 2 (9%) | 1 (6%) | –
Lymphatic sinus, mediastinal, ectasia | 1 (4%) | 1 (5%) | – | 1 (8%)
Lymphatic sinus, renal, ectasia | – | 3 (14%) | 1 (6%) | 1 (8%)
Mediastinal, congestion | – | – | 2 (11%) | –
Mediastinal, erythrophagocytosis | 6 (24%) | 5 (23%) | 5 (28%) | 6 (50%)
Mediastinal, hemorrhage | 1 (4%) | 1 (5%) | – | –
Mediastinal, infiltration cellular, histiocyte | – | 1 (5%) | – | –
Pancreatic, erythrophagocytosis | 3 (12%) | 1 (5%) | – | 2 (17%)
Pancreatic, hemorrhage | 1 (4%) | – | – | –
Pancreatic, hyperplasia, lymphocyte | 1 (4%) | – | – | –
Pancreatic, proliferation, plasma cell | – | – | 1 (6%) | –
Renal, erythrophagocytosis | 8 (32%) | 4 (18%) | 3 (17%) | 1 (8%)
Renal, hemorrhage | – | 1 (5%) | – | –
Renal, hyperplasia, lymphocyte | – | 1 (5%) | – | 1 (8%)
Renal, proliferation, plasma cell | 2 (8%) | – | – | 1 (8%)
Lymph node, mandibular | (89) | (90) | (89) | (90)
Atrophy, lymphoid | – | 1 (1%) | – | –
Congestion | – | – | – | 3 (3%)
Erythrophagocytosis | – | 2 (2%) | 4 (4%) | 3 (3%)
Hemorrhage | – | 1 (1%) | – | –
Hyperplasia, lymphocyte | 41 (46%) | 50 (56%) | 54 (61%) | 57 (63%)
Infiltration cellular, histiocyte | – | – | – | 1 (1%)
Infiltration cellular, polymorphonuclear | 2 (2%) | – | – | –
Inflammation, suppurative | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | – | 1 (1%)
Pigment | – | – | 1 (1%) | 1 (1%)
Proliferation, plasma cell | 49 (55%) | 67 (74%) | 69 (78%) | 68 (76%)
Lymphatic sinus, ectasia | 16 (18%) | 12 (13%) | 20 (22%) | 16 (18%)
Lymph node, mesenteric | (90) | (89) | (86) | (89)
Atrophy | – | 1 (1%) | – | –
Depletion cellular | – | – | 1 (1%) | –
Erythrophagocytosis | 17 (19%) | 7 (8%) | 7 (8%) | 8 (9%)
vHyperplasia, lymphocyte | 2 (2%) | – | 1 (1%) | 4 (4%)
Infiltration cellular, histiocyte | 1 (1%) | – | 1 (1%) | –
Infiltration cellular, polymorphonuclear | 2 (2%) | – | – | –
Proliferation, plasma cell | – | – | – | 1 (1%)
Artery, inflammation, chronic active | – | – | 1 (1%) | –
Lymphatic sinus, ectasia | – | 3 (3%) | 2 (2%) | 1 (1%)
Lymphocyte, depletion | 2 (2%) | – | – | –
Spleen | (90) | (90) | (89) | (90)
Congestion | – | – | – | 1 (1%)
Developmental malformation | 1 (1%) | – | – | –
Erythrophagocytosis | – | – | – | 1 (1%)
Extramedullary hematopoiesis | 45 (50%) | 58 (64%) | 56 (63%) | 64 (71%)
Hemorrhage | – | – | 2 (2%) | –
Hyperplasia, lymphocyte | 5 (6%) | 2 (2%) | 2 (2%)
Hyperplasia, plasma cell | – | – | 1 (1%) | 2 (2%)
Pigment | 57 (63%) | 62 (69%) | 74 (83%) | 74 (82%)
Arteriole, mineral | 1 (1%) | – | – | –
Artery, inflammation, chronic active | – | 1 (1%) | 4 (4%) | 1 (1%)
Artery, mineral | – | – | 1 (1%) | –
Capsule, fibrosis | – | 1 (1%) | – | –
Red pulp, atrophy | 26 (29%) | 10 (11%) | 10 (11%) | 3 (3%)
White pulp, atrophy | 30 (33%) | 16 (18%) | 13 (15%) | 11 (12%)
Thymus | (88) | (86) | (88) | (86)
Atrophy | 79 (90%) | 71 (83%) | 75 (85%) | 78 (91%)
Congestion | – | – | – | 1 (1%)
Cyst | 10 (11%) | 10 (12%) | 9 (10%) | 10 (12%)
Ectopic parathyroid gland | 6 (7%) | 1 (1%) | 2 (2%) | 3 (3%)
Ectopic thyroid | 1 (1%) | 4 (5%) | – | 2 (2%)
Hemorrhage | 2 (2%) | 2 (2%) | 2 (2%) | 2 (2%)
Hyperplasia, epithelial | 2 (2%) | 4 (5%) | 2 (2%) | 2 (2%)
Thrombus | – | – | 2 (2%) | –
Artery, inflammation, chronic active | 6 (7%) | 3 (3%) | 2 (2%) | 1 (1%)
Integumentary System
Mammary gland | (82) | (76) | (82) | (82)
Atrophy | 1 (1%) | – | 2 (2%) | –
Galactocele | 1 (1%) | – | – | –
Hyperplasia | – | 2 (3%) | 5 (6%) | 2 (2%)
Inflammation, granulomatous | – | 1 (1%) | – | –
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Duct, dilation | 3 (4%) | 13 (17%) | 3 (4%) | 13 (16%)
Skin | (90) | (90) | (90) | (90)
Cyst epithelial inclusion | 3 (3%) | 6 (7%) | 8 (9%) | 10 (11%)
Cyst epithelial inclusion, multifocal | – | – | – | 1 (1%)
Hyperkeratosis | – | 1 (1%) | 2 (2%) | –
Inflammation, chronic | – | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | 1 (1%) | 2 (2%) | 1 (1%)
Ulcer | 2 (2%) | 3 (3%) | 2 (2%) | –
Artery, subcutaneous tissue, inflammation, chronic active | 1 (1%) | – | – | –
Epidermis, hyperplasia | 1 (1%) | 2 (2%) | 2 (2%) | 1 (1%)
Hair follicle, atrophy | – | 1 (1%) | 1 (1%)
Hair follicle, dilation | – | – | – | 1 (1%)
Lip, subcutaneous tissue, foreign body | – | – | – | 1 (1%)
Lip, subcutaneous tissue, inflammation, chronic active | – | – | – | 1 (1%)
Prepuce, cyst epithelial inclusion | – | 1 (1%) | – | –
Subcutaneous tissue, degeneration | – | 1 (1%) | – | –
Subcutaneous tissue, fibrosis | – | – | – | 1 (1%)
vSubcutaneous tissue, inflammation, suppurative | 1 (1%) | – | – | –
Subcutaneous tissue, inflammation, acute | | 1 (1%) | – | –
Subcutaneous tissue, inflammation, chronic | 1 (1%) | – | – | –
Subcutaneous tissue, inflammation, chronic active | – | 2 (2%) | 1 (1%) | 2 (2%)
Musculoskeletal System
Bone | (90) | (90) | (90) | (90)
Fibrous osteodystrophy | 46 (51%) | 18 (20%) | 14 (16%) | 6 (7%)
Increased bone | – | – | – | 1 (1%)
Skeletal muscle | (90) | (90) | (90) | (90)
Degeneration | 34 (38%) | 49 (54%) | 43 (48%) | 37 (41%)
Mineral | 2 (2%) | – | – | –
Nervous System
Brain | (90) | (90) | (90) | (90)
Compression | 7 (8%) | 9 (10%) | 4 (4%) | 10 (11%)
Cyst | – | 1 (1%) | 1 (1%) | 1 (1%)
Edema | – | 2 (2%) | 1 (1%) | –
Hemorrhage | 2 (2%) | 1 (1%) | 2 (2%) | –
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Mineral | 5 (6%) | 4 (4%) | 6 (7%) | 2 (2%)
Necrosis | 7 (8%) | 3 (3%) | 4 (4%) | 3 (3%)
Vacuolation, cytoplasmic | – | 1 (1%) | – | –
Brain stem, hemorrhage | – | – | 1 (1%) | –
Cerebellum, atrophy | – | – | – | 2 (2%)
Choroid plexus, degeneration | 1 (1%) | – | – | –
Choroid plexus, mineral | 3 (3%) | 1 (1%) | – | –
Glial cell, hyperplasia | – | 2 (2%) | 3 (3%) | 1 (1%)
Meninges, hyperplasia | 1 (1%) | – | – | –
Meninges, hyperplasia, granular cell | 1 (1%) | – | 1 (1%) | –
Meninges, metaplasia, osseous | – | – | 1 (1%) | –
Meninges, mineral | – | 1 (1%) | – | –
Perivascular, infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Pineal gland, infiltration cellular, mononuclear cell | – | – | 1 (1%) | 1 (1%)
Pineal gland, mineral | 3 (3%) | 10 (11%) | 8 (9%) | 3 (3%)
Pineal gland, vacuolation, cytoplasmic | 12 (13%) | 19 (21%) | 20 (22%) | 13 (14%)
Nerve trigeminal | (84) | (88) | (87) | (88)
Degeneration | 63 (75%) | 69 (78%) | 65 (75%) | 63 (72%)
Peripheral nerve, sciatic | (90) | (90) | (90) | (90)
Degeneration | 86 (96%) | 88 (98%) | 90 (100%) | 87 (97%)
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Peripheral nerve, tibial | (88) | (89) | (90) | (88)
Degeneration | 84 (95%) | 84 (94%) | 90 (100%) | 85 (97%)
Spinal cord, cervical | (90) | (90) | (90) | (90)
Degeneration | 30 (33%) | 38 (42%) | 41 (46%) | 32 (36%)
Spinal cord, lumbar | (90) | (90) | (90) | (90)
Degeneration | 21 (23%) | 10 (11%) | 17 (19%) | 12 (13%)
Nerve, degeneration | 79 (88%) | 82 (91%) | 87 (97%) | 81 (90%)
Spinal cord, thoracic | (90) | (90) | (90) | (90)
Degeneration | 58 (64%) | 68 (76%) | 72 (80%) | 69 (77%)
Hemorrhage, focal | 1 (1%) | – | – | –
Trigeminal ganglion | (75) | (73) | (77) | (77)
Degeneration | 23 (31%) | 25 (34%) | 22 (29%) | 15 (19%)
Respiratory System
Lung | (90) | (90) | (90) | (90)
Congestion | 13 (14%) | 15 (17%) | 11 (12%) | 10 (11%)
Cyst | – | 1 (1%) | – | –
Fibrosis | – | 1 (1%) | – | –
Foreign body | 4 (4%) | – | 2 (2%) | 1 (1%)
Hemorrhage | 3 (3%) | 4 (4%) | 3 (3%)
vInflammation, suppurative | 3 (3%) | 1 (1%) | 2 (2%) | 1 (1%)
Inflammation, granulomatous | – | – | 3 (3%) | –
Inflammation, chronic active | 2 (2%) | 8 (9%) | 5 (6%) | 3 (3%)
Inflammation, subacute | 2 (2%) | – | – | –
Mineral | – | – | 1 (1%) | –
Alveolar epithelium, hyperplasia | – | – | 1 (1%) | –
Alveolus, infiltration cellular, histiocyte | 37 (41%) | 40 (44%) | 43 (48%) | 48 (53%)
Artery, inflammation, chronic active | 3 (3%) | 5 (6%) | 6 (7%) | 3 (3%)
Artery, mineral | 1 (1%) | – | – | –
Artery, mediastinum, inflammation, chronic active | 2 (2%) | – | – | –
Bronchiole, hyperplasia, epithelial | – | – | 1 (1%) | –
Epithelium, alveolus, hyperplasia | 3 (3%) | 3 (3%) | 3 (3%) | 1 (1%)
Interstitium, fibrosis | – | – | 1 (1%) | –
Interstitium, mineral | 1 (1%) | – | 2 (2%) | –
Perivascular, inflammation, chronic active | 1 (1%) | – | – | –
Nose | (89) | (90) | (90) | (89)
Foreign body | 5 (6%) | 3 (3%) | 2 (2%) | 4 (4%)
Fungus | – | 1 (1%) | – | –
Hyperplasia, lymphocyte | – | – | 2 (2%) | –
Inflammation, suppurative | 10 (11%) | 12 (13%) | 13 (14%) | 10 (11%)
Inflammation, chronic active | – | 1 (1%) | 2 (2%) | –
Mineral | – | – | 1 (1%) | –
Nasopharyngeal duct, respiratory epithelium, hyperplasia | 1 (1%) | – | – | –
Olfactory epithelium, accumulation, hyaline droplet | 79 (89%) | 87 (97%) | 82 (91%) | 81 (91%)
Olfactory epithelium, atrophy | – | – | 1 (1%) | –
Olfactory epithelium, hyperplasia | – | – | 2 (2%) | –
Olfactory epithelium, metaplasia, respiratory | 3 (3%) | 6 (7%) | 7 (8%) | 2 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 3 (3%) | 2 (2%) | 1 (1%) | 1 (1%)
Respiratory epithelium, atrophy | – | 2 (2%) | – | –
Respiratory epithelium, hyperplasia | 3 (3%) | 11 (12%) | 14 (16%) | 11 (12%)
Respiratory epithelium, hyperplasia, goblet cell | 1 (1%) | – | – | –
Respiratory epithelium, metaplasia, squamous | – | – | 1 (1%) | –
Respiratory epithelium, mineral | 1 (1%) | – | – | –
Septum, developmental malformation | – | – | – | 1 (1%)
Trachea | (90) | (88) | (87) | (86)
Artery, inflammation, chronic active | – | 1 (1%) | – | 1 (1%)
Artery, mineral | 1 (1%) | – | – | –
Epithelium, hyperplasia | 1 (1%) | – | – | –
Epithelium, metaplasia, squamous | 1 (1%) | – | – | –
Glands, inflammation, acute | – | – | – | 1 (1%)
Special Senses System
Eye | (85) | (86) | (87) | (83)
Retinal detachment | 1 (1%) | – | – | –
Anterior chamber, inflammation, acute | 4 (5%) | 5 (6%) | 3 (3%) | 2 (2%)
Cornea, degeneration | – | 1 (1%) | – | –
Cornea, fibrosis | 1 (1%) | 3 (3%) | 4 (5%) | 6 (7%)
Cornea, inflammation, acute | 28 (33%) | 33 (38%) | 25 (29%) | 25 (30%)
Cornea, neovascularization | 10 (12%) | 19 (22%) | 20 (23%) | 19 (23%)
Cornea, ulcer | 6 (7%) | 2 (2%) | 1 (1%) | 2 (2%)
Cornea, epithelium, degeneration | – | 2 (2%) | 2 (2%) | 2 (2%)
Cornea, epithelium, hyperplasia | 13 (15%) | 17 (20%) | 15 (17%) | 20 (24%)
Cornea, epithelium, regeneration | – | 2 (2%) | 2 (2%) | –
Lens, cataract | – | 2 (2%) | – | 2 (2%)
Retina, atrophy | 6 (7%) | 10 (12%) | 12 (14%) | 14 (17%)
Retina, degeneration | 1 (1%) | – | – | –
Retina, dysplasia | – | 1 (1%) | – | –
Retina, gliosis | – | 1 (1%) | – | –
Harderian gland | (90) | (90) | (90) | (90)
Atrophy | 1 (1%) | 1 (1%) | 1 (1%) | –
Cyst | – | – | 1 (1%) | –
Degeneration, cystic | 2 (2%) | – | – | 3 (3%)
Hyperplasia | – | – | – | 3 (3%)
Hypertrophy | – | 2 (2%) | | 1 (1%)
Inflammation, granulomatous | – | – | 2 (2%) | –
Inflammation, acute | 2 (2%) | – | – | –
Inflammation, chronic | – | – | 2 (2%) | –
Inflammation, chronic active | 2 (2%) | | 1 (1%) | 1 (1%)
Lacrimal gland | (2) | (1) | (2) | (2)
Inflammation, granulomatous | – | – | 1 (50%) | –
Metaplasia, Harderian gland | 2 (100%) | 1 (100%) | 2 (100%) | 2 (100%)
Urinary System
Kidney | (90) | (90) | (90) | (90)
Infarct | – | – | 1 (1%) | –
Inflammation, suppurative | – | – | 1 (1%) | 1 (1%)
Mineral | 1 (1%) | – | 1 (1%) | 1 (1%)
Nephropathy, chronic progressive | 88 (98%) | 89 (99%) | 90 (100%) | 89 (99%)
Thrombus | 1 (1%) | – | – | –
Artery, inflammation, chronic active | – | – | – | 1 (1%)
Artery, mineral | 2 (2%) | 1 (1%) | – | –
Pelvis, dilation | 1 (1%) | 2 (2%) | 1 (1%) | –
Pelvis, inflammation, suppurative | – | 1 (1%) | 1 (1%) | 1 (1%)
Pelvis, inflammation, chronic active | – | – | – | 1 (1%)
Renal tubule, accumulation, hyaline droplet | – | – | 1 (1%) | 1 (1%)
Renal tubule, cyst | 18 (20%) | 17 (19%) | 14 (16%) | 6 (7%)
Renal tubule, hyperplasia | – | 2 (2%) | 1 (1%) | 2 (2%)
Renal tubule, hyperplasia, atypical | 2 (2%) | – | – | –
Renal tubule, hyperplasia, oncocytic | 2 (2%) | – | – | –
Urothelium, hyperplasia | 1 (1%) | 2 (2%) | 1 (1%) | 2 (2%)
Ureter | (0) | (1) | (0) | (0)
Dilation | – | 1 (100%) | – | –
Urethra | (0) | (0) | (1) | (0)
Urinary bladder | (89) | (89) | (86) | (85)
Dilation | – | – | 1 (1%) | –
Hemorrhage | 2 (2%) | – | – | –
Inflammation, suppurative | – | – | – | 1 (1%)
Inflammation, acute | 2 (2%) | – | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Necrosis | 1 (1%) | – | – | –
Artery, inflammation, chronic active | | 1 (1%) | – | –
Muscularis, degeneration | 1 (1%) | – | – | –
Serosa, inflammation, chronic active | – | 1 (1%) | – | –
Urothelium, hyperplasia | 1 (1%) | 1 (1%) | 2 (2%) | 1 (1%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.