# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-594

Report Series: NTP Technical Report Series

Report Series Number: 594

Official citation: National Toxicology Program (NTP). 2018. NTP Technical report on the toxicology and carcinogenesis studies of p-Chloro-α,α,α-trifluorotoluene (CASRN 98-56-6) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 594.