# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  G.K. Roberts, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  A.R. Pandiri, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, B.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results, conducted pathology review and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Conducted pathology review
  R.C. Kovi, Ph.D.
  R.A. Miller, D.V.M., Ph.D.
  R.R. Moore, D.V.M.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  B.K. Hayden
  N. Moore, Ph.D.
  K.M. Patton, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Reviews
  D.K. Giri, D.V.M., Ph.D., Coordinated 3-month rats and mice (August 30, 2011)
  C.J. Willson, D.V.M., Ph.D., Coordinated 3-month rats, reevaluation of testes and epididymides (July 14, 2016)
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  K.A. Szabo, D.V.M., Coordinated 2-year rats (September 10, 2015)
  L.H. Kooistra, D.V.M., Ph.D., Coordinated 2-year mice (September 15, 2015)
- RTI International, Research Triangle Park, North Carolina, USA
  Provided SMVCE analysis
  R.W. Tyl, Ph.D., Principal Investigator
  C.S. Sloan, M.S.