# References

1 The Merck Index: an encyclopaedia of chemicals, drugs, and biologicals. 14th ed. O’Neil CJ, editor. Whitehouse Station, NJ: Merck and Company, Inc; 2006. p. 352.
2 Lewis RJ. Hawley’s condensed chemical dictionary. 15th ed. New York, NY: John Wiley & Sons, Inc; 2007.10.1002/9780470114735
3 Daubert TE, Danner RP. Physical and thermodynamic properties of pure chemicals data compilation. Washington, DC: Taylor and Francis; 1989.
4 National Toxicology Program (NTP). Chemical information profile for 1-chloro-4-(trifluoromethyl)-benzene [CAS No. 98-56-6]. Supporting nomination for toxicological evaluation by the National Toxicology Program. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2009. Toxicity Study Report Series No. 14. NIH Publication No. 92-3133. https://ntp.niehs.nih.gov/ntp/noms/support_docs/pcbtf060409.pdf [Accessed: January 28, 2016]
5 Hazardous Substances Data Bank (HSDB). 1-Chloro-4-(trifluoromethyl)benzene. HSDB Record Number 4251. 2011. https://pubchem.ncbi.nlm.nih.gov/compound/7394 [Accessed: February 15, 2016]
6 U.S. Environmental Protection Agency (USEPA). Chemical Data Reporting, CAS No. 98-56-6. Washington, DC: U.S. Environmental Protection Agency; 2016. https://chemview.epa.gov/chemview [Accessed: July 7, 2016]
7 Lee EG, Lewis B, Burns DA, Kashon ML, Kim SW, Harper M. Assessing exposures to 1-chloro-4-(trifluoromethyl) benzene (PCBTF) in US workplaces. J Occup Environ Hyg. 2015; 12(7):D123–130. 10.1080/15459624.2015.1009989 25625325
8 U.S. Environmental Protection Agency (USEPA). Documentation of environmental indicator determination; RCRA corrective action; environmental indicator (EI) RCRIS code (CA725). Washington, DC: U.S. Environmental Protection Agency; 2001. https://www3.epa.gov/region02/waste/occ_b725.pdf [Accessed: January 13, 2016]
9 Elder VA, Proctor BL, Hites RA. Organic compounds found near dump sites in Niagara Falls, New York. Environ Sci Technol. 1981; 15(10):1237–1243. 10.1021/es00092a015 22299705
10 Yurawecz MP. Gas-liquid chromatographic and mass spectrometric identification of chlorinated trifluorotoluene residues in Niagara River fish. J Assoc Off Anal Chem. 1979;62:36–40.10.1093/jaoac/62.1.36 422503
11 U.S. Environmental Protection Agency (USEPA). Record of Decision: Diaz Chemical Corporation Site, Village of Holley, Orleans County, New York. Superfund Identification No. NYD067532580. New York, NY: U.S. Environmental Protection Agency, Region II; 2005. https://semspub.epa.gov/work/02/88931.pdf [Accessed: January 15, 2016]
12 Cacco G, Ferrari G. Absorption and translocation of 4-(trifluoromethyl) chlorobenzene in soil and crops. J Agric Food Chem. 1982; 30(1):196–197.10.1021/jf00109a046
13 U.S. Environmental Protection Agency (USEPA). Environmental monitoring at Love Canal. Volume 1. Washington, DC: U.S. Environmental Protection Agency, Office of Research and Development; 1982.
14 U.S. Environmental Protection Agency (USEPA). Region 9 PRG Table. 2004. https://archive.epa.gov/region9/superfund/web/pdf/04prgtable.pdf
15 U.S. Environmental Protection Agency (USEPA). Health Effects Assessment Summary Tables (HEAST). Washington, DC: U.S. Environmental Protection Agency; 1997. https://cfpub.epa.gov/ncea/risk/recordisplay.cfm?deid=2877&CFID=44505341&CFTOKEN=3780420 [Accessed: January 19, 2016]
16 Hooker Chemical Company. Gas chromatographic assay PCBTF and modified 90-day gavage and reproduction study in rats - Part II. 1981. [Accessed: January 21, 2016]
17 Kowa American Corporation. Material Safety Data Sheet: para-Chlorobenzotrifluoride [PCBTF]. 2005.
18 New York State Division of Water. Ambient water quality standards and guidance values and groundwater effluent limitations. 1998. https://www.dec.ny.gov/docs/water_pdf/togs111.pdf [Accessed: January 19, 2016]
19 Knaak JB, Al-Bayati MA, Raabe OG. Development of partition coefficients, V max and K m values, and allometric relationships. Toxicol Lett. 1995; 79(1-3):87–98. 10.1016/0378-4274(95)03360-W 7570677
20 Quistad GB, Mulholland KM. Metabolism of p-chlorobenzotrifluoride by rats. J Agric Food Chem. 1983; 31(3):585–589. 10.1021/jf00117a029 6886214
21 National Toxicology Program (NTP). Toxicity studies of p-chloro-α,α,α-trifluorotoluene (CAS No. 98-56-6) administered in corn oil and α-cyclodextrin to F344/N rats and B6C3F1 mice in 14 day comparative gavage studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1992. Toxicity Study Report Series No. 14. NIH Publication No. 92-3133.
22 Pelosi GD, Oberdoerster J, Olson JR, Knaak JB, Smith LW, Newton PE. Characterization of rat hepatic cytochrome P-450 activities following inhalation exposure to p-chlorobenzotrifluoride. Inhal Toxicol. 1998; 10(1):49–63.10.1080/089583798197871
23 Knaak JB, Smith LW, Fitzpatrick RD, Olson JR, Newton PE. In vitro hepatic metabolism of PCBTF: Development of Vmax and Km values and partition coefficients and their use in an inhalation PBPK model. Inhal Toxicol. 1998; 10(1):65–85.10.1080/089583798197880
24 Macrì A, Ricciardi C, Stazi AV, Mantovani A, Vendramin Macri C, Piccioni A, Badellino E, Bianchi MP, Pepe M, Ceccanti M. Subchronic oral toxicity of 4-chloro-α, α, α-trifluorotoluene in Sprague-Dawley rats. Food Chem Toxicol. 1987; 25(10):781–786. 10.1016/0278-6915(87)90234-1 3679024
25 Lilly Research Laboratories. Subchronic (three-month) toxicity study in Fischer 344 rats given daily gavage doses of 4-chlorobenzotrifluoride (PCBTF) with cover letter to Timm g dated 011684. 1984. [Accessed: August 4, 2016]
26 Occidental Chemical Corporation. Initial submission: Subchronic inhalation toxicity of PCBTF in rats with cover letter dated 071593. TSCATS [unpublished Health and Safety Studies submitted to EPA]. 1993. U.S. EPA/OPTS Public Files. Microfiche No. 0570838. Document No. 88-930000353. [Accessed: July 15, 2016]
27 Newton PE, Bolte HF, Richter WR, Knaak JB, Smith LW. Inhalation toxicity, neurotoxicity, and toxicokinetic studies of p-chlorobenzotrifluoride. Inhal Toxicol. 1998; 10(1):33–48.10.1080/089583798197862
28 Hooker Chemical Company. Acute inhalation toxicity study of parachlorobenzotrifluoride in the rat. 1979. [Accessed: January 21, 2016]
29 Hooker Chemical Company. Acute oral toxicity (LD50) in albino rats. 1979. [Accessed: January 21, 2016]
30 Hooker Chemical Company. Acute dermal toxicity (LD50) in albino rabbits. 1978. [Accessed: January 21, 2016]
31 Cameo Chemicals. Chemical Datasheet: p-Chloro-benzotrifluoride. NOAA; 2016. https://cameochemicals.noaa.gov/chemical/7335 [Accessed: April 6, 2016]
32 Occidental Chemical Corporation. Initial submission: Mortality patterns of workers in the Niagara plant (final report on mixtures of chemical substances) with attachments and cover letter dated 022192. 1992. [Accessed: April 25, 2016]
33 Haworth S, Lawlor T, Mortelmans K, Speck W, Zeiger E. Salmonella mutagenicity test results for 250 chemicals. Environ Mutagen. 1983; Supplement 1:3-142. 10.1002/em.2860050703
34 Bignami M, Crebelli R. A simplified method for the induction of 8-azaguanine resistance in Salmonella typhimurium. Toxicol Lett. 1979; 3(3):169–175.10.1016/0378-4274(79)90018-3
35 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
36 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
37 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
38 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481.10.1080/01621459.1958.10501452
39 Cox DR. Regression models and life‐tables. J R Stat Soc [Ser A]. 1972; 34(2):187–220.
40 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690.10.1093/biomet/62.3.679
41 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44:417–431. 10.2307/2531856 3390507
42 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London: Chapman and Hall; 1997.
43 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
44 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
45 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
46 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
47 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
48 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
49 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
50 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
51 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
52 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145.10.2307/2333011
53 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill Book Company, Inc; 1957.10.2307/2332898
54 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
55 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200.10.1177/009286159202600210
56 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21(1):52-59. 10.1006/rtph.1995.1009
57 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
58 Code of Federal Regulations (CFR). 21:Part 58.
59 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the US Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
60 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
61 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
62 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co., Inc; 1985. p. 13–59.
63 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67:233–241. 7021938
64 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
65 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
66 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16(S18):1-14. 10.1002/em.2850160502
67 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three‐exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutag. 1993; 21(2):160-179. 10.1002/em.2850210210
68 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutag. 1995; 25(4):302-313. 10.1002/em.2850250407
69 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
70 Hall AP, Elcombe CR, Foster JR, Harada T, Kaufmann W, Knippel A, Küttler K, Malarkey DE, Maronpot RR, Nishikawa A, et al. Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes—conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012; 40(7):971–994. 10.1177/0192623312448935 22723046
71 Dixon D, Alison R, Bach U, Colman K, Foley GL, Harleman JH, Haworth R, Herbert R, Heuser A, Long G, et al. Nonproliferative and proliferative lesions of the rat and mouse female reproductive system. J Toxicol Pathol. 2014; 27(3-4):1S–107S. 10.1293/tox.27.1S 25516636
72 Hoenerhoff MJ, Pandiri AR, Snyder SA, Hong H-HL, Ton T-V, Peddada S, Shockley K, Witt K, Chan P, Rider C, et al. Hepatocellular carcinomas in B6C3F1 mice treated with Ginkgo biloba extract for two years differ from spontaneous liver tumors in cancer gene mutations and genomic pathways. Toxicol Pathol. 2013; 41(6):826–841. 10.1177/0192623312467520 23262642
73 Maronpot RR, Fox T, Malarkey DE, Goldsworthy TL. Mutations in the ras proto-oncogene: Clues to etiology and molecular pathogenesis of mouse liver tumors. Toxicology. 1995; 101(3):125–156. 10.1016/0300-483X(95)03112-S 7676462
74 Ennulat D, Walker D, Clemo F, Magid-Slav M, Ledieu D, Graham M, Botts S, Boone L. Effects of hepatic drug-metabolizing enzyme induction on clinical pathology parameters in animals and man. Toxicol Pathol. 2010; 38(5):810–828. 10.1177/0192623310374332 20585144
75 Hard GC, Rodgers IS, Baetcke KP, Richards WL, McGaughy RE, Valcovic LR. Hazard evaluation of chemicals that cause accumulation of alpha 2u-globulin, hyaline droplet nephropathy, and tubule neoplasia in the kidneys of male rats. Environ Health Perspect. 1993;99:313–349. 10.1289/ehp.9399313 7686485
76 Creasy DM. Evaluation of testicular toxicity in safety evaluation studies: The appropriate use of spermatogenic staging. Toxicol Pathol. 1997; 25(2):119–131. 10.1177/019262339702500201 9125770
77 Moffit JS, Bryant BH, Hall SJ, Boekelheide K. Dose-dependent effects of sertoli cell toxicants 2, 5-hexanedione, carbendazim, and mono-(2-ethylhexyl) phthalate in adult rat testis. Toxicol Pathol. 2007; 35(5):719–727. 10.1080/01926230701481931 17763286
78 Ku WW, Chapin RE, Wine RN, Gladen BC. Testicular toxicity of boric acid (BA): Relationship of dose to lesion development and recovery in the F344 rat. Reprod Toxicol. 1993; 7(4):305–319. 10.1016/0890-6238(93)90020-8 8400621
79 Murphy CJ, Richburg JH. Implications of Sertoli cell induced germ cell apoptosis to testicular pathology. Spermatogenesis. 2014; 4(2). 10.4161/21565562.2014.979110 26413394
80 Vidal JD, Whitney KM. Morphologic manifestations of testicular and epididymal toxicity. Spermatogenesis. 2014; 4(2). 10.4161/21565562.2014.979099 26413388
81 Hoenerhoff MJ, Hill GD, Gruebbel MM. Adrenal gland, cortex – atrophy. National Toxicology Program nonneoplastic lesion atlas. 2014. https://ntp.niehs.nih.gov/nnl/endocrine/adrenal/cxatrophy/index.htm [Accessed: October 24, 2016]
82 National Toxicology Program (NTP). Toxicology studies of indole-3-carbinol (CAS No. 700-06-1) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of indole-3-carbinol in Harlan Sprague Dawley rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2017. Technical Report Series No. 584.
83 National Cancer Institute (NCI). Bioassay of 2,4-diaminoanisole sulfate for possible carcinogenicity (CAS No. 39156-41-7). Bethesda, MD: U.S. Department of Health, Education, and Welfare; 1978. Technical Report Series No. 84, NIH Publication No. 78-1334.
84 National Cancer Institute (NCI). Bioassay of tetrachlorvinphos for possible carcinogenicity (CAS No. 961-11-5). Bethesda, MD: U.S. Department of Health Education and Welfare; 1978. Technical Report Series No. 33, NIH Publication No. 78-833.
85 National Toxicology Program (NTP). Carcinogenesis bioassay of ziram (CAS No. 137-30-4) in F344/N rats and B6C3F1 mice (feed study). Research Triangle Park, NC and Bethesda, MD: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1983. Technical Report Series No. 238. NIH Publication No. 83-1794.
86 National Toxicology Program (NTP). Carcinogenesis studies of 4, 4'-methylenedianiline dihydrochloride (CAS No. 13552-44-8) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1983. Technical Report Series No. 248. NIH Publication No. 83-2504.
87 Capen CC, Martin SL. The effects of xenobiotics on the structure and function of thyroid follicular and C-cells. Toxicol Pathol. 1989; 17(2):266–293. 10.1177/019262338901700205 2675279
88 Bjerre Knudsen L, Madsen LW, Andersen S, Almholt K, de Boer AS, Drucker DJ, Gotfredsen C, Egerod FL, Hegelund AC, Jacobsen H, et al. Glucagon-like peptide-1 receptor agonists activate rodent thyroid C-cells causing calcitonin release and C-cell proliferation. Endocrinology. 2010; 151(4):1473–1486. 10.1210/en.2009-1272 20203154
89 Leininger JR, Jokinen MP. Oviduct, uterus, and vagina. In: Boorman GA, Eustis SL, Elwell MR, Montgomery CA Jr, MacKenzie WF, editors. Pathology of the Fischer Rat, Reference and Atlas. San Diego, CA: Academic Press, Inc; 1990. p. 443–459.
90 Davis B. Endometrial stromal polyps in rodents: Biology, etiology, and relevance to disease in women. Toxicol Pathol. 2012; 40(3):419–424. 10.1177/0192623311431466 22215514
91 Klaunig JE, Dekant W, Plotzke K, Scialli AR. Biological relevance of decamethylcyclopentasiloxane (D5) induced rat uterine endometrial adenocarcinoma tumorigenesis: Mode of action and relevance to humans. Regul Toxicol Pharm. 2016; 74:S44-S56. 10.1016/j.yrtph.2015.06.021
92 Sakamoto Y, Inoue K, Takahashi M, Taketa Y, Kodama Y, Nemoto K, Degawa M, Gamou T, Ozawa S, Nishikawa A, et al. Different pathways of constitutive androstane receptor–mediated liver hypertrophy and hepatocarcinogenesis in mice treated with piperonyl butoxide or decabromodiphenyl ether. Toxicol Pathol. 2013; 41(8):1078–1092. 10.1177/0192623313482055 23531792
93 National Center for Biotechnology Information (NCBI). PubChem bioassay compound summary; CID=7394. 2016. https://pubchem.ncbi.nlm.nih.gov/compound/7394#section=BioAssay-Results [Accessed: August 16, 2016]
94 Bucher JR, Shackelford CC, Haseman JK, Johnson JD, Kurtz PJ, Persing RL. Carcinogenicity studies of oxazepam in mice. Fundam Appl Toxicol. 1994; 23(2):280–297. 10.1006/faat.1994.1106 7982536
95 Parkinson A, Leonard N, Draper A, Ogilvie BW. On the mechanism of hepatocarcinogenesis of benzodiazepines: Evidence that diazepam and oxazepam are CYP2B inducers in rats, and both CYP2B and CYP4A inducers in mice. Drug Metab Rev. 2006; 38(1-2):235–259. 10.1080/03602530600570081 16684660
96 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
97 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutag. 2004; 44(5):427-435. 10.1002/em.20075
98 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
99 Thermo Fisher Scientific™. Aldrich FT-IR Collection, 2nd ed., index 6694. 2007.
100 Kim Y, Sills RC, Houle CD. Overview of the molecular biology of hepatocellular neoplasms and hepatoblastomas of the mouse liver. Toxicol Pathol. 2005; 33(1):175–180. 10.1080/01926230590522130 15805069
101 Fox TR, Schumann AM, Watanabe PG, Yano BL, Maher VM, McCormick JJ. Mutational analysis of the H-ras oncogene in spontaneous C57BL/6× C3H/He mouse liver tumors and tumors induced with genotoxic and nongenotoxic hepatocarcinogens. Cancer Res. 1990; 50(13):4014–4019. 2191770
102 Yamada Y, Yoshimi N, Sugie S, Suzui M, Matsunaga K, Kawabata K, Hara A, Mori H. β‐catenin (Ctnnb1) gene mutations in diethylnitrosamine (DEN)‐induced liver tumors in male F344 rats. Jap J Cancer Res. 1999; 90(8):824-828. 10.1111/j.1349-7006.1999.tb00822.x
103 National Toxicology Program (NTP). Toxicology studies of a pentabromodiphenyl ether mixture [DE 71 (technical grade)] (CAS No. 32534-81-9) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of a pentabromodiphenyl ether mixture [DE-71 (technical grade)] in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Technical Report Series No. 589.
104 Sills RC, Boorman GA, Neal JE, Hong HL, Devereux TR. Mutations in ras genes in experimental tumours of rodents. IARC Sci Publ. 1999;(146):55–86. 10353384
105 Hayashi S-M, Ton TV, Hong H-HL, Irwin RD, Haseman JK, Devereux TR, Sills RC. Genetic alterations in the Catnb gene but not the H-ras gene in hepatocellular neoplasms and hepatoblastomas of B6C3F1 mice following exposure to diethanolamine for 2 years. Chem Biol Interact. 2003; 146(3):251–261. 10.1016/j.cbi.2003.07.001 14642737