# Conclusions

Under the conditions of these 2-year inhalation studies, there was some evidence of carcinogenic activity^a^ of p-chloro-α,α,α-trifluorotoluene in male Hsd:Sprague Dawley^®^ SD^®^ rats based on increased incidences of C-cell adenoma in the thyroid gland. The combined occurrences of alveolar/bronchiolar adenoma or carcinoma in the lung of male rats may have been related to treatment. There was some evidence of carcinogenic activity of p-chloro-α,α,α-trifluorotoluene in female Hsd:Sprague Dawley^®^ SD^®^ rats based on increased incidences of C-cell adenoma in the thyroid gland, increased incidences of benign pheochromocytoma in the adrenal medulla, increased incidences of adenocarcinoma in the uterus, and increased incidences of stromal polyp in the uterus. There was clear evidence of carcinogenic activity of p-chloro-α,α,α-trifluorotoluene in male B6C3F1/N mice based on increased incidences of hepatocellular carcinoma and hepatoblastoma in the liver. There was clear evidence of carcinogenic activity of p-chloro-α,α,α-trifluorotoluene in female B6C3F1/N mice based on increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma in the liver. The combined incidences of adenoma or adenocarcinoma in the Harderian gland of female mice were also considered to be related to treatment.

a See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix M.

Exposure to p-chloro-α,α,α-trifluorotoluene caused increased incidences of nonneoplastic lesions in the lung and liver of male and female rats and mice, in the nose of male rats, in the adrenal medulla and uterus of female rats, in the forestomach of male and female mice, and in the larynx in male mice. Exposure to p-chloro-α,α,α-trifluorotoluene caused increased severity of nonneoplastic lesions in the kidney of male rats.