# Discussion

p-Chloro-α,α,α-trifluorotoluene is a volatile organic compound-exempt solvent used in paints and coatings and for automobile parts and body cleaning. As a solvent with non-ozone depleting status, p-chloro-α,α,α-trifluo-rotoluene also has greater use in end-user applications, potentially resulting in higher exposure compared to industrial settings. p-Chloro-α,α,α-trifluorotoluene was nominated by Kowa American Corporation for study due to the lack of occupational exposure limits from the Occupational Safety and Health Administration, the National Institute for Occupational Safety and Health, or the American Conference of Governmental Industrial Hygienists. In addition, there are no chronic toxicity or carcinogenicity studies available in the literature. To address these data gaps, the National Toxicology Program (NTP) conducted 3-month toxicity and 2-year toxicity and carcinogenicity studies of p-chloro-α,α,α-trifluorotoluene, via whole body inhalation, in Hsd:Sprague Dawley^®^ SD^®^ rats and B6C3F1/N mice.

In the 3-month studies, higher body weights were observed fairly consistently in female rats (500 ppm or greater) and male (500 ppm or greater) and female (250 ppm or greater) mice. Clinical signs were transiently observed in the 2,000 ppm rats and mice, including nasal and ocular discharge, tremors and lethargy in rats, and excitability in mice; these signs were no longer observed after several weeks on study. Exposure-related increases in liver weights were observed in both sexes and species and increased kidney weights were observed in male rats and male and female mice. Other studies, via various routes of exposure, have also consistently reported effects on liver and kidney weights following exposure to p-chloro-α,α,α-trifluorotoluene^21; 24; 25; 27^.

The liver was one of the primary target organs for toxicity observed in the 3-month studies. Histopathologic lesions of the liver were observed in male and female rats and mice; centrilobular hepatocyte hypertrophy was commonly seen in rats and female mice at higher exposure concentrations and in all male mice exposed to 250 ppm or greater. Low incidences of hepatocellular necrosis were observed in 2,000 ppm male rats and in male and female mice exposed to 250 ppm or greater. p-Chloro-α,α,α-trifluorotoluene has been shown to induce cytochrome P450 enzymes, specifically CYP2B^22^, and this suggests that the liver weight changes and hepatocyte hypertrophy observed in the current study could be due to enzyme induction.

Clinical chemistry alterations, consistent with the observed hepatic histopathology, were also observed in male and female rats in the 3-month study. Mild increases in alanine aminotransferase (ALT) and sorbitol dehydrogenase (SDH) activities observed in 2,000 ppm male rats were consistent with the hepatocellular necrosis. Mild increases in ALT and SDH activities in 2,000 ppm females may also indicate mild hepatic injury, although hepatocellular necrosis was not observed. Small increases (below twofold) in ALT activities have been reported with the administration of CYP2B inducers (among others) at dose levels where centrilobular hypertrophy was present without accompanying degenerative changes^70; 74^. Alkaline phosphatase (ALP) activities were mildly elevated in most exposed groups of males and females, while bile salt levels were elevated in females. Bile salt levels and ALP activities are used as markers of cholestasis. The increase in ALP activity was relatively mild and no histologic changes associated with cholestasis were observed. Thus, the increases in ALP activities and bile salt levels may be related to the hepatocyte hypertrophy (enzyme induction) or altered hepatic metabolism, respectively^74^.

The kidney was a target organ for toxicity in the 3-month rat study, with an exposure-related increase in the severity of nephropathy in males. Kidney toxicity was also observed in the NTP 2-week oral gavage study of p-chloro-α,α,α-trifluorotoluene, where treatment was associated with an accumulation of α2u-protein in the F344/N male rat kidney: α2u accounted for 11%, 17%, 34%, and 55% of total protein in the kidney at doses of 0, 50, 400, and 1,000 mg p-chloro-α,α,α-trifluoro-toluene/kg body weight per day, respectively^21^. Hyaline droplet accumulation was confirmed in the current 3-month study using a Mallory-Heindenhain stain.

In the current 2-year study, the kidney was also a major target organ for toxicity in male rats: nephropathy was the cause of death for 18%, 30%, 56%, and 78% of animals in the 0, 100, 300, and 1,000 ppm groups, respectively. Based on α2u-protein measurements in the NTP 2-week gavage study in F344/N rats^21^ and Mallory-Heindenhain staining in the current 3-month inhalation study it is possible that the observed nephropathy in the current 2-year study may have been, in part due to an α2u-mediated mechanism. However, in the 3-month study, there was a lack of degeneration, necrosis and granular casts that are typically observed in α2u-mediated nephropathy along with slight increases in the incidences and severities of nephropathy in female rats and increased kidney weights in mice, suggesting additional mechanisms of action for p-chloro-α,α,α-trifluorotoluene-induced kidney toxicity. Neoplastic and nonneoplastic outcomes in the male rat kidney that are considered α2u-mediated are frequently not duplicated in other sexes/species and are not considered relevant to humans in risk assessments^75^. In the current study, the lack of renal tubule mineralization in the presence of renal nephropathy-induced mortality and kidney effects in other sexes/species, along with the lack of other typical features of α2u-nephropathy, may indicate that the severe nephropathy observed in male rats was predominantly an exacerbation of the back-ground chronic progressive nephropathy commonly seen in rats.

In the 3-month studies, p-chloro-α,α,α-trifluorotoluene exposure resulted in effects on the male reproductive system in rats and mice. Lower sperm motility was observed in rats at 1,000 and 2,000 ppm and in all groups of exposed mice evaluated. Male rats also had lower epididymal weights and lower epididymal sperm counts per cauda. In rats, the effects on sperm parameters were supported by histopathologic findings in the epididymal duct (exfoliated germ cells) and the testes (germ cell degeneration and spermatid retention), suggesting disruption of spermatogenesis. Spermatid retention is considered a sensitive endpoint with which to measure testicular toxicity, often occurring at lower exposure levels than other findings^76; 77^. For example, exposure to boric acid at lower concentrations leads to spermatid retention, while at higher concentrations germ cell degeneration/exfoliation and testicular atrophy are also observed^78^. Effects on spermiation and germ cell exfoliation have been associated with Sertoli cell toxicants; however, the exact target of toxicity is difficult to discern without more targeted mechanistic studies^79; 80^.

p-Chloro-α,α,α-trifluorotoluene exposure in the 3-month studies also produced alterations in estrus cycling in female rats and mice. In rats, extended diestrus was observed in animals exposed to 2,000 ppm and in mice, extended estrus was observed in all exposed groups. Also observed in the 3-month study of mice was degeneration of the X-zone in the adrenal gland. Although regression of the X-zone is a normal occurrence in mice that typically occurs several weeks after puberty in females, the diagnosis of degeneration of the X-zone represents an alteration in the temporal sequence of the normal regression. The regression of the X-zone is mediated by gonadal and thyroid gland hormones and alterations in hormone levels can alter the normal regression of the X-zone^81^. The estrus cycle deregulation observed in rats may have played a role in the uterine histopathologic findings observed in the 2-year study. Based on these findings, p-chloro-α,α,α-trifluorotoluene exposure via inhalation exhibits the potential to be a reproductive toxicant in both male and female Hsd:Sprague Dawley^®^ SD^®^ rats and B6C3F1/N mice.

In the 2-year studies, lower survival was observed in male rats and mice. Mortality in male rats was largely attributed to nephropathy. Decreases in survival were observed relatively late in the studies, beginning at approximately week 89 in male rats and after week 90 in male mice. In mice, a majority of male and approximately half of female moribund removals and early deaths were attributed to liver neoplasms, corresponding with clinical observations of distended abdomens. Final body weights were within 10% of chamber controls for male and female rats and male mice. Similar to the 3-month study, higher, yet nonsignificant, body weights were observed in p-chloro-α,α,α-trifluorotoluene-exposed female mice. Overall in the 2-year studies, the primary target organs for carcinogenicity differed between rats and mice, with some concordance between males and females within a species. The primary target organs were the thyroid gland (C-cell), adrenal gland (females), and uterus (females) of rats and the liver and Harderian gland (females) of mice. While carcinogenicity targets differed between rats and mice, exposure in all sexes and species resulted in strong nonneoplastic responses in the lung and liver.

Along with other criteria, NTP takes historical control tumor incidences into account when interpreting the results of a study. NTP historical control database consists of 2-year studies that were started within a 5-year time period of the study being evaluated. As previously mentioned, there are no Hsd:Sprague Dawley^®^ SD^®^ historical control studies for the inhalation route that can provide context to interpret the findings of the current study. There is one Hsd:Sprague Dawley^®^ SD^®^ study via the gavage route that fits the criteria for historical controls of all routes of exposure^82^ and has been included for reference. The limited nature of the available data and the notable differences in study design between inhalation and noninhalation studies limit the utility of this historical control reference for interpretation of the current study.

p-Chloro-α,α,α-trifluorotoluene displayed carcinogenic activity in the thyroid gland C-cells of male and female rats exposed via whole body inhalation for 2 years. In males, there were significant trend and pairwise increases (P < 0.001) in C-cell adenoma at 1,000 ppm (2/50 at 0 ppm, 12/50 at 1,000 ppm) indicating an exposure-related effect. The incidence of C-cell adenoma in controls (26%) in the other NTP study with Hsd:Sprague Dawley^®^ SD^®^ rats^82^ is similar to the incidence in 1,000 ppm males from the current study. In females, there were significant trend (P < 0.008) and pairwise (P < 0.003) increases in the incidence of C-cell adenoma at 1,000 ppm, with contribution from animals with bilateral lesions. The incidence of C-cell adenoma in 1,000 ppm female rats was higher than the incidence in control females in the other recent NTP study with Hsd:Sprague Dawley^®^ SD^®^ rats^82^. Due to limitations cited above for these historical controls, the weight of interpretation for these findings was placed on the concurrent controls, as they were considered to be most relevant. Taken together, the increased incidences of C-cell adenoma were considered to be some evidence of carcinogenic activity in male and female rats.

Proliferative lesions of the C-cells are considered to represent a biological continuum with potential for progression from hyperplasia to adenoma to carcinoma. There were no increases in the incidences of C-cell hyperplasia in male or female rats. Low incidences of C-cell carcinoma were sporadically observed in male and female rats; in female rats, C-cell carcinoma was only observed in animals exposed to p-chloro-α,α,α-trifluorotoluene. Treatment-related increases in the incidences of C-cell lesions have not been observed recently in NTP 2-year studies and have only been reported in four other NTP Technical Reports in rats: 2,4-diaminoanisole sulfate, tetrachlorvinphos, ziram, and 4,4′-methylenedianiline dihydrochloride^83-86^. C-cells of the thyroid gland are responsible for the production and release of calcitonin in order to regulate plasma calcium levels. Calcitonin functions to increase renal clearance of calcium, as well as decrease bone desorption of calcium. Calcitonin is continuously secreted; however, elevated plasma calcium will signal large releases of stored calcitonin. If hypercalcemia is persistent, C-cell proliferation and associated lesions (hyperplasia, adenoma, and carcinoma) will arise to sustain calcitonin demands^87^. Pharmacologic agents have been shown to cause C-cell proliferation and C-cell adenoma via the glucagon-like peptide-1 receptor.^88^ Serum cal-cium levels were not assessed in the current study, and the cause of the increased incidences of observed C-cell adenoma is unknown.

In the lung of male rats following p-chloro-α,α,α-trifluorotoluene exposure for 2 years, there were higher incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in the 100 and 1,000 ppm groups compared to the chamber controls. In 1,000 ppm males, there were two occurrences of alveolar/bronchiolar carcinoma with a positive trend statistic, but the combined incidence of adenoma or carcinoma was not statistically significant by trend or pairwise comparison. No alveolar/bronchio-lar neoplasms were observed in the lung of the concurrent chamber controls or control male rats from the recent NTP gavage study in Hsd:Sprague Dawley^®^ SD^®^ rats^82^. NTP has limited recent experience with Hsd:Sprague Dawley^®^ SD^®^ rats, but based on more extensive historical control experience with F344/N and Wistar Han rats, neoplastic lesions of the lung are considered rare in rats. Due to the rarity of lung neoplasms, the combined occurrence of alveolar/bronchiolar adenoma or carcinoma in the lung of male rats may have been related to treatment. There were high incidences of nonneoplastic lesions in the lung of male and female rats in the current study, but they were not considered preneoplastic (e.g., fibrosis). Although not preneoplastic, fibrosis is an important lesion with relevance to chronic lung disease in humans and is discussed in more depth below.

In the adrenal medulla of female rats, the incidences of benign pheochromocytoma increased with increasing exposure concentration and there was a significant pairwise (P < 0.05) increased incidence in the 1,000 ppm group. In addition, there were significant trend and pairwise increased incidences of hyperplasia of the adrenal medulla, considered preneoplastic, at 300 and 1,000 ppm. Pheochromocytoma, benign or malignant, was not observed in control animals in the current study or the other NTP study in Hsd:Sprague Dawley^®^ SD^®^ rats^82^. The increased incidences of benign pheochromocytoma were considered to be related to treatment. These effects were not observed in male rats.

In the uterus of female rats, there was a significant increasing trend in the incidence of adenocarcinoma (chamber control, 1/50; 1,000 ppm, 5/50). Atypical hyperplasia of the endometrium, considered preneoplastic, was also observed in the 1,000 ppm group at a low incidence, and was considered supporting evidence for carcinogenic activity. The increased incidence of adenocarcinoma in the uterus of female rats was considered to be related to treatment. In the other NTP study with Hsd:Sprague Dawley^®^ SD^®^ rats^82^, the uterus was not sectioned longitudinally and cannot be used as a reference to interpret these findings.

Also in the uterus of female rats, there was a significant pairwise increase in the incidence of stromal polyp (16/50) at 300 ppm. The highest incidence of multiple polyps (4/50) also occurred in the 300 ppm group. There was not a significant trend due to a lower response at 1,000 ppm (12/50) compared to 300 ppm. While the neoplasm response did not increase with exposure concentration at 1,000 ppm, all exposed groups had increased incidences of stromal polyp compared to the chamber controls, and the observed responses were considered to be related to p-chloro-α,α,α-trifluorotoluene exposure. One stromal sarcoma was observed in the 300 ppm group; stromal sarcoma can occasionally arise from within a stromal polyp^71^ and are often considered together with stromal polyps. In female rats, the increased incidences of C-cell adenoma in the thyroid gland, benign pheochromocytoma in the adrenal medulla, adenocarcinoma in the uterus, and stromal polyp in the uterus were all considered to contribute to the conclusion of some evidence of carcinogenic activity.

Spontaneous uterine lesions in rats are largely associated with natural changes in hormone regulation. Stromal polyps are considered a common background lesion in many strains of rats and their occurrence is thought to coincide with natural estrous cycle deregulation in rats and prolonged progesterone stimulation^89^. Conversely, others have suggested that rodent stromal polyps are not hormone sensitive^90^. In the current study, there was evidence that exposure to p-chloro-α,α,α-trifluorotoluene for 3 months resulted in estrous cycle alterations in female rats and mice. In the 2-year study, the occurrence of stromal polyps in rats may be related to prolonged diestrus, observed at 3 months, and progesterone stimulation. The hormonal stimulation of uterine adenocarcinomas is not as well understood, but prolonged or constant estrous is considered a potential factor^91^.

In mice exposed to p-chloro-α,α,α-trifluorotoluene for 2 years, the primary target organ for toxicity and carcinogenicity was the liver. In males, there were trend and pairwise increases in the incidences of hepatocellular carcinoma (including multiple) in all exposed groups, with a large contribution of animals with multiple neoplasms. The incidence of hepatocellular carcinoma at 400 ppm (35/50, 70%) exceeded the historical control ranges for inhalation studies (16% to 50%) and all routes of exposure (16% to 50%). There was also a significant trend and a pairwise increased incidence of hepatoblastoma (including multiple) in 400 ppm males (15/50, 30%), exceeding the historical control ranges for inhalation studies (0% to 4%) and all routes of exposure (0% to 8%). In male mice, the occurrence of hepatocellular carcinoma and hepatoblastoma were separately considered to contribute to the conclusion of clear evidence of carcinogenic activity. The incidences of hepatocellular adenoma did not increase with increasing p-chloro-α,α,α-trifluoro-toluene exposure; however, the contribution of animals with multiple adenoma did increase in an exposure concentration-dependent manner with significantly higher incidences of multiple adenoma at 200 and 400 ppm.

In female mice, there were significantly increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma, separately. There were trend and pairwise increases in the incidences of hepatocellular adenoma, with exposure-related contribution of multiples at 200 and 400 ppm. The incidence of hepatocellular adenoma at 400 ppm (34/50, 68%) exceeded the historical control ranges for inhalation studies (12% to 38%) and all routes of exposure (10% to 67%). There were trend and pairwise significant increases in the incidences of hepatocellular carcinoma (including multiple) at 400 ppm. The incidences of hepatocellular carcinoma at 200 ppm (12/50, 24%) and 400 ppm (34/50, 68%) exceeded the historical control ranges for inhalation studies (10% to 20%) and all routes of exposure (4% to 20%). The incidence of hepatoblastoma at 400 ppm (8/50, 16%) was significantly greater than that of the chamber controls and exceeded the historical control ranges for inhalation studies (0% to 2%) and all routes of exposure (0% to 2%). In female mice, the increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma were all separately considered to contribute to the conclusion of clear evidence of carcinogenic activity.

There were statistically significant trend and pairwise differences in the negative direction for Hras mutations at codon 61 between spontaneous hepatocellular carcinomas (HCCs) in chamber control mice (males and females combined) and HCCs resulting from chronic p-chloro-α,α,α-trifluorotoluene exposure (Appendix L). The Hras mutations in spontaneous and chemically exposed rodent hepatocellular tumors are frequently localized within codon 61^72; 73^. p-Chloro-α,α,α-trifluorotoluene is nongenotoxic (Ames assay negative, chromosomal aberration assay negative) and may not directly cause mutations and initiate carcinogenesis. However, further mechanistic studies are needed to better understand the p-chloro-α,α,α-trifluorotoluene-induced hepatocellular carcinogenesis.

There is evidence that p-chloro-α,α,α-trifluorotoluene inhalation exposure can lead to CYP2B induction in the liver of Sprague-Dawley rats^22^; liver microsomes from male rats exposed to 250 ppm p-chloro-α,α,α-trifluorotoluene had approximately six times higher CYP2B activity compared to controls, with little activity seen at lower exposure concentrations or in females. Other CYP isoforms evaluated also showed higher activity in exposed animals; however the strongest induction was CYP2B. CYP2B activation via the constitutive androstane receptor (CAR) is a known mechanism of tumor promotion activity in the liver of rodents^92^. The potential for p-chloro-α,α,α-trifluorotoluene to activate CAR was evaluated in the Tox21 screening program but results were inconclusive^93^. Liver weights and nonneoplastic lesions observed in the current 3-month and 2-year studies are also consistent with a potential CAR-mechanism of action and similar responses have been observed in other studies with CAR/CYP2B inducers^94; 95^.

In the Harderian gland of female mice following 2 years of p-chloro-α,α,α-trifluorotoluene exposure, there were trend and pairwise significant increases in the incidences of adenoma or adenocarcinoma (combined) in the 200 (9/50) and 400 (8/50) ppm groups compared to concurrent controls (2/50). The incidences at 200 and 400 ppm exceeded the historical control range for inhalation studies (4% to 14%; n = 6 studies) but not for all routes of exposure (4% to 20%; n = 11 studies). The average incidence of these neoplasms in control B6C3F1/N mice observed in NTP studies by all routes of exposure is 8.6% and all except one study (e.g., 10 of 11 studies) had control incidences lower than those observed in the 200 and 400 ppm groups in the current study. Although not observed in mice, Harderian gland degeneration was observed in rats in the 3-month study. The combined incidences of adenoma or adenocarcinoma in the Harderian gland of female mice were considered to be related to treatment.

Consistent patterns of nonneoplastic lesions were observed in the liver and lung of rats and mice in the 2-year studies. In the lung, there were increased incidences of fibrosis in both sexes of rats and mice, as well as hemorrhage and chronic inflammation in rats and alveolar/bronchiolar epithelium hyperplasia in mice. The exposure response for fibrosis was flat in rats with approximately one-half of the exposed rats in each group being diagnosed. In mice, nearly all animals in each exposure group were diagnosed with fibrosis, indicating a maximal response even at 100 ppm. There was no indication of this lesion in the 3-month studies and a no-observed-effect level was not identified in the current study for this lesion in any sex or species. The lung fibrosis response observed in the current study may be of particular interest to humans exposed to p-chloro-α,α,α-trifluorotoluene. While fibrosis is not considered a preneoplastic lesion, it can critically alter pulmonary function and contribute to chronic lung diseases in humans.

In the liver, there were increased incidences of eosinophilic foci and centrilobular hepatocyte hypertrophy in all sexes/species. Low incidences of liver necrosis were observed in male rats and male and female mice. Increased incidences of fatty change, clear cell focus (females only) and mixed cell focus (females only) were also observed in rats following 2 years of exposure to p-chloro-α,α,α-trifluorotoluene. In mice, multinucleated hepatocytes and intrahepatocellular erythrocytes (males only) were also observed. Despite a similar response in nonneoplastic lesions of the liver, a robust neoplastic response was only observed in mice.

Other nonneoplastic lesions observed following 2 years of inhalation exposure to p-chloro-α,α,α-trifluorotoluene included adrenal cortex hyperplasia in female rats, and hyperplasia of the forestomach (males and females) and larynx (males) in mice. Mammary gland hyperplasia was observed in female rats in both the 3-month and 2-year studies; however, decreased trends for mammary gland fibroadenoma, adenoma, and adenocarcinoma were observed in the 2-year studies.

p-Chloro-α,α,α-trifluorotoluene was negative in several bacterial mutagenicity assays (Salmonella typhimurium strains TA98, TA100, TA1535, and TA1537 and Escherichia coli strain WP2 uvrA/pKM101). A small but statistically significant increase in micronucleated mature erythrocytes was observed in male mice after 3 months of inhalation exposure to the highest concentration of p-chloro-α,α,α-trifluorotoluene (2,000 ppm) and was judged to be a positive result. No induction of micronuclei was observed in female mice or male or female rats. Overall these results suggest that while p-chloro-α,α,α-trifluorotoluene may be capable of inducing chromosomal damage at high levels of inhalation exposure in male mice, the mode of action for the carcinogenicity of p-chloro-α,α,α-trifluorotoluene observed in rats and mice is unlikely to be driven by genotoxicity.