# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-594.

## Rats

### Three-month Study

All animals survived to the end of the study except one 2,000 ppm female that was removed early due to a sublingual abscess unrelated to chemical exposure (Table 2); the animal also had clinical observations of abnormal breathing, thinness, and nasal/eye discharge. The final mean body weights and mean body weight gains of females exposed to 500 ppm or greater were significantly greater than those of the chamber controls (Table 2; Figure 2). The increases in the final mean body weight and mean body weight gain of males exposed to 125 ppm were not considered biologically relevant because they were within 10% of chamber controls and only occurred at the lowest exposure concentration. Clinical observations occurred primarily in 2,000 ppm males and females and included nasal and eye discharge, tremors, and lethargy after exposure. Clinical observations resolved by the mornings following exposure and were no longer apparent by week 4.

Table 2 Survival and Body Weights of Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 129 ± 2 | 393 ± 7 | 264 ± 8 | –
125 | 10/10 | 128 ± 2 | 426 ± 5* | 298 ± 6* | 108
250 | 10/10 | 128 ± 2 | 414 ± 11 | 286 ± 10 | 105
500 | 10/10 | 127 ± 2 | 412 ± 11 | 285 ± 10 | 105
1,000 | 10/10 | 129 ± 2 | 401 ± 7 | 273 ± 7 | 102
2,000 | 10/10 | 129 ± 2 | 376 ± 6 | 247 ± 6 | 96
Female
0 | 10/10 | 118 ± 1 | 240 ± 5 | 122 ± 4 | –
125 | 10/10 | 119 ± 2 | 249 ± 5 | 130 ± 5 | 104
250 | 10/10 | 119 ± 2 | 255 ± 6 | 136 ± 4 | 106
500 | 10/10 | 118 ± 2 | 259 ± 5* | 141 ± 5* | 108
1,000 | 10/10 | 118 ± 1 | 267 ± 9** | 149 ± 8** | 111
2,000 | 9/10^c^ | 117 ± 2 | 294 ± 8** | 177 ± 8** | 123

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 7.

Figure 2

Growth Curves for Rats Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months

The leukocyte count was significantly decreased in 2,000 ppm females, and the lymphocyte counts were significantly decreased in 2,000 ppm males and females (Table F-1). In addition, the neutrophil counts were significantly increased in males exposed to 500 ppm or greater. This combination of changes is consistent with a stress leukogram, which is due to the chronic production of endogenous corticosteroids. It is also plausible that the increases in male neutrophil counts were due to mild inflammation secondary to the observed hepatic necrosis; this is supported by the significantly increased globulin concentrations in 1,000 and 2,000 ppm males. Total protein and globulin concentrations were also significantly increased in 2,000 ppm females.

Alanine aminotransferase and sorbitol dehydrogenase activities were significantly increased in 2,000 ppm males and females (Table 3 and Table F-1). Alkaline phosphatase activities were significantly increased in all exposed male groups and in females exposed to 250 ppm or greater, and bile salt concentrations were significantly increased in females exposed to 500 ppm or greater.

Table 3 Selected Clinical Chemistry Data for Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Alanine aminotransferase (IU/L) | 55 ± 2 | 53 ± 2 | 52 ± 2 | 52 ± 2 | 59 ± 3 | 73 ± 4*
Sorbitol dehydrogenase (IU/L) | 13 ± 1 | 12 ± 1 | 14 ± 1 | 15 ± 0 | 16 ± 1 | 18 ± 1**
Alkaline phosphatase (IU/L) | 165 ± 6 | 192 ± 9* | 229 ± 10** | 261 ± 15** | 238 ± 13** | 247 ± 17**
Cholesterol (mg/dL) | 132 ± 6 | 135 ± 4 | 137 ± 6 | 149 ± 5* | 182 ± 6** | 268 ± 15**
Triglycerides (mg/dL) | 71 ± 6 | 82 ± 5 | 74 ± 4 | 96 ± 8* | 118 ± 11** | 137 ± 6**
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Alanine aminotransferase (IU/L) | 49 ± 1 | 48 ± 2 | 48 ± 3 | 50 ± 1 | 51 ± 2 | 62 ± 4**
Sorbitol dehydrogenase (IU/L) | 11 ± 1 | 10 ± 0 | 12 ± 1 | 12 ± 0 | 13 ± 1 | 18 ± 2**
Alkaline phosphatase (IU/L) | 12 1± 6 | 147 ± 12 | 185 ± 10** | 201 ± 12** | 227 ± 12** | 216 ± 15**
Bile salts (µmol/L) | 12.5 ± 5.5 | 16.0 ± 2.5 | 13.6 ± 4.0 | 33.8 ± 6.5** | 33.5 ± 6.0** | 14.7 ± 3.1**
Cholesterol (mg/dL) | 110 ± 6 | 117 ±2 | 128 ± 3* | 141 ± 5** | 189 ± 6** | 261 ± 10**
Triglycerides (mg/dL) | 51 ± 4 | 53 ± 6 | 44 ± 4 | 58 ± 4 | 83 ± 5** | 115 ± 9**

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

There were significant exposure concentration-dependent increases in cholesterol and triglyceride concentrations in males exposed to 500 ppm or greater (Table 3 and Table F-1). In females, cholesterol concentrations were significantly increased in groups exposed to 250 ppm or greater and triglyceride concentrations were significantly increased in the 1,000 and 2,000 ppm groups. Although the exact mechanism is not known, these increases were most likely due to alterations in lipid metabolism and the toxicologic significance is unknown.

There were significant exposure concentration-related increases in the absolute and relative liver weights of males exposed to 250 ppm or greater; the absolute liver weight of the 2,000 ppm group was 180% of that of the chamber controls (Table 4 and Table G-1). The absolute liver weight of 125 ppm males was also significantly increased, but the relative liver weight was not significantly increased. The absolute and relative liver weights of females exposed to 500 ppm or greater were significantly increased compared to those of the chamber controls. Among females, the mean absolute liver weight was highest in the 2,000 ppm group (240% of that in the chamber controls).

Table 4 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 393 ± 7 | 426 ± 5* | 414 ± 11 | 412 ± 11 | 401 ± 7 | 376 ± 6
R. Kidney
Absolute | 1.28 ± 0.04 | 1.46 ± 0.02** | 1.48 ± 0.03** | 1.57 ± 0.04** | 1.61 ± 0.04** | 1.58 ± 0.06**
Relative | 3.24 ± 0.05 | 3.44 ± 0.06 | 3.57 ± 0.06** | 3.82 ± 0.07** | 4.00 ± 0.05** | 4.20 ± 0.14**
Liver
Absolute | 12.22 ± 0.38 | 13.74 ± 0.21* | 14.41 ± 0.56** | 16.56 ± 0.65** | 19.34 ± 0.49** | 22.02 ± 0.69**
Relative | 31.03 ± 0.56 | 32.32 ± 0.50 | 34.79 ± 0.83** | 40.18 ± 1.10** | 48.25 ± 1.26** | 58.48 ± 1.29**
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy body wt | 240 ± 5 | 249 ± 5 | 255 ± 6 | 259 ± 5* | 267 ± 9** | 294 ± 8**
R. Kidney
Absolute | 0.84 ± 0.01 | 0.89 ± 0.02 | 0.94 ± 0.03* | 0.94 ± 0.02* | 0.94 ± 0.04* | 1.06 ± 0.03**
Relative | 3.51 ± 0.05 | 3.58 ± 0.05 | 3.67 ± 0.06 | 3.64 ± 0.06 | 3.50 ± 0.07 | 3.62 ± 0.08
Liver
Absolute | 7.07 ± 0.19 | 7.47 ± 0.26 | 7.93 ± 0.21 | 8.82 ± 0.23** | 11.10 ± 0.51** | 16.95 ± 0.52**
Relative | 29.50 ± 0.39 | 30.00 ± 0.72 | 31.15 ±0 .48 | 34.05 ± 0.51** | 41.58 ± 1.27** | 57.75 ± 1.47**
Thymus
Absolute | 0.254 ± 0.012 | 0.258 ± 0.013 | 0.265 ± 0.014 | 0.241 ± 0.017 | 0.257 ± 0.015 | 0.238 ± 0.020
Relative | 1.062 ± 0.049 | 1.037 ± 0.049 | 1.038 ± 0.049 | 0.925 ± 0.056 | 0.964 ± 0.050 | 0.804 ± 0.059**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Absolute kidney weights were significantly increased in all exposed groups of males (up to 126% of the chamber control group in the 1,000 ppm group), and relative kid-ney weights were significantly increased in males exposed to 250 ppm or greater (Table 4 and Table G-1). In females, the absolute kidney weights were significantly increased in groups exposed to 250 ppm or greater, but the relative kidney weights were not significantly increased.

There was a significant decrease in the relative thymus weight in 2,000 ppm females, but there was no change in absolute thymus weight and no histologic lesions associated with the change in relative weight (Table 4 and Table G-1).

Absolute heart weights were significantly increased in 125 ppm males and in females exposed to 500 ppm or greater, but there were no changes in relative heart weights and these increases were not considered to be related to chemical exposure (Table G-1).

There were no gross lesions associated with exposure to p-chloro-α,α,α-trifluorotoluene. Significant histologic lesions were recorded in the liver, Harderian gland, adrenal cortex, and kidney of males and females, in the mammary gland of females, and in the testes and epididymides of males.

In the liver, incidences of centrilobular hepatocyte hypertrophy were significantly increased in males exposed to 250 ppm or greater and in females exposed to 1,000 or 2,000 ppm compared to those of the respective chamber control groups (Table 5). Two 2,000 ppm males and one 1,000 ppm male had necrosis of the liver. Hepatocyte hypertrophy was centrilobular to midzonal in location and was characterized by an increase in the size of the hepatocytes. Hepatocellular hypertrophy corresponded to increased liver weights in males exposed to 250 ppm or greater. In females, hepatocellular hypertrophy occurred in the 1,000 and 2,000 ppm groups. Hypertrophy was not recorded in the 500 ppm group despite the 15% increase in relative liver weight in this group. Due to the natural variation in the size of hepatocytes, hypertrophy is sometimes difficult to discern histologically until liver weights are increased more than 20%^70^. Necrosis was characterized by small foci of pale-staining hepatocytes lacking cellular detail or brightly eosinophilic individual hepatocytes with pyknotic nuclei.

Table 5 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
Adrenal Cortex^a^ | 10 | 10 | 10 | 10 | 10 | 10
Vacuolization Cytoplasmic^b^ | 0 | 0 | 0 | 0 | 0 | 7** (1.0)^c^
Epididymis | 10 | 10 | 10 | 10 | 10 | 10
Duct, Exfoliated Germ Cell | 0 | 0 | 1 (4.0) | 0 | 1 (1.0) | 6** (1.5)
Harderian Gland | 10 | 10 | 10 | 10 | 10 | 10
Degeneration | 0 | 1 (1.0) | 9** (1.1) | 10** (1.4) | 10** (1.1) | 10** (2.0)
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Accumulation, Hyaline Droplet | 10 (1.0) | 10 (1.0) | 10 (1.6) | 10 (2.0) | 10 (3.0) | 10 (3.0)
Nephropathy, Chronic | 10 (1.6) | 10 (1.3) | 10 (1.5) | 10 (1.7) | 10 (1.7) | 10 (2.6)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 8** (1.0) | 10** (1.0) | 10** (1.9) | 10** (2.0)
Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 2 (2.0)
Testes | 10 | 10 | 10 | 10 | 10 | 10
Germ Cell, Degeneration | 0 | 0 | 1 (4.0) | 0 | 2 (1.0) | 6** (1.3)
Seminiferous Tubule, Spermatid Retention | 0 | 0 | 0 | 3 (1.3) | 4* (1.5) | 4* (1.5)
Female
Adrenal Cortex | 10 | 10 | 10 | 10 | 10 | 10
Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 4* (1.0) | 10** (1.0)
Harderian Gland | 10 | 10 | 10 | 10 | 10 | 10
Degeneration | 0 | 3 (1.0) | 5* (1.0) | 9** (1.1) | 10** (1.5) | 10** (2.0)
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Nephropathy, Chronic | 7 (1.0) | 4 (1.0) | 7 (1.0) | 9 (1.2) | 10 (1.1) | 10 (1.6)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 10** (1.3) | 10** (2.0)
Mammary Gland | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia | 1 (1.0) | 0 | 0 | 4 (1.3) | 6* (1.3) | 10** (1.9)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Degeneration of the Harderian gland occurred in all exposure groups, and the incidences were significantly increased in males and females exposed to 250 ppm or greater (Table 5). Degeneration was characterized by clusters of shrunken, hypereosinophilic cells lacking cellular detail and containing pyknotic nuclei (Figure 8 and Figure 9). Occasionally, sloughed cells could be found in the lumens of acini or ducts. Enlarged nuclei and cellular piling could be seen as evidence of regeneration, which was seen occasionally as part of the degenerative process.

Figure 8

Normal Harderian Gland in a Chamber Control Male Rat in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene (H&E)

The cells of the gland are large and have abundant, foamy cytoplasm due to numerous vacuoles.

Figure 9

Degeneration in the Harderian Gland of a Male Rat Exposed to 2,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months (H&E)

Compared to the normal Harderian gland in Figure 8, the epithelial cells are smaller and more eosinophilic.

In the adrenal cortex, there were significantly increased incidences of cytoplasmic vacuolization in 2,000 ppm males and 1,000 and 2,000 ppm females (Table 5). Focal areas of cells of the zona fasciculata contained numerous small, round, cytoplasmic vacuoles. At times, this vacuolization caused some enlargement of the cytoplasm, and subsequently the adrenal cortex, but the primary lesion was considered to be the microvesicular droplets within the cytoplasm.

In the kidney, the severities of hyaline droplet accumulation and chronic nephropathy generally increased with increasing exposure concentration in males (Table 5). In females, there were more occurrences of chronic nephropathy in the 1,000 and 2,000 ppm groups, although there was no pairwise significance between the incidences of nephropathy in groups of exposed females and the chamber controls. Hyaline droplet accumulation was characterized by fine eosinophilic droplets randomly dispersed throughout the cytoplasm of renal tubule cells. These droplets stained prominently with Mallory-Heidenhain stain, consistent with α2u-globulin (Figure 10 and Figure 11). In 2,000 ppm males, the droplets were increased in number, and occasionally in size, with the presence of some angular and crystalline forms. The appearance of more, larger, and angular or crystalline forms of hyaline droplets is consistent with hyaline droplet nephropathy, however, other changes typically observed in clear cases of hyaline droplet nephropathy (such as degeneration, necrosis, and granular casts) were lacking, suggesting that this might be a mild response. Chronic progressive nephropathy was typical of that seen in rats, and was characterized by regenerating tubules, thickened basement membranes, interstitial inflammation, and hyaline casts. Increases in the severities of hyaline droplet accumulation and chronic progressive nephropathy corresponded to increases in kidney weights.

Figure 10

Normal Kidney (Stained with Mallory-Heidenhain Stain) in a Chamber Control Male Rat in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Hyaline droplets stain bright red, and compared to the exposed animal (Figure 11), there are not many droplets found in the renal tubule epithelium. Erythrocytes also stain very bright red, and are found in vessels located between renal tubules.

Figure 11

Hyaline Droplet Accumulation in the Kidney (Stained with Mallory-Heidenhain Stain) of a Male Rat Exposed to 2,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months

Within the proximal tubule epithelial cells there are numerous small, bright red droplets consistent with alpha-2u-globulin protein.

The incidences of mammary gland hyperplasia were significantly increased in 1,000 and 2,000 ppm females (Table 5). Hyperplasia consisted of an increase in the number and size of the glandular acini. Glandular epithelial cells were often increased in size and contained multiple small, clear vacuoles.

Incidences of seminiferous tubule, spermatid retention in the testis were significantly increased in males exposed to 1,000 or 2,000 ppm, and germ cell degeneration in the testis and exfoliated germ cell in the epididymis duct were significantly increased in 2,000 ppm males (Table 5). Spermatid retention, or delayed spermiation, was evaluated by examining stage IX through XII tubules at high power. Spermatid retention was characterized by the presence of step 19 spermatids at the luminal surface, within the germinal epithelium, or at the base in stage IX through XII tubules. These mature spermatids should normally be released during stage VIII. A number of changes comprised the diagnosis of germ cell degeneration in the testes. These primarily involved tubular vacuolation and apoptosis of germ cells. Vacuolation was seen as both macrovacuolation (a single large, well-demarcated vacuole) and microvacuolation (multiple, small, sometimes poorly delineated vacuoles with pale, wispy cytoplasm). Microvacuolation was often associated with focal germinal epithelium disorganization or a focal cohort of germ cell loss. Apoptotic germ cells were characterized by cytoplasmic eosinophilia and nuclear pyknosis. Germ cell degeneration was a multifocal lesion, affecting scattered tubules and numerous stages. Less often, degenerating germ cells included multinucleated giant cell forms. Partial depletion of germ cells, segmental germ cell loss, disordered arrangement of the germ cell layers, and decreased elongated spermatids each occurred less frequently then apoptosis and vacuolation, but were also considered to be components of degeneration. Exfoliated germ cells in the epididymis were characterized by the presence of intact, round cells intermixed with cell debris and mature sperm within the epididymal duct lumina that exceeded the level of occasional sloughed cells in chamber control animals.

Male rats exposed to 2,000 ppm had significantly decreased left cauda and left epididymis weights and numbers of sperm per cauda epididymis (Table 6 and Table H-1). Sperm motility was also significantly decreased in 1,000 and 2,000 ppm males. Female rats exposed to 2,000 ppm had decreased frequency of estrus and increased frequency of diestrus, a significantly higher probability of extended diestrus, a fewer number of cycles, and a fewer number of rats exhibiting cycles compared to the chamber control group (Table 6, Table H-2, Table H-3, and Figure H-1). p-Chloro-α,α,α-trifluorotoluene exposure via inhalation exhibited the potential to be a reproductive toxicant in male and female Hsd:Sprague Dawley^®^ SD^®^ rats.

Table 6 Summary of Reproductive Tissue Evaluations for Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
Male
n | 10 | 10 | 10 | 10
Weights (g)
L. Cauda epididymis | 0.273 ± 0.0146 | 0.283 ± 0.0066 | 0.256 ± 0.0065 | 0.212 ± 0.0065**
L. Epididymis | 0.648 ± 0.0280 | 0.669 ± 0.0147 | 0.625 ± 0.0164 | 0.555 ± 0.0128**
L. Testis | 1.920 ± 0.0896 | 2.069 ± 0.0361 | 1.976 ± 0.0503 | 1.978 ± 0.0233
Spermatid measurements
Spermatid heads (10^6^/testis) | 270.92 ± 22.197 | 303.18 ± 19.790 | 263.56 ± 10.265 | 265.95 ± 13.848
Spermatid heads (10^6^/g testis) | 138.97 ± 7.762 | 146.82 ± 10.025 | 133.51 ± 4.364 | 134.67 ± 7.351
Epididymal spermatozoal measurements
Sperm motility (%) | 76.9 ± 3.06 | 74.9 ± 3.33 | 68.7 ± 1.51* | 68.4 ± 1.67*
Sperm (10^6^/cauda epididymis) | 158.6 ± 7.14 | 164.8 ± 9.11 | 144.0 ± 10.22 | 123.6 ± 5.62**
Female
n | 10 | 10 | 10 | 3^b^
Number of estrous cycles | 2.2 ± 0.25 | 2.0 ± 0.26 | 1.9 ± 0.18 | 1.3 ± 0.33
Estrous stages (% of cycle)
Diestrus | 55.0 | 53.1 | 48.1 | 78.5
Proestrus | 10.6 | 5.6 | 7.5 | 0.7
Estrus | 33.8 | 37.5 | 42.5 | 14.6
Metestrus | 0.0 | 3.1 | 1.9 | 6.3

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (left cauda epididymis and left epididymis weights) or Shirley’s test (sperm/cauda epididymis).

^a^ Data for organ weights, epididymal spermatozoal measurements, and number of estrous cycles are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (numbers of estrous cycles). Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated that 2,000 ppm females spent significantly more time in extended diestrus (P < 0.001) than the chamber control group.

^b^ Estrous cyclicity samples were evaluated for 9 female rats; however, in 6 of 9 animals estrous cycles were longer than 16 days or unclear and were not included in these analyses.

Exposure Concentration Selection Rationale: Statistically significant exposure-related increases in liver weights (approximately 80% or greater) in 2,000 ppm males and females precluded the use of this concentration in the 2-year study. Due to logistical considerations regarding the number of whole body inhalation chambers that can be included in a study, the same p-chloro-α,α,α-trifluorotoluene exposure concentrations were selected for males and females: 100, 300, and 1,000 ppm. These concentrations were selected to accommodate logistical challenges while adequately challenging both males and females; half-log (base 10) spacing of exposure concentrations was selected to capture a wider exposure range.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 7 and in the Kaplan-Meier survival curves (Figure 3). There was a significant negative trend of survival in males and survival of the 1,000 ppm males was significantly less than that of the chamber controls, with only five animals surviving to the end of the study. Most of the early deaths occurred relatively late in the study and were due to nephropathy. Survival of exposed groups of females was similar to that of the chamber controls.

Table 7 Survival of Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 16 | 19 | 21 | 27
Natural deaths | 9 | 10 | 14 | 18
Animals surviving to study termination | 25 | 21 | 15 | 5
Percent probability of survival at end of study^a^ | 50 | 42 | 30 | 10
Mean survival (days)^b^ | 661 | 641 | 655 | 602
Survival analysis^c^ | P < 0.001 | P = 0.568 | P = 0.137 | P < 0.001
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^d^ | 0 | 1 | 0 | 0
Moribund | 22 | 27 | 18 | 18
Natural deaths | 5 | 1 | 7 | 2
Animals surviving to study termination | 23^e^ | 21 | 25 | 30
Percent probability of survival at end of study | 44 | 43 | 50 | 60
Mean survival (days) | 626 | 643 | 664 | 694
Survival analysis | P = 0.029N | P = 0.884N | P = 0.419N | P = 0.045N

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^40^ is in the chamber control column, and the results of the life table pairwise comparisons^39^ with the chamber controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^d^ Censored in the survival analysis.

^e^ Includes one animal that died during the last week of the study.

Figure 3

Kaplan-Meier Survival Curves for Rats Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years

#### Body Weights and Clinical Observations

Mean body weights of exposed groups of males were within 10% of the chamber controls with the exception of the 1,000 ppm group that was at least 10% less than the chamber controls for 3 weeks very early in the study (Figure 4; Table 8). Subsequent mean body weights for the 1,000 ppm group were within 10% of the chamber controls. Mean body weights of females exposed to 100 or 300 ppm were similar to those of the chamber controls throughout the study (Figure 4; Table 9). The mean body weights of 1,000 ppm females were similar to those of the chamber controls for most of the study and were approximately 10% less than the chamber controls from around day 506. There were no clinical observations that were clearly attributable to exposure, although there were more occurrences of abnormal breathing in the 100 and 300 ppm males and the 1,000 ppm females than in the chamber control groups.

Figure 4

Growth Curves for Rats Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years

Table 8 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Day | Chamber Control | | 100 ppm | | | 300 ppm | | | 1,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 120 | 50 | 120 | 100 | 50 | 119 | 99 | 50 | 119 | 99 | 50
9 | 177 | 50 | 177 | 100 | 50 | 173 | 97 | 50 | 154 | 87 | 50
16 | 222 | 50 | 222 | 100 | 50 | 220 | 99 | 50 | 195 | 88 | 50
23 | 263 | 50 | 263 | 100 | 50 | 262 | 100 | 50 | 233 | 89 | 50
30 | 289 | 50 | 291 | 101 | 50 | 292 | 101 | 50 | 265 | 92 | 50
37 | 312 | 50 | 314 | 101 | 50 | 316 | 102 | 50 | 290 | 93 | 50
44 | 331 | 50 | 335 | 101 | 50 | 337 | 102 | 50 | 308 | 93 | 50
51 | 348 | 50 | 352 | 101 | 50 | 356 | 103 | 50 | 327 | 94 | 50
58 | 360 | 50 | 364 | 101 | 50 | 370 | 103 | 50 | 342 | 95 | 50
65 | 372 | 50 | 376 | 101 | 50 | 382 | 103 | 50 | 356 | 96 | 50
72 | 382 | 50 | 386 | 101 | 50 | 392 | 103 | 50 | 368 | 96 | 50
79 | 393 | 50 | 397 | 101 | 50 | 405 | 103 | 50 | 380 | 97 | 50
86 | 402 | 50 | 408 | 102 | 50 | 417 | 104 | 50 | 391 | 97 | 50
114 | 430 | 50 | 439 | 102 | 50 | 450 | 105 | 50 | 427 | 99 | 49
142 | 452 | 50 | 462 | 102 | 50 | 475 | 105 | 50 | 451 | 100 | 49
170 | 465 | 50 | 482 | 104 | 50 | 498 | 107 | 50 | 478 | 103 | 49
198 | 482 | 50 | 496 | 103 | 50 | 507 | 105 | 50 | 488 | 101 | 49
226 | 494 | 50 | 509 | 103 | 50 | 522 | 106 | 50 | 499 | 101 | 49
254 | 508 | 50 | 523 | 103 | 50 | 541 | 107 | 50 | 517 | 102 | 49
282 | 517 | 50 | 536 | 104 | 50 | 554 | 107 | 50 | 528 | 102 | 49
310 | 532 | 50 | 550 | 104 | 47 | 568 | 107 | 50 | 542 | 102 | 49
338 | 541 | 50 | 559 | 103 | 46 | 579 | 107 | 50 | 554 | 102 | 49
366 | 554 | 50 | 574 | 104 | 45 | 591 | 107 | 50 | 565 | 102 | 49
394 | 561 | 49 | 582 | 104 | 45 | 595 | 106 | 50 | 569 | 102 | 49
422 | 567 | 49 | 590 | 104 | 45 | 601 | 106 | 50 | 573 | 101 | 48
450 | 574 | 49 | 599 | 104 | 45 | 610 | 106 | 50 | 577 | 101 | 47
478 | 583 | 49 | 606 | 104 | 45 | 614 | 105 | 48 | 581 | 100 | 45
506 | 591 | 45 | 612 | 104 | 44 | 617 | 104 | 47 | 586 | 99 | 41
534 | 594 | 43 | 615 | 104 | 42 | 623 | 105 | 42 | 587 | 99 | 38
562 | 605 | 41 | 620 | 102 | 41 | 625 | 103 | 42 | 590 | 97 | 35
590 | 609 | 36 | 627 | 103 | 38 | 617 | 101 | 40 | 585 | 96 | 29
618 | 608 | 35 | 626 | 103 | 36 | 620 | 102 | 33 | 582 | 96 | 24
646 | 605 | 34 | 624 | 103 | 32 | 612 | 101 | 30 | 570 | 94 | 22
660 | 598 | 33 | 617 | 103 | 30 | 612 | 102 | 29 | 565 | 95 | 18
674 | 601 | 29 | 619 | 103 | 29 | 607 | 101 | 27 | 561 | 93 | 14
688 | 599 | 28 | 616 | 103 | 26 | 608 | 102 | 25 | 565 | 94 | 12
702 | 595 | 28 | 612 | 103 | 25 | 605 | 102 | 20 | 543 | 91 | 12
716 | 591 | 28 | 607 | 103 | 23 | 598 | 101 | 19 | 554 | 94 | 7
Mean for Weeks
1–13 | 305 | – | 308 | 101 | – | 311 | 102 | – | 287 | 94 | –
14–52 | 491 | – | 506 | 103 | – | 522 | 106 | – | 498 | 101 | –
53–103 | 590 | – | 609 | 103 | – | 610 | 103 | – | 572 | 97 | –

Table 9 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Day | Chamber Control | | 100 ppm | | | 300 ppm | | | 1,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 112 | 50 | 112 | 99 | 50 | 111 | 99 | 50 | 110 | 98 | 50
9 | 145 | 50 | 145 | 100 | 50 | 141 | 97 | 50 | 137 | 94 | 50
16 | 164 | 50 | 164 | 100 | 50 | 161 | 98 | 50 | 163 | 100 | 50
23 | 182 | 50 | 183 | 101 | 50 | 180 | 99 | 50 | 183 | 101 | 50
30 | 193 | 50 | 196 | 101 | 50 | 193 | 100 | 50 | 198 | 103 | 50
37 | 205 | 50 | 209 | 102 | 50 | 206 | 101 | 50 | 210 | 103 | 50
44 | 213 | 50 | 217 | 102 | 50 | 215 | 101 | 50 | 218 | 102 | 50
51 | 222 | 50 | 226 | 102 | 50 | 224 | 101 | 50 | 225 | 102 | 50
58 | 228 | 50 | 233 | 102 | 50 | 230 | 101 | 50 | 232 | 102 | 50
65 | 233 | 50 | 239 | 103 | 49 | 235 | 101 | 50 | 238 | 102 | 50
72 | 237 | 50 | 244 | 103 | 49 | 241 | 101 | 50 | 242 | 102 | 50
79 | 242 | 50 | 248 | 102 | 49 | 245 | 101 | 50 | 246 | 102 | 50
86 | 246 | 50 | 252 | 103 | 49 | 250 | 102 | 50 | 250 | 102 | 50
114 | 260 | 50 | 269 | 104 | 49 | 265 | 102 | 50 | 266 | 102 | 50
142 | 270 | 50 | 277 | 103 | 49 | 273 | 101 | 50 | 271 | 100 | 50
170 | 275 | 50 | 287 | 104 | 49 | 285 | 104 | 50 | 282 | 102 | 50
198 | 284 | 50 | 294 | 104 | 49 | 287 | 101 | 50 | 283 | 100 | 50
226 | 288 | 50 | 294 | 102 | 49 | 293 | 102 | 50 | 286 | 99 | 50
254 | 295 | 50 | 305 | 103 | 49 | 303 | 103 | 50 | 291 | 99 | 50
282 | 300 | 50 | 311 | 104 | 49 | 306 | 102 | 50 | 296 | 99 | 50
310 | 305 | 49 | 317 | 104 | 49 | 313 | 103 | 50 | 300 | 98 | 50
338 | 310 | 47 | 324 | 105 | 49 | 320 | 103 | 50 | 304 | 98 | 50
366 | 319 | 47 | 331 | 104 | 49 | 326 | 102 | 50 | 306 | 96 | 50
394 | 325 | 46 | 338 | 104 | 49 | 332 | 102 | 50 | 312 | 96 | 50
422 | 332 | 46 | 343 | 103 | 48 | 339 | 102 | 49 | 314 | 95 | 50
450 | 341 | 45 | 349 | 102 | 48 | 348 | 102 | 49 | 317 | 93 | 50
478 | 349 | 44 | 355 | 102 | 45 | 353 | 101 | 45 | 321 | 92 | 50
506 | 360 | 43 | 368 | 102 | 45 | 361 | 100 | 45 | 324 | 90 | 50
534 | 362 | 38 | 371 | 102 | 41 | 368 | 102 | 44 | 327 | 91 | 49
562 | 365 | 33 | 375 | 103 | 39 | 375 | 103 | 42 | 328 | 90 | 47
590 | 367 | 31 | 382 | 104 | 38 | 374 | 102 | 39 | 333 | 91 | 45
618 | 377 | 29 | 386 | 102 | 35 | 380 | 101 | 37 | 331 | 88 | 43
646 | 374 | 27 | 371 | 99 | 30 | 381 | 102 | 34 | 338 | 91 | 39
674 | 377 | 25 | 375 | 99 | 24 | 390 | 104 | 30 | 338 | 90 | 35
702 | 370 | 24 | 376 | 102 | 22 | 386 | 104 | 27 | 335 | 90 | 30
Mean for Weeks
1–13 | 202 | – | 205 | 101 | – | 202 | 100 | – | 204 | 101 | –
14–52 | 287 | – | 298 | 104 | – | 294 | 102 | – | 287 | 100 | –
53–101 | 355 | – | 363 | 102 | – | 363 | 102 | – | 325 | 92 | –

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the thyroid gland, lung, adrenal medulla, uterus, liver, kidney, nose, adrenal cortex, small intestine, mammary gland, pituitary gland, and brain. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Thyroid Gland: Compared to those of the chamber controls, there were significantly increased incidences of C-cell adenoma and C-cell adenoma or carcinoma (combined) in 1,000 ppm males and females; the combined incidence in 100 ppm females was also significantly increased (Table 10, Table A-1, Table A-2, Table B-1, and Table B-2). The incidences of C-cell hyperplasia in exposed groups of males and females were similar to those in the chamber control groups (Table 10, Table A-3 and Table B-3). C-cell adenomas consisted of discrete proliferations of C-cells that were larger than five follicles in diameter and caused compression of surrounding follicles (Figure 12). C-cell carcinomas tended to be large, and were diagnosed when there was evidence of invasion of the thyroid gland capsule or surrounding tissue (Figure 13).

Table 10 Incidences of Neoplasms and Nonneoplastic Lesions of the Thyroid Gland in Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Male
Number Examined Microscopically | 50 | 49 | 49 | 50
C-cell, Hyperplasia^a^ | 16 (1.4)^b^ | 12 (1.7) | 14 (1.6) | 15 (1.5)
Bilateral, C-cell, Adenoma | 0 | 1 | 1 | 1
C-cell Adenoma (includes bilateral)^c^
Overall rate^d^ | 2/50 (4%) | 5/49 (10%) | 3/49 (6%) | 12/50 (24%)
Adjusted rate^e^ | 5.1% | 13.4% | 7.9% | 36.3%
Terminal rate^f^ | 2/25 (8%) | 4/21 (19%) | 1/15 (7%) | 3/5 (60%)
First incidence (days) | 729 (T) | 680 | 669 | 568
Poly-3 test^g^ | P < 0.001 | P = 0.192 | P = 0.482 | P < 0.001
C-cell, Carcinoma^h^ | 1 | 0 | 1 | 1
C-cell Adenoma or Carcinoma^i^
Overall rate | 3/50 (6%) | 5/49 (10%) | 4/49 (8%) | 13/50 (26%)
Adjusted rate | 7.6% | 13.4% | 10.6% | 39.2%
Terminal rate | 3/25 (12%) | 4/21 (19%) | 1/15 (7%) | 3/5 (60%)
First incidence (days) | 729 (T) | 680 | 669 | 568
Poly-3 test | P < 0.001 | P = 0.326 | P = 0.481 | P < 0.001
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
C-cell, Hyperplasia | 16 (1.4) | 15 (1.2) | 21 (1.4) | 13 (1.9)
Bilateral, C-cell, Adenoma | 0 | 0 | 0 | 3
C-cell Adenoma (includes bilateral)^j^
Overall rate | 2/50 (4%) | 8/50 (16%) | 8/50 (16%) | 14/50 (28%)
Adjusted rate | 5.5% | 20.4% | 20.2% | 31.6%
Terminal rate | 0/22 (0%) | 3/21 (14%) | 8/25 (32%) | 11/30 (37%)
First incidence (days) | 459 | 534 | 731 (T) | 646
Poly-3 test | P = 0.008 | P = 0.056 | P = 0.057 | P = 0.003
C-cell, Carcinoma^k^ | 0 | 2 | 0 | 1
C-cell Adenoma or Carcinoma^j^
Overall rate | 2/50 (4%) | 10/50 (20%) | 8/50 (16%) | 15/50 (30%)
Adjusted rate | 5.5% | 25.5% | 20.2% | 33.6%
Terminal rate | 0/22 (0%) | 5/21 (24%) | 8/25 (32%) | 11/30 (37%)
First incidence (days) | 459 | 534 | 731 (T) | 646
Poly-3 test | P = 0.009 | P = 0.017 | P = 0.057 | P = 0.002

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for all routes of 2-year studies (incidence per study): 15/100 (2/50, 13/50).

^d^ Number of animals with neoplasm per number of animals with thyroid gland examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Historical control incidence: 1/100 (1/50, 0/50).

^i^ Historical control incidence: 16/100 (3/50, 13/50).

^j^ Historical control incidence: 13/99 (2/50, 11/49).

^k^ Historical control incidence: 0/99 (0/50, 0/49).

Figure 12

C-cell Adenoma in the Thyroid Gland of a Female Rat Exposed to 1,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The adenoma is a discrete mass, typically larger than five average sized follicles, composed of proliferations of C-cells.

Figure 13

C-cell carcinoma in the Thyroid Gland of a Female Rat Exposed to 1,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The large mass has completely effaced the normal architecture of the thyroid gland and has invaded through the capsule of the gland and into the trachea (arrows), causing compression of the tracheal lumen (T).

Lung: In males, alveolar/bronchiolar adenoma and alveolar/bronchiolar carcinoma were only observed in the 100 and 1,000 ppm groups, although the incidences were not significantly different from those of the chamber controls (Table 11 and Table A-1). No alveolar/bronchiolar neoplasms were observed in females (Table B-1). Alveolar/bronchiolar adenomas were well demarcated, densely cellular proliferations of cuboidal to columnar cells forming short projections into alveolar spaces and causing compression of the surrounding parenchyma. Alveolar/bronchiolar carcinomas were larger, and often poorly demarcated and composed of pleomorphic cells forming different patterns of growth (Figure 14 and Figure 15).

Table 11 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Fibrosis^a^ | 8 (1.4)^b^ | 22** (1.5) | 28** (1.4) | 24** (1.8)
Hemorrhage | 11 (1.2) | 23* (1.7) | 28** (1.5) | 28** (1.7)
Inflammation, Chronic | 32 (1.2) | 42* (1.5) | 47** (1.4) | 45** (1.8)
Alveolar/bronchiolar Adenoma^c^ | 0 | 2 | 0 | 1
Alveolar/bronchiolar Carcinoma^c^
Overall rate^d^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate^e^ | 0.0% | 0.0% | 0.0% | 6.4%
Terminal rate^f^ | 0/25 (0%) | 0/21 (0%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | –^h^ | – | – | 549
Poly-3 test^g^ | P = 0.032 | –^i^ | – | P = 0.191
Alveolar/bronchiolar Adenoma or Carcinoma^c^
Overall rate | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 5.3% | 0.0% | 9.3%
Terminal rate | 0/25 (0%) | 1/21 (5%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 650 | – | 516
Poly-3 test | P = 0.073 | P = 0.228 | – | P = 0.086
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Fibrosis | 11 (1.0) | 17 (1.1) | 24** (1.4) | 28** (1.4)
Hemorrhage | 12 (1.1) | 11 (1.5) | 18 (1.4) | 26* (1.4)
Inflammation, Chronic | 35 (1.2) | 42* (1.2) | 48** (1.4) | 46* (1.4)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for all routes of 2-year studies (incidence per study): 0/99 (0/50, 0/49).

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

Figure 14

Alveolar/Bronchiolar Carcinoma in the Lung of a Male Rat Exposed to 1,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

Figure 15

Higher Magnification of Figure 14 (H&E)

Cells have lost their orderly arrangement and are piling up (arrowheads). Note also the variation in nuclear size and the mitotic figure (arrow).

Although the chamber control groups had fairly high incidences of chronic inflammation, there were significantly increased incidences of chronic inflammation in all exposed groups of males and females (Table 11, Table A-3, and Table B-3). There were significantly increased incidences of fibrosis in all exposed male groups and in 300 and 1,000 ppm females, and significantly increased incidences of hemorrhage in all groups of exposed males and in 1,000 ppm females. Chronic inflammation of collections of large, foamy macrophages, with fewer neutrophils and lymphocytes, within the alveolar spaces and the interstitium. Multinucleated giant cells were seen in many areas of inflammation, often containing phagocytosed cells or debris. Hemorrhage was characterized by red blood cells and fibrin within the alveolar spaces or the interstitium, often in perivascular areas (Figure 16). Evidence of the antemortem nature of the hemorrhage was provided by the presence of erythrophagocytosis. Thickening of the interstitium by fibrous connective tissue, which on occasion progressed to fibrous nodules that protruded into alveolar and bronchiolar spaces, was diagnosed as fibrosis (Figure 17). This diagnosis was recorded only when the amount of fibrosis exceeded that which would be expected in a typical focus of chronic inflammation. Fibrosis was often associated with areas of hemorrhage and fibrin, with the fibrosis almost appearing to be forming as part of the organization of fibrin. Inflammation, hemorrhage and fibrosis were usually seen together, with the degree of severity of inflammation generally corresponding to the amount of hemorrhage and fibrosis.

Figure 16

Hemorrhage in the Lung of a Male Rat Exposed to 1,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

Hemorrhage is within the alveolar spaces, along with erythrophagocytosis, thrombin, and inflammatory cells. Alveolar septae are thickened due to inflammation and fibrosis.

Figure 17

Fibrosis in the Lung of a Female Rat Exposed to 300 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

Note the fibrous connective tissue (asterisks) within the interstitium.

Adrenal Medulla: There was a significantly increased incidence of benign pheochromocytoma in 1,000 ppm females (Table 12, Table B-1, and Table B-2). The incidences of medullary hyperplasia were also significantly increased in 300 and 1,000 ppm females (Table 12 and Table B-3). Benign pheochromocytoma was diagnosed when there was a well-demarcated, expansile proliferation of mildly pleomorphic medullary cells arranged in large trabeculae or solid clusters (Figure 18). Hyperplasia was characterized by a focal area of increased cellularity with no compression of the surrounding tissue; hyperplastic cells were typically smaller and more basophilic than normal medullary cells.

Table 12 Incidences of Neoplasms and Nonneoplastic Lesions of the Adrenal Medulla in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Number Examined Microscopically | 49 | 50 | 50 | 50
Hyperplasia^a^ | 17 (1.1)^b^ | 25 (1.6) | 34** (1.1) | 36** (1.5)
Benign Pheochromocytoma^c^
Overall rate^d^ | 0/49 (0%) | 3/50 (6%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate^e^ | 0.0% | 8.1% | 9.9% | 13.5%
Terminal rate^f^ | 0/21 (0%) | 2/21 (10%) | 2/25 (8%) | 4/30 (13%)
First incidence (days) | –^h^ | 691 | 478 | 530
Poly-3 test^g^ | P = 0.066 | P = 0.135 | P = 0.085 | P = 0.035

** Significantly different (P ≤ 0.01) from the chamber control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for all routes of 2-year studies (incidence per study): 0/99 (0/49, 0/50).

^d^ Number of animals with neoplasm per number of animals with adrenal medulla examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Not applicable; no neoplasms in animal group.

Figure 18

Benign Pheochromocytoma in the Adrenal Medulla of a Female Rat Exposed to 1,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The well demarcated mass is compressing the adjacent, normal medulla (arrows).

Uterus: There was a positive trend in the incidences of adenocarcinoma (Table 13, Table B-1, and Table B-2). Adenocarcinomas were characterized by poorly circumscribed proliferations of cuboidal to columnar epithelial cells that displayed pleomorphism and atypia. The cells were arranged in papillary or glandular structures, and there was effacement of the normal parenchyma and invasion into the underlying musculature. Atypical hyperplasia occurred in the 300 and 1,000 ppm groups, but the incidences were not significantly increased compared to the chamber control group (Table 13 and Table B-3). It has been reported that atypical hyperplasia can progress to adenocarcinoma^71^. Atypical hyperplasia was characterized by clusters of enlarged glands lined by thickened, disorganized epithelium; epithelial cells displayed loss of nuclear polarization, karyomegaly, mitoses, and cellular pleomorphism.

Table 13 Incidences of Neoplasms and Nonneoplastic Lesions of the Uterus in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Atypical Hyperplasia^a^ | 0 | 0 | 1 (2.0)^b^ | 3 (2.3)
Adenocarcinoma^c^
Overall rate^d^ | 1/50 (2%) | 1/50 (2%) | 0/50 (0%) | 5/50 (10%)
Adjusted rate^e^ | 2.9% | 2.7% | 0.0% | 11.3%
Terminal rate^f^ | 1/22 (5%) | 1/21 (5%) | 0/25 (0%) | 3/30 (10%)
First incidence (days) | 731 (T) | 731 (T) | –^h^ | 530
Poly-3 test^g^ | P = 0.017 | P = 0.748N | P = 0.475N | P = 0.166
Stromal Polyp, Multiple | 0 | 1 | 4 | 2
Stromal Polyp (includes multiple)
Overall rate | 7/50 (14%) | 9/50 (18%) | 16/50 (32%) | 12/50 (24%)
Adjusted rate | 19.6% | 23.8% | 39.3% | 27.2%
Terminal rate | 5/22 (23%) | 6/21 (29%) | 12/25 (48%) | 10/30 (33%)
First incidence (days) | 590 | 643 | 558 | 646
Poly-3 test | P = 0.419 | P = 0.440 | P = 0.047 | P = 0.298
Stromal Sarcoma | 0 | 0 | 1 | 0
Stromal Polyp or Stromal Sarcoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 17/50 (34%) | 12/50 (24%)
Adjusted rate | 19.6% | 23.8% | 41.8% | 27.2%
Terminal rate | 5/22 (23%) | 6/21 (29%) | 13/25 (52%) | 10/30 (33%)
First incidence (days) | 590 | 643 | 558 | 646
Poly-3 test | P = 0.439 | P = 0.440 | P = 0.028 | P = 0.298

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ No historical controls are available for uterine findings due to a protocol change for uterine pathology sectioning.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^h^ Not applicable; no neoplasms in animal groupendometrial glands. A single stromal sarcoma occurred in the 300 ppm group. This sarcoma was composed of spindle-shaped cells with elongated, hyperchromatic nuclei. The sarcoma was poorly demarcated with indistinct borders and infiltrated surrounding tissues.

There was a significantly increased incidence of stromal polyp in 300 ppm females (Table 13, Table B-1, and Table B-2). Histologically, stromal polyps were exophytic nodules that projected into the uterine lumen. They were covered by normal-appearing endometrial surface epithelium and supported by a broad stalk of endometrial stroma with blood vessels and occasionally endometrial glands. A single stromal sarcoma occurred in the 300 ppm group. This sarcoma was composed of spindle-shaped cells with elongated, hyperchromatic nuclei. The sarcoma was poorly demarcated with indistinct borders and infiltrated surrounding tissues.

Liver: There were significantly increased incidences of centrilobular hepatocyte hypertrophy in all exposed male groups and in 300 and 1,000 ppm females and significantly increased incidences of fatty change in 300 and 1,000 ppm males and females (Table 14, Table A-3, and Table B-3). There were significantly increased incidences of eosinophilic focus in 1,000 ppm males and mixed cell focus and clear cell focus in 1,000 ppm females; in all exposed male groups, there were significantly decreased incidences of clear cell focus. Hepatocellular adenoma or carcinoma (combined) occurred in three 100 ppm males, hepatocellular carcinoma occurred in one 1,000 ppm male, and cholangiocarcinoma occurred in two 100 ppm females (Table A-1, Table A-2, and Table B-1). These sporadic occurrences of liver neoplasms were not considered related to exposure.

Table 14 Incidences of Nonneoplastic Lesions of the Liver in Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Males
Number Examined Microscopically | 50 | 50 | 50 | 50
Centrilobular, Hepatocyte, Hypertrophy^a^ | 2 (1.0)^b^ | 17** (1.2) | 39** (1.5) | 47** (1.8)
Clear Cell Focus | 40 | 31* | 29** | 10**
Eosinophilic Focus | 1 | 5 | 6 | 8**
Fatty Change | 0 | 3 (1.3) | 7** (1.3) | 26** (1.2)
Females
Number Examined Microscopically | 50 | 50 | 50 | 50
Centrilobular, Hepatocyte, Hypertrophy | 0 | 1 (2.0) | 10** (1.1) | 45** (1.9)
Clear Cell Focus | 16 | 15 | 23 | 38**
Eosinophilic Focus | 7 | 6 | 7 | 15
Fatty Change | 2 (1.0) | 4 (1.0) | 11* (1.2) | 10* (1.3)
Mixed Cell Focus | 6 | 6 | 8 | 18*

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** (P ≤ 0.01).

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Centrilobular hepatocellular hypertrophy was characterized by an increased amount of granular cytoplasm causing an increase in the size of hepatocytes; occasionally nuclei of affected hepatocytes were also enlarged. Severity was based upon the amount of the hepatic lobule involved, with minimal hypertrophy diagnosed when hepatocytes adjacent to central veins were enlarged. Mild and moderate hypertrophy were diagnosed when a central veins were enlarged. Mild and moderate hypertrophy were diagnosed when a greater percentage of each lobule was involved, typically around 20% to 50% for mild and greater than 50% for moderate. Severe hypertrophy was recorded when the entire lobule was involved throughout the liver, giving the appearance of diffuse hypertrophy. Fatty change was primarily microvesicular in nature, consisting of scattered areas of hepatocytes with multiple small lipid vacuoles. Eosinophilic foci were areas of hepatocytes that were more eosinophilic than surrounding hepatocytes. The involved hepatocytes were occasionally larger, causing some compression of adjacent parenchyma, although not typically as much as would be seen with a hepatocellular adenoma. Also unlike a hepatocellular adenoma, foci did not tend to disrupt the lobular architecture of the liver. Mixed cell foci were made up of cells that resembled those of two different kinds of foci, typically eosinophilic and clear cell in this study. Clear cell foci were typically composed of small hepatocytes with clear cytoplasm, due to either multiple small vacuoles or a single large vacuole.

Kidney: Grossly, there were increased occurrences of granular kidneys in exposed male groups compared to the chamber controls. These changes corresponded histologically with increased severities of nephropathy in the exposed groups (Table 15 and Table A-3). Histologically, nephropathy was characterized by protein casts; dilated tubules with basophilic and attenuated to hypertrophic renal tubule epithelium; hyper- or hypocellular glomeruli; interstitial inflammation and fibrosis; and hyperplasia of the transitional epithelium of the renal pelvis. The severity of nephropathy was graded on a scale of 1 (minimal) to 4 (marked). Minimal nephropathy consisted of one to 15 tubules with the tubule changes listed above; mild nephropathy was diagnosed when 16 to 50 tubules were affected. Moderate nephropathy was diagnosed when there were coalescing areas of affected tubules and marked nephropathy was diagnosed when no or nearly no unaffected renal tubules were observed. There were more males in the 1,000 ppm group with marked severity than in the chamber control group (11, 13, 27, and 30 in the chamber control, 100, 300, and 1,000 ppm groups, respectively).

Table 15 Incidences of Selected Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Kidney^a^ | 50 | 50 | 50 | 50
Nephropathy^b^ | 49 (2.5)^c^ | 49 (2.7) | 50 (3.3) | 50 (3.4)
Nose | 50 | 50 | 50 | 50
Exudate | 8 (1.3) | 12 (1.0) | 12 (1.0) | 18** (1.1)

** Significantly different (P ≤ 0.01) from the chamber control group by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Nose: There was a significantly increased incidence of exudate in 1,000 ppm males (Table 15 and Table A-3). Histologically, this lesion was characterized by clusters of neutrophils within the lumen of the nasal cavity.

Other Tissues: In the adrenal cortex of females, low incidences of adenoma were observed in exposed groups, but the incidences were not statistically different from that of the chamber control group (Table B-1). There were also increased incidences of hyperplasia in exposed female groups, but the increases were not statistically significant (Table B-3). In the small intestine of males, adenocarcinoma occurred in three 100 ppm animals and one 300 ppm animal (Table A-1 and Table A-2). While not statistically significant, these lesions are unusual. In females, there were decreased, but generally not significantly, incidences of mammary gland fibroadenoma (1,000 ppm), adenoma (300 and 1,000 ppm), and adenocarcinoma (all exposed groups) compared to the chamber control group incidences (Table B-1 and Table B-2). In 1,000 ppm females, there was a significantly decreased incidence of pars distalis adenoma in the pituitary gland and a concomitant significantly decreased incidence of compression in the brain (hypothalamus) (Table B-1, Table B-2, and Table B-3). The biological significance of the findings described in this paragraph is unknown.

## Mice

### Three-month Study

All mice survived to the end of the study, and the final mean body weights and mean body weight gains of males exposed to 500 ppm or greater and females exposed to 250 ppm or greater were significantly greater than those of the chamber control groups; the mean body weight gain of 250 ppm males was also significantly increased (Table 16, Figure 5). The highest final mean body weights were found in 1,000 ppm males and females, which were 14% and 20% greater than those of the chamber control groups, respectively. A clinical observation of excitability was observed on days 8 and 17 of the study in the 2,000 ppm groups, but was not observed as the study continued.

Table 16 Survival and Body Weights of Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 21.6 ± 0.3 | 33.9 ± 0.6 | 12.2 ± 0.4 | –
125 | 10/10 | 21.9 ± 0.3 | 34.2 ± 1.0 | 12.3 ± 0.9 | 101
250 | 10/10 | 21.7 ± 0.3 | 35.8 ± 0.9 | 14.2 ± 0.7* | 106
500 | 10/10 | 21.5 ± 0.3 | 36. 9 ± 0.8** | 15.4 ± 0.6** | 109
1,000 | 10/10 | 21.8 ± 0.3 | 38.6 ± 0.8** | 16.7 ± 0.7** | 114
2,000 | 10/10 | 21.8 ± 0.3 | 36.8 ± 0.4** | 15.0 ± 0.4** | 109
Female
0 | 10/10 | 18.4 ± 0.3 | 28.2 ± 0.4 | 9.8 ± 0.3 | –
125 | 10/10 | 19.0 ± 0.3 | 29.9 ± 0.8 | 11.0 ± 0.7 | 106
250 | 10/10 | 18.5 ± 0.2 | 31.0 ± 0.7** | 12.5 ± 0.6** | 110
500 | 10/10 | 19.0 ± 0.3 | 32.2 ± 0.7** | 13.2 ± 0.7** | 114
1,000 | 10/10 | 18.7 ± 0.2 | 33.7 ± 0.8** | 15.0 ± 0.7** | 120
2,000 | 10/10 | 18.8 ± 0.3 | 29.7 ± 0.7** | 10.9 ± 0.6** | 106

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 5

Growth Curves for Mice Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months

Erythrocyte counts, hematocrit values, and packed cell volumes were significantly decreased in 2,000 ppm males and 1,000 and 2,000 ppm females compared to those in the chamber control groups (Table F-2). Hemoglobin concentration was also significantly decreased in the 2,000 ppm males and females. In males, reticulocyte counts were significantly decreased in the 1,000 and 2,000 ppm groups. These changes are consistent with mild erythroid suppression secondary to inflammation (forestomach and liver). Platelet counts in males exposed to 500 ppm or greater and in 1,000 and 2,000 ppm females were significantly increased; the mechanism is not known but may reflect increased production or altered peripheral distribution. Absolute liver weights were significantly increased in an exposure concentration-dependent manner in males and females exposed to 250 ppm or greater (Table 17 and Table G-2). Absolute liver weights in 2,000 ppm males and females were 277% and 212% of the chamber control liver weights, respectively. Relative liver weights were also significantly increased in males exposed to 250 ppm or greater and females exposed to 500 ppm or greater. In males, absolute kidney weights were significantly increased in groups exposed to 500 ppm or greater, with the greatest weight (131% of that of the chamber controls) in the 2,000 ppm group (Table 17 and Table G-2). Relative kidney weights were significantly increased in the 1,000 and 2,000 ppm groups of males. In females, absolute kidney weights were significantly increased in the 1,000 and 2,000 ppm groups, and relative kidney weight was significantly increased in the 2,000 ppm group. The increases in females were not as great as those in the males, with the greatest absolute kidney weight (115% of that of the chamber controls) occurring in the 2,000 ppm group. The increases in kidney weights were not associated with corresponding histologic changes in males or females.

Table 17 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 33.9 ± 0.6 | 34.2 ± 1.0 | 35.8 ± 0.9 | 36.9 ± 0.8** | 38.6 ± 0.8** | 36.8 ± 0.4**
R. Kidney
Absolute | 0.29 ± 0.01 | 0.30 ± 0.01 | 0.31 ± 0.01 | 0.32 ± 0.01* | 0.36 ± 0.01** | 0.38 ± 0.01**
Relative | 8.65 ± 0.14 | 8.86 ± 0.19 | 8.74 ± 0.20 | 8.75 ± 0.23 | 9.36 ± 0.23* | 10.28 ± 0.22**
Liver
Absolute | 1.30 ± 0.04 | 1.44 ± 0.06 | 1.65 ± 0.07** | 2.09 ± 0.07** | 3.07 ± 0.07** | 3.60 ± 0.05**
Relative | 38.43 ± 0.87 | 42.11 ± 1.30 | 46.01 ± 1.36** | 56.73 ± 1.84** | 79.75 ± 1.16** | 97.85 ± 1.59**
Thymus
Absolute | 0.038 ± 0.002 | 0.041 ± 0.003 | 0.044 ± 0.002 | 0.043 ± 0.003 | 0.043 ± 0.002 | 0.032 ± 0.002
Relative | 1.121 ± 0.056 | 1.196 ± 0.074 | 1.242 ± 0.044 | 1.173 ± 0.065 | 1.108 ± 0.053 | 0.859 ± 0.053*
Female
Necropsy body wt | 28.2 ± 0.4 | 29.9 ± 0.8 | 31.0 ± 0.7** | 32.2 ± 0.7** | 33.7 ± 0.8** | 29.7 ± 0.7**
R. Kidney
Absolute | 0.20 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01* | 0.23 ± 0.01**
Relative | 6.97 ± 0.20 | 6.98 ± 0.13 | 7.01 ± 0.17 | 6.55 ± 0.17 | 6.48 ± 0.12 | 7.69 ± 0.29*
Liver
Absolute | 1.23 ± 0.05 | 1.33 ± 0.05 | 1.51 ± 0.05* | 1.81 ± 0.08** | 2.44 ± 0.08** | 2.61 ± 0.14**
Relative | 43.51 ± 1.66 | 44.28 ± 0.91 | 48.73 ± 0.79 | 56.18 ± 1.98** | 72.49 ± 1.95** | 87.58 ± 3.36**
Thymus
Absolute | 0.055 ± 0.002 | 0.058 ± 0.001 | 0.060 ± 0.004 | 0.065 ± 0.003 | 0.062 ± 0.001 | 0.041 ± 0.004**
Relative | 1.956 ± 0.100 | 1.938 ± 0.054 | 1.925 ± 0.108 | 2.011 ± 0.068 | 1.858 ± 0.044 | 1.371 ± 0.102**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Absolute thymus weight was significantly decreased in 2,000 ppm females (75% of the chamber controls) and relative thymus weights were significantly decreased in 2,000 ppm males and females (Table 17 and Table G-2). There were no corresponding histologic lesions in the thymus.

There were significantly increased absolute heart weights in males exposed to 500 ppm or greater and significantly decreased relative heart and relative lung weights in females exposed to 500 ppm or greater (Table G-2).

There were no gross lesions associated with exposure to p-chloro-α,α,α-trifluorotoluene. Significant histologic lesions were recorded in the liver, forestomach, adrenal cortex, and spleen of male and female mice.

In the liver, there were significantly increased incidences of centrilobular hepatocyte hypertrophy in males exposed to 250 ppm or greater and females exposed to 500 ppm or greater compared to their respective chamber control groups (Table 18); severities also generally increased with increasing exposure concentration, with most 1,000 and 2,000 ppm males and most 2,000 ppm females having marked hypertrophy. Increased incidences of hepatocyte hypertrophy correspond with the higher liver weights. There were also significantly increased incidences of centrilobular hepatocyte necrosis and multinucleated hepatocytes in males exposed to 500 ppm or greater and females exposed to 1,000 or 2,000 ppm.

Table 18 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
Adrenal Cortex^a^ | 10 | 10 | 10 | 10 | 10 | 9
Zona Fasciculata, Hypertrophy^b^ | 1 (1.0)^c^ | 0 | 0 | 0 | 1 (1.0) | 6* (1.0)
Forestomach | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Hyperplasia | 0 | 0 | 1 (1.0) | 4* (1.0) | 7** (1.3) | 9** (2.0)
Inflammation, Granulomatous | 0 | 0 | 0 | 1 (1.0) | 2 (1.0) | 10** (1.5)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 10** (1.5) | 10** (2.7) | 10** (3.9) | 10** (4.0)
Centrilobular, Hepatocyte, Necrosis | 0 | 0 | 2 (1.0) | 10** (1.2) | 10** (1.5) | 10** (2.0)
Hepatocyte, Multinucleated | 0 | 0 | 1 (1.0) | 8** (1.6) | 10** (3.5) | 10** (4.0)
Spleen | 10 | 10 | 10 | 10 | 10 | 10
Red Pulp, Hematopoietic Cell Proliferation Erythrocytic | 0 | 0 | 0 | 1 (1.0) | 2 (1.0) | 10** (1.0)
Red Pulp, Hematopoietic Cell Proliferation, Megakaryocyte | 0 | 0 | 0 | 1 (1.0) | 6** (1.3) | 10** (2.0)
Female
Adrenal Cortex | 10 | 10 | 10 | 10 | 10 | 10
X-zone, Degeneration | 0 | 0 | 0 | 0 | 0 | 10** (3.7)
Zona Fasciculata, Hypertrophy | 0 | 0 | 0 | 0 | 0 | 7** (1.6)
Forestomach | 10 | 9 | 9 | 10 | 10 | 10
Epithelium, Hyperplasia | 0 | 2 (1.0) | 3 (1.0) | 5* (1.0) | 10** (1.6) | 10** (2.1)
Inflammation, Granulomatous | 0 | 0 | 0 | 0 | 0 | 8** (1.8)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 2 (1.5) | 4* (1.0) | 10** (2.2) | 10** (3.9)
Centrilobular, Hepatocyte, Necrosis | 0 | 0 | 1 (1.0) | 2 (1.0) | 8** (1.1) | 10** (1.6)
Hepatocyte, Multinucleated | 0 | 0 | 0 | 0 | 6** (1.5) | 10** (3.3)
Spleen | 10 | 10 | 10 | 10 | 10 | 10
Red Pulp, Hematopoietic Cell Proliferation Erythrocytic | 0 | 0 | 5* (1.0) | 4* (1.0) | 9** (1.0) | 10** (1.0)
Red Pulp, Hematopoietic Cell Proliferation, Megakaryocyte | 0 | 0 | 5* (1.0) | 6** (1.2) | 10** (1.5) | 10** (2.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Hepatocyte hypertrophy was characterized by enlargement of hepatocytes up to two or three times normal size (Figure 19). The hypertrophic hepatocytes had increased amounts of cytoplasm, which was often eosinophilic or granular in appearance, and enlarged nuclei. Severity grading of hepatocyte hypertrophy was based primarily on the amount of each hepatic lobule that was involved; lesions of minimal severity affected only the centrilobular hepatocytes, whereas with mild and moderate lesions, an increasing area of each hepatic lobule was affected. With marked severity, the hypertrophy was essentially a diffuse change, but it was still recorded as centrilobular as it was considered the same process as that seen with lesser severities. Also, as the severity increased, the size of the individual hepatocytes tended to increase as well. Centrilobular hepatocyte necrosis was characterized by a loss of cellular detail and differential staining, with replacement by eosinophilic cellular and karyorrhectic debris, in the centrilobular zone. Typically, there was a lack of associated inflammation. Multinucleated hepatocytes were large hepatocytes containing three or more nuclei, often up to eight or 10. Severity grading of multinucleated hepatocytes was based primarily on the number of multinucleated hepatocytes observed within a given section of liver.

Figure 19

Centrilobular Hepatocyte Hypertrophy in the Liver of a Male Mouse Exposed to 2,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months (H&E)

The hepatocytes around the central veins (C) are much larger than those around the portal veins (P). The hypertrophied hepatocytes contain large amounts of eosinophilic cytoplasm, often with a granular appearance, and lack the typical glycogen content found in periportal hepatocytes. Nuclei in affected cells are also enlarged.

In the forestomach, there were significantly increased incidences of epithelium hyperplasia in males and females exposed to 500 ppm or greater (Table 18). In 2,000 ppm males and females, there were significantly increased incidences of granulomatous inflammation. Epithelium hyperplasia was characterized by increased numbers of squamous epithelial cells that caused an increased thickness of the mucosal epithelium up to three times as thick as that seen in chamber control animals (Figure 20). Granulomatous inflammation consisted of focal to multifocal infiltrates of histiocytes, with fewer multinucleated giant cells, within the submucosa.

Figure 20

Epithelium Hyperplasia in the Forestomach of a Female Mouse Exposed to 2,000 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months (H&E)

The squamous epithelium of the normal forestomach is typically three to five cell layers thick, while the epithelium in this example is irregular, with downward projections, and up to three times thicker than normal. Overlying the hyperplastic epithelium is a thick layer of keratin, and in the submucosa, there is a mixed inflammatory cell infiltrate.

In the adrenal cortex, there were significantly increased incidences of zona fasciculata hypertrophy in 2,000 ppm males and females (Table 18). In 2,000 ppm females, there was also a significantly increased incidence of X-zone degeneration. Hypertrophy was characterized by eosinophilic cells with increased amounts of cytoplasm, within the zona fasciculata. X-zone degeneration was characterized by a narrow X-zone, with fewer cells, condensed nuclei, and increased intercellular spaces. Degeneration of the X-zone is a normal physiological process that takes place several weeks after puberty in female mice. When degeneration of the X-zone is diagnosed, it typically reflects a shift in the normal time course of degeneration of the X-zone (a process influenced by hormones) rather than a unique pathological process.

In the red pulp of the spleen, there were significantly increased incidences of megakaryocyte and erythrocytic hematopoietic cell proliferation in females exposed to 250 ppm or greater (Table 18). In males, there were significantly increased incidences of megakaryocyte hematopoietic cell proliferation at 1,000 and 2,000 ppm, and a significantly increased incidence of erythrocytic hematopoietic cell proliferation at 2,000 ppm. Hematopoietic cell proliferation was characterized by increased numbers of megakaryocytes (megakaryocyte hematopoietic cell proliferation) or red blood cell precursors (erythrocytic hematopoietic cell proliferation) within the red pulp of the spleen.

All exposed groups of males evaluated displayed significant exposure concentration-related decreases in sperm motility (Table 19 and Table H-4). The number of sperm/cauda epididymis was increased in these exposed groups; however, the value in the chamber control group was on the lower side of NTP historical experience. In 1,000 and 2,000 ppm females, there were significant increases in estrous cycle length compared to the chamber control group (Table 19 and Table H-5). All exposed female groups evaluated had significantly higher probabilities of extended estrus (Table 19, Table H-5, Table H-6, and Figure H-2). p-Chloro-α,α,α-trifluorotoluene exposure via inhalation exhibited the potential to be a reproductive toxicant in male and female B6C3F1/N mice.

Table 19 Summary of Reproductive Tissue Evaluations for Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10
Male
Spermatid measurements
Spermatid heads (10^6^/testis) | 19.72 ± 1.004 | 22.31 ± 0.656 | 19.99 ± 1.324 | 17.72 ± 1.321
Spermatid heads (10^6^/g testis) | 191.87 ± 8.230 | 206.29 ± 7.450 | 192.82 ± 11.952 | 172.12 ±12.644
Epididymal spermatozoal measurements
Sperm motility (%) | 79.9 ± 0.89 | 67.1 ± 3.33** | 63.2 ± 1.42** | 60.1 ± 1.31**
Sperm (10^6^/cauda epididymis) | 11.3 ± 0.55 | 14.8 ± 0.66* | 14.2 ± 1.29 | 15.0 ± 1.15*
Female
Estrous cycle length (days) | 4.1 ± 0.10 | 4.5 ± 0.16 | 4.6 ± 0.14* | 5.3 ± 0.65**
Estrous stages (% of cycle)
Diestrus | 36.9 | 32.5 | 28.8 | 30.0
Proestrus | 0.0 | 2.5 | 4.4 | 6.9
Estrus | 47.5 | 48.1 | 44.4 | 45.0
Metestrus | 15.6 | 16.3 | 21.3 | 16.9

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test (sperm/cauda epididymis) or Dunn’s test (estrous cycle length).

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test (sperm motility) or Dunn’s test (estrous cycle length).

^a^ Data for sperm motility, sperm/cauda epididymis, and estrous cycle length are presented as mean ± standard error. Differences from the control group for spermatid measurements are not significant by Dunn’s test. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated that all exposed groups evaluated spent significantly more time in extended estrus (P ≤ 0.001) than the chamber control group.

Exposure Concentration Selection Rationale: Statistically significant exposure-related increases in liver weight (approximately 50% or greater) and increased incidences of liver necrosis and other liver lesions precluded the use of 500 ppm in male mice and 1,000 ppm in female mice. The p-chloro-α,α,α-trifluorotoluene exposure concentrations selected for the 2-year inhalation study in mice were 100, 200, and 400 ppm. Similar to rats, these concentrations were selected to accommodate logistical challenges while adequately challenging both males and females.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 20 and in the Kaplan-Meier survival curves (Figure 6). Survival of 400 ppm males was significantly decreased compared to the chamber control group. Survival of 400 ppm females was less than the chamber control group, but the difference was not statistically significant. Decreased survival in the 400 ppm groups occurred very late in the study. Sixteen of the 22 male and 11 of the 23 female early deaths and moribund removals were attributable to liver neoplasms.

Table 20 Survival of Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 8 | 5 | 11 | 12
Natural deaths | 2 | 5 | 4 | 10
Animals surviving to study termination | 40 | 40 | 35 | 28
Percent probability of survival at end of study^a^ | 80 | 80 | 70 | 56
Mean survival (days)^b^ | 705 | 714 | 692 | 680
Survival analysis^c^ | P = 0.002 | P = 1.000 | P = 0.348 | P = 0.018
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^d^ | 0 | 0 | 1 | 0
Moribund | 7 | 12 | 9 | 16
Natural deaths | 5 | 5 | 3^e^ | 7
Animals surviving to study termination | 38 | 33 | 37 | 27^f^
Percent probability of survival at end of study | 76 | 66 | 76 | 54
Mean survival (days) | 700 | 688 | 687 | 688
Survival analysis | P = 0.059 | P = 0.398 | P = 1.000 | P = 0.051

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^40^ is in the chamber control column, and the results of the life table pairwise comparisons^39^ with the chamber controls are in the exposed group columns.

^d^ Censored in the survival analysis.

^e^ Includes two animals that died during the last week of the study.

^f^ Includes one animal that died during the last week of the study.

Figure 6

Kaplan-Meier Survival Curves for Mice Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years

#### Body Weights and Clinical Observations

Mean body weights of exposed groups of males were within 10% of those of the chamber controls throughout the study (Figure 7, Table 21). The mean body weights of 100 ppm females were at least 10% greater than those of the chamber controls generally after week 69 (Figure 7, Table 22). The mean body weights of 200 and 400 ppm females were at least 10% greater than those of the chamber controls after weeks 13 and 2, respectively. Clinical observations included increased occurrences of distended abdomen at removal, which were associated with liver neoplasms. There were also increased occurrences of thinness in 400 ppm males and females.

Figure 7

Growth Curves for Mice Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years

Table 21 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Day | Chamber Control | | 100 ppm | | | 200 ppm | | | 1,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 21.6 | 50 | 21.5 | 100 | 50 | 21.5 | 100 | 50 | 21.5 | 100 | 50
11 | 24.0 | 50 | 24.4 | 102 | 50 | 24.8 | 103 | 50 | 25.1 | 105 | 50
18 | 25.1 | 50 | 25.2 | 101 | 50 | 25.6 | 102 | 50 | 26.5 | 106 | 50
25 | 26.3 | 50 | 26.6 | 101 | 50 | 27.0 | 103 | 50 | 28.0 | 107 | 50
32 | 27.0 | 50 | 27.3 | 101 | 50 | 27.9 | 104 | 50 | 29.2 | 108 | 50
39 | 27.8 | 50 | 28.1 | 101 | 50 | 28.9 | 104 | 50 | 30.1 | 108 | 50
46 | 28.6 | 50 | 28.7 | 100 | 50 | 29.6 | 104 | 50 | 30.8 | 108 | 50
53 | 29.2 | 50 | 29.4 | 101 | 50 | 30.3 | 104 | 50 | 31.5 | 108 | 50
60 | 29.7 | 50 | 30.2 | 102 | 50 | 31.1 | 105 | 50 | 32.2 | 108 | 50
67 | 30.5 | 50 | 31.1 | 102 | 50 | 32.2 | 106 | 50 | 33.2 | 109 | 50
74 | 31.4 | 50 | 32.0 | 102 | 50 | 33.1 | 105 | 50 | 34.1 | 109 | 50
81 | 31.9 | 50 | 32.5 | 102 | 50 | 33.6 | 105 | 50 | 34.8 | 109 | 50
88 | 32.7 | 50 | 33.3 | 102 | 50 | 34.6 | 106 | 50 | 35.6 | 109 | 50
116 | 35.9 | 50 | 36.9 | 103 | 50 | 38.3 | 107 | 50 | 39.0 | 109 | 50
144 | 38.2 | 50 | 39.0 | 102 | 50 | 39.9 | 105 | 50 | 40.9 | 107 | 50
172 | 41.1 | 50 | 42.0 | 102 | 50 | 43.2 | 105 | 50 | 44.1 | 107 | 50
200 | 42.1 | 50 | 42.9 | 102 | 50 | 44.6 | 106 | 50 | 45.3 | 108 | 50
228 | 44.7 | 50 | 45.2 | 101 | 50 | 46.9 | 105 | 50 | 47.9 | 107 | 50
256 | 45.7 | 50 | 46.2 | 101 | 50 | 48.2 | 106 | 50 | 49.1 | 107 | 50
284 | 47.6 | 50 | 47.7 | 100 | 50 | 49.6 | 104 | 50 | 50.3 | 106 | 50
312 | 48.2 | 50 | 48.6 | 101 | 50 | 50.3 | 105 | 50 | 51.2 | 106 | 50
340 | 50.1 | 50 | 50.0 | 100 | 50 | 51.6 | 103 | 49 | 52.5 | 105 | 50
368 | 50.7 | 50 | 50.8 | 100 | 50 | 52.0 | 103 | 49 | 52.9 | 104 | 50
396 | 50.7 | 50 | 50.9 | 100 | 50 | 52.0 | 103 | 49 | 53.1 | 105 | 50
424 | 51.6 | 49 | 51.3 | 100 | 50 | 52.7 | 102 | 49 | 53.6 | 104 | 49
452 | 51.7 | 49 | 51.4 | 99 | 50 | 52.8 | 102 | 48 | 53.6 | 104 | 49
480 | 52.3 | 49 | 51.9 | 99 | 50 | 53.5 | 102 | 48 | 54.2 | 104 | 48
508 | 52.3 | 48 | 51.9 | 99 | 50 | 53.3 | 102 | 48 | 53.5 | 102 | 48
536 | 52.7 | 48 | 52.3 | 99 | 49 | 53.8 | 102 | 47 | 52.7 | 100 | 48
564 | 52.4 | 48 | 52.1 | 100 | 49 | 54.0 | 103 | 46 | 52.6 | 100 | 47
592 | 52.3 | 47 | 52.3 | 100 | 49 | 54.3 | 104 | 43 | 53.9 | 103 | 43
620 | 52.0 | 44 | 51.6 | 99 | 47 | 53.9 | 104 | 43 | 51.6 | 99 | 42
648 | 51.8 | 43 | 51.0 | 99 | 47 | 53.6 | 104 | 41 | 51.3 | 99 | 37
676 | 51.0 | 43 | 51.6 | 101 | 44 | 53.6 | 105 | 39 | 50.5 | 99 | 31
704 | 50.3 | 41 | 51.6 | 103 | 41 | 53.6 | 106 | 38 | 48.4 | 96 | 29
Mean for Weeks
1–13 | 28.1 | – | 28.5 | 101 | – | 29.2 | 104 | – | 30.2 | 107 | –
14–52 | 43.7 | – | 44.3 | 101 | – | 45.8 | 105 | – | 46.7 | 107 | –
53–101 | 51.7 | – | 51.6 | 100 | – | 53.3 | 103 | – | 52.5 | 102 | –

Table 22 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Day | Chamber Control | | 100 ppm | | | 200 ppm | | | 1,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.6 | 50 | 18.6 | 100 | 50 | 18.6 | 100 | 50 | 18.7 | 101 | 50
11 | 20.4 | 50 | 20.9 | 103 | 50 | 21.3 | 105 | 50 | 22.1 | 109 | 50
18 | 21.1 | 50 | 21.5 | 102 | 50 | 22.1 | 105 | 50 | 23.2 | 110 | 50
25 | 22.2 | 50 | 22.8 | 103 | 50 | 23.3 | 105 | 50 | 24.8 | 112 | 50
32 | 23.3 | 50 | 23.9 | 103 | 50 | 24.5 | 105 | 50 | 25.9 | 111 | 50
39 | 24.0 | 50 | 24.6 | 103 | 50 | 25.4 | 106 | 50 | 26.9 | 112 | 50
46 | 24.7 | 50 | 25.2 | 102 | 50 | 26.2 | 106 | 50 | 27.5 | 112 | 50
53 | 25.6 | 50 | 26.0 | 102 | 50 | 27.1 | 106 | 50 | 28.5 | 112 | 50
60 | 25.9 | 50 | 26.4 | 102 | 50 | 27.8 | 107 | 50 | 29.0 | 112 | 50
67 | 26.0 | 50 | 26.8 | 103 | 50 | 28.0 | 108 | 50 | 29.5 | 114 | 50
74 | 26.6 | 50 | 27.5 | 103 | 50 | 28.8 | 108 | 50 | 30.3 | 114 | 50
81 | 27.4 | 50 | 28.2 | 103 | 50 | 29.1 | 106 | 50 | 30.7 | 112 | 50
88 | 27.7 | 50 | 28.3 | 102 | 50 | 29.8 | 107 | 50 | 31.5 | 113 | 50
116 | 30.1 | 50 | 31.2 | 104 | 50 | 33.4 | 111 | 49 | 35.1 | 117 | 50
144 | 32.3 | 50 | 33.4 | 103 | 50 | 36.2 | 112 | 49 | 37.0 | 115 | 50
172 | 34.7 | 50 | 36.8 | 106 | 50 | 39.5 | 114 | 49 | 40.6 | 117 | 50
200 | 37.0 | 50 | 38.4 | 104 | 50 | 41.2 | 111 | 49 | 43.0 | 116 | 50
228 | 39.0 | 50 | 41.5 | 106 | 49 | 44.6 | 114 | 49 | 46.7 | 120 | 50
256 | 40.9 | 50 | 43.2 | 105 | 49 | 46.5 | 114 | 49 | 48.8 | 119 | 50
284 | 43.8 | 50 | 45.8 | 105 | 49 | 49.5 | 113 | 49 | 52.2 | 119 | 50
312 | 45.3 | 50 | 48.1 | 106 | 49 | 51.8 | 114 | 49 | 54.4 | 120 | 50
340 | 47.1 | 50 | 50.1 | 106 | 49 | 54.1 | 115 | 49 | 57.0 | 121 | 50
368 | 50.2 | 50 | 53.2 | 106 | 49 | 56.3 | 112 | 49 | 59.1 | 118 | 50
396 | 51.3 | 50 | 54.5 | 106 | 49 | 58.1 | 113 | 49 | 60.5 | 118 | 49
424 | 52.7 | 50 | 55.6 | 106 | 49 | 59.0 | 112 | 49 | 61.5 | 117 | 49
452 | 53.6 | 50 | 58.3 | 109 | 49 | 60.1 | 112 | 49 | 63.5 | 118 | 49
480 | 55.3 | 49 | 59.9 | 108 | 49 | 62.0 | 112 | 48 | 65.5 | 118 | 47
508 | 55.0 | 47 | 60.2 | 110 | 48 | 62.4 | 114 | 47 | 66.0 | 120 | 47
536 | 55.9 | 47 | 61.0 | 109 | 48 | 63.7 | 114 | 46 | 66.3 | 119 | 46
564 | 55.4 | 45 | 61.2 | 111 | 46 | 63.2 | 114 | 44 | 66.3 | 120 | 46
592 | 55.4 | 45 | 60.7 | 110 | 44 | 63.8 | 115 | 43 | 67.1 | 121 | 45
620 | 53.8 | 45 | 59.7 | 111 | 42 | 63.0 | 117 | 41 | 63.6 | 118 | 44
648 | 53.3 | 43 | 59.0 | 111 | 41 | 62.2 | 117 | 40 | 61.7 | 116 | 41
676 | 53.0 | 39 | 58.5 | 110 | 39 | 61.3 | 116 | 40 | 60.3 | 114 | 36
704 | 52.4 | 39 | 59.3 | 113 | 33 | 61.0 | 116 | 40 | 58.5 | 112 | 34
Mean for Weeks
1–13 | 24.1 | – | 24.7 | 102 | – | 25.5 | 106 | – | 26.8 | 111 | –
14–52 | 38.9 | – | 40.9 | 105 | – | 44.1 | 113 | – | 46.1 | 119 | –
53–101 | 53.6 | – | 58.5 | 109 | – | 61.2 | 114 | – | 63.1 | 118 | –

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver, Harderian gland, lung, larynx, and forestomach. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: The overall incidences of hepatocellular adenoma were significantly increased in 200 and 400 ppm females, and the overall incidences of hepatocellular carcinoma were significantly increased in all exposed male groups and 400 ppm females (Table 23, Table C-1, Table C-2, Table D-1, and Table D-2). In addition, there were significantly increased incidences of multiple hepatocellular adenoma in 200 and 400 ppm males and females and multiple hepatocellular carcinoma in 400 ppm males and females compared to the chamber control groups. There were significantly increased incidences of hepatoblastoma in 400 ppm males and females. The incidences of hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma (combined) were significantly increased in 200 and 400 ppm males and females.

Table 23 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Centrilobular, Hepatocyte, Hypertrophy^a^ | 0 | 8** (1.0)^b^ | 19** (1.1) | 49** (1.5)
Clear Cell Focus | 15 | 16 | 23* | 15
Eosinophilic Focus | 11 | 14 | 18 | 21*
Hepatocyte, Multinucleated | 2 (1.0) | 8 (1.0) | 19** (1.1) | 49** (1.4)
Hepatocyte, Necrosis | 3 (1.0) | 4 (2.5) | 3 (2.0) | 15** (1.5)
Intrahepatocellular Erythrocytes | 0 | 1 (1.0) | 6* (1.0) | 15** (1.3)
Hepatocellular Adenoma, Multiple | 9 | 15 | 19* | 21**
Hepatocellular Adenoma (includes multiple)^c^
Overall rate^d^ | 25/50 (50%) | 24/50 (48%) | 31/50 (62%) | 29/50 (58%)
Adjusted rate^e^ | 53.0% | 50.2% | 68.1% | 64.3%
Terminal rate^f^ | 23/40 (58%) | 21/40 (53%) | 27/35 (77%) | 18/28 (64%)
First incidence (days) | 424 | 660 | 551 | 477
Poly-3 test^g^ | P = 0.079 | P = 0.473N | P = 0.096 | P = 0.181
Hepatocellular Carcinoma, Multiple | 2 | 5 | 7 | 30**
Hepatocellular Carcinoma (includes multiple)^h^
Overall rate | 8/50 (16%) | 19/50 (38%) | 16/50 (32%) | 35/50 (70%)
Adjusted rate | 17.0% | 38.6% | 34.1% | 75.3%
Terminal rate | 6/40 (15%) | 12/40 (30%) | 8/35 (23%) | 22/28 (79%)
First incidence (days) | 488 | 605 | 523 | 548
Poly-3 test | P < 0.001 | P = 0.015 | P = 0.046 | P < 0.001
Hepatoblastoma, Multiple | 0 | 0 | 0 | 5*
Hepatoblastoma (includes multiple)^i^
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 15/50 (30%)
Adjusted rate | 2.1% | 2.1% | 2.3% | 34.6%
Terminal rate | 0/40 (0%) | 1/40 (3%) | 1/35 (3%) | 8/28 (29%)
First incidence (days) | 591 | 729 (T) | 729 (T) | 638
Poly-3 test | P < 0.001 | P = 0.757N | P = 0.749 | P < 0.001
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^j^
Overall rate | 31/50 (62%) | 37/50 (74%) | 40/50 (80%) | 48/50 (96%)
Adjusted rate | 64.1% | 74.9% | 84.3% | 98.6%
Terminal rate | 26/40 (65%) | 28/40 (70%) | 30/35 (86%) | 28/28 (100%)
First incidence (days) | 424 | 605 | 523 | 477
Poly-3 test | P < 0.001 | P = 0.169 | P = 0.017 | P < 0.001
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Centrilobular, Hepatocyte, Hypertrophy | 0 | 4 (1.0) | 5* (1.2) | 40** (1.2)
Eosinophilic Focus | 4 | 8 | 24** | 31**
Hepatocyte, Multinucleated | 0 | 2 (1.0) | 2 (1.0) | 25** (1.0)
Hepatocyte, Necrosis | 2 (2.0) | 1 (1.0) | 3 (1.7) | 10* (1.3)
Number Examined Microscopically | 50 | 50 | 50 | 50
Hepatocellular Adenoma, Multiple | 3 | 5 | 15** | 25**
Hepatocellular Adenoma (includes multiple)^k^
Overall rate | 12/50 (24%) | 14/50 (28%) | 24/50 (48%) | 34/50 (68%)
Adjusted rate | 26.1% | 31.9% | 54.5% | 72.6%
Terminal rate | 9/38 (24%) | 11/33 (33%) | 24/37 (65%) | 18/27 (67%)
First incidence (days) | 544 | 685 | 731 (T) | 530
Poly-3 test | P < 0.001 | P = 0.355 | P = 0.004 | P < 0.001
Hepatocellular Carcinoma, Multiple | 2 | 3 | 7 | 28**
Hepatocellular Carcinoma (includes multiple)^l^
Overall rate | 7/50 (14%) | 8/50 (16%) | 12/50 (24%) | 34/50 (68%)
Adjusted rate | 15.3% | 18.1% | 26.9% | 75.9%
Terminal rate | 4/38 (11%) | 5/33 (15%) | 9/37 (24%) | 23/27 (85%)
First incidence (days) | 664 | 578 | 576 | 642
Poly-3 test | P < 0.001 | P = 0.472 | P = 0.136 | P < 0.001
Hepatoblastoma^m^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 8/50 (16%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 18.3%
Terminal rate | 0/38 (0%) | 0/33 (0%) | 1/37 (3%) | 4/27 (15%)
First incidence (days) | –^n^ | – | 731 (T) | 673
Poly-3 test | P < 0.001 | –^o^ | P = 0.495 | P = 0.003
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^p^
Overall rate | 18/50 (36%) | 18/50 (36%) | 29/50 (58%) | 46/50 (92%)
Adjusted rate | 38.8% | 40.4% | 65.0% | 97.6%
Terminal rate | 13/38 (34%) | 13/33 (39%) | 26/37 (70%) | 27/27 (100%)
First incidence (days) | 554 | 578 | 576 | 530
Poly-3 test | P < 0.001 | P = 0.523 | P = 0.008 | P < 0.001

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 147/300 (49.0% ± 9.0%), range 34%–60%; all routes: 302/550 (54.9% ± 12.4%), range 34%–78%.

^d^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^h^ Historical incidence for inhalation studies: 97/300 (32.3% ± 12.6%), range 16%–50%; all routes: 165/550 (30.0% ± 10.0%), range 16%–50%.

^i^ Historical incidence for inhalation studies: 6/300 (2.0% ± 1.8%), range 0%–4%; all routes: 18/550 (3.3% ± 2.4%), range 0%–8%.

^j^ Historical incidence for inhalation studies: 207/300 (69.0% ± 7.2%), range 62%–78%; all routes: 395/550 (71.8% ± 8.1%), range 62%–84%.

^k^ Historical incidence for inhalation studies: 71/300 (23.7% ± 8.9%), range 12%–38%; all routes: 141/549 (25.8% ± 15.9%), range 10%–67%.

^l^ Historical incidence for inhalation studies: 45/300 (15.0% ± 4.2%), range 10%–20%; all routes: 71/549 (12.9% ± 5.1%), range 4%–20%.

^m^ Historical incidence for inhalation studies: 3/300 (1.0% ± 1.1%), range 0%–2%; all routes: 3/549 (0.6% ± 0.9%), range 0%–2%.

^n^ Not applicable; no neoplasms in animal group.

^o^ Value of statistic cannot be computed.

^p^ Historical incidence for inhalation studies: 104/300 (34.7% ± 9.4%), range 24%–50%; all routes: 189/549 (34.5% ± 15.8%), range 16%–73%.

Hepatocellular adenomas were discrete, well-circumscribed lesions that compressed surrounding parenchyma and had hepatic cords generally oriented perpendicularly to surrounding hepatic cords. Central veins and portal areas were generally absent. Hepatocytes were well differentiated with variable size and tinctoral characteristics. Hepatocellular carcinomas were large lesions, frequently with areas of necrosis, which caused compression of, and invasion into, surrounding parenchyma. Typically, hepatocellular carcinomas were characterized by hepatocytes forming trabeculae that were at least three cells thick, although some of the areas of carcinomas were of a solid pattern of growth (Figure 21). Cells within the hepatocellular carcinomas ranged from eosinophilic to basophilic in staining, and displayed marked pleomorphism and an increased mitotic rate. Nucleoli tended to be distinct and larger than normal. Hepatoblastomas were composed of small cells with scant cytoplasm and hyperchromatic, oval nuclei (Figure 22). Cells were often arranged in rows around variably sized vascular spaces. Hepatoblastomas often arose from within a hepatocellular carcinoma, and when this occurred, only the hepatoblastoma was recorded, but several hepatoblastomas were observed with no connection to hepatocellular tumors.

Figure 21

Hepatocellular Carcinoma in the Liver of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

Trabeculae are three cell layers or more thick and separated by blood-filled spaces. The cells within the trabeculae are often small and crowded together and do not maintain the normal arrangement of hepatocellular cords.

Figure 22

Hepatoblastoma in the Liver of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The tumor is well demarcated from the surrounding liver parenchyma (asterisks) and composed of tightly packed cells with scant cytoplasm and basophilic oval nuclei.

There were significantly increased incidences of eosinophilic focus in 400 ppm males and 200 and 400 ppm females (Table 23, Table C-4, and Table D-4). There were significantly increased incidences of centrilobular hepatocyte hypertrophy in all exposed groups of males and in 200 and 400 ppm females. There were significantly increased incidences of multinucleated hepatocytes in 200 and 400 ppm males and 400 ppm females. The incidences of hepatocyte necrosis were significantly increased in 400 ppm males and females. Intrahepatocellular erythrocytes only occurred in exposed males, and the incidences were significantly increased in the 200 and 400 ppm groups. There was a significantly increased incidence of clear cell focus in 200 ppm males, but this was considered biological variation due to the lack of exposure concentration response and the fact that clear cell foci are fairly common as a background change.

Eosinophilic foci were discrete groups of enlarged hepatocytes with brightly eosinophilic cytoplasm. Some foci caused compression of some of the surrounding parenchyma, but not to the extent of hepatocellular adenomas. Hepatocytes within foci were generally aligned with hepatocytes in the normal liver, and portal triads and hepatic veins were present within foci, in contrast to hepatocellular adenomas. Foci typically lacked cellular atypia and mitotic figures. Centrilobular hepatocyte hypertrophy was characterized by an accentuated lobular pattern due to the presence of enlarged hepatocytes, primarily in the centrilobular zone, but expanding into the midzonal and periportal zones within increasing severity (Figure 23). Involved hepatocytes had abundant granular eosinophilic cytoplasm containing clumped basophilic material (Figure 24). Nuclei were frequently enlarged and had stippled chromatin, prominent nucleoli, and occasional bright eosinophilic inclusions. Severity grading was based upon the amount of hepatic lobule involved, with minimal, mild, or moderate being recorded when 1% to 20%, 20% to 50%, or more than 50% of each hepatic lobule was affected, respectively (no marked lesions were recorded.) Multinucleated hepatocytes were characterized by enlarged hepatocytes containing three or more, often up to 10 and occasionally as many as 20, nuclei (Figure 25). Severity grading was based on the number of affected hepatocytes, with only minimal and mild lesions being recorded. Minimal severity typically consisted of one to five affected hepatocytes within a section of liver. Hepatocyte necrosis was characterized by randomly scattered clusters of three to 15 necrotic hepatocytes; necrosis was not diagnosed if it occurred within a tumor. Severity grading was based upon the amount of hepatic parenchyma involved, with 1% to 3%, 4% to 10%, or 11% to 50% involvement being recorded as minimal, mild, or moderate, respectively. Intrahepatocellular erythrocytes, when present, were randomly scattered throughout the liver with no particular zonality.

Figure 23

Centrilobular Hepatocyte Hypertrophy in the Liver of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

A zonal pattern is apparent due to enlarged hepatocytes in the centrilobular region. (C = central vein; P = portal vein).

Figure 24

Higher Magnification of Figure 23 (H&E)

The hepatocytes in the centrilobular region are enlarged, with abundant granular eosinophilic cytoplasm containing clumped basophilic material. Nuclei are frequently enlarged, with stippled chromatin and prominent nucleoli. (C = central vein; P = portal vein).

Figure 25

Multinucleated Hepatocytes in the Liver of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

At high magnification, two examples of hepatocytes containing multiple nuclei are noted (arrows); the surrounding hepatocytes are also enlarged.

The number of erythrocytes within hepatocytes varied from one to too numerous to count. Affected hepatocytes were often increased in size, with the increase in size usually correlating to the number of intracellular erythrocytes, and the cytoplasm and nuclei of these hepatocytes was usually peripheralized (Figure 26). Minimal severity grade was recorded when less than three or four hepatocytes with intracellular erythrocytes were noted throughout the liver sections examined, while mild was used when several areas containing multiple affected hepatocytes were noted.

Figure 26

Intrahepatocellular Erythrocytes in the Liver of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

At high magnification, several markedly enlarged hepatocytes containing abundant erythrocytes are noted; the remaining cytoplasm and nuclei are displaced to the periphery of the enlarged cells.

Liver Molecular Pathology: Hras mutations in rodent hepatocellular carcinomas (HCCs) are commonly observed within codon 61^72; 73^. In the current study, the incidence of Hras mutations in mouse HCCs examined from all p-chloro-α,α,α-trifluorotoluene-exposed groups was 37% (23/62) and the incidence in chamber controls was 73% (11/15) (Appendix L); these mutations were located within codon 61. There were significant trend and pairwise differences for Hras mutation incidence in the negative direction between HCCs occurring spontaneously in chamber controls and HCCs resulting from chronic exposure to p-chloro-α,α,α-trifluorotoluene. There were no statistically significant differences in Ctnnb1 mutations in mouse HCCs resulting from chronic exposure to p-chloro-α,α,α-trifluoro-toluene compared to the chamber control groups. Four of the HCCs arising spontaneously harbored Ctnnb1 mutations all of which were point mutations in codon 15-46. There was a deletion of codons 27-35 in five HCCs from p-chloro-α,α,α-trifluorotoluene-exposed groups. None of the spontaneous HCCs had deletions in the Ctnnb1 gene. There were no differences in the incidences of mutations between male and female mice (data not presented) and hence, the combined data from both male and female mice are presented in Appendix L.

Harderian Gland: There was a significantly increased incidence of adenoma in 400 ppm females, and significantly increased incidences of adenoma or adenocarcinoma (combined) in 200 and 400 ppm females (Table 24, Table D-1, and Table D-2). Adenomas were fairly well-circumscribed nodules that caused compression of surrounding parenchyma. The cells were cuboidal to tall columnar epithelium, similar to that found in a normal gland, but patterns of growth included papillary and cystic (Figure 27). Adenocarcinomas were expansile and invasive, and had a solid, cystic, or papillary growth pattern or a combination of different growth patterns (Figure 28). Cells were typically smaller than normal, and often had a single large clear cytoplasmic vacuole, in contrast to the numerous small vacuoles usually seen in the cytoplasm of normal Harderian gland cells.

Table 24 Incidences of Neoplasms of the Harderian Gland in Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Adenoma^a^
Overall rate^b^ | 2/50 (4%) | 6/50 (12%) | 6/50 (12%) | 8/50 (16%)
Adjusted rate^c^ | 4.4% | 13.6% | 13.5% | 18.1%
Terminal rate^d^ | 2/38 (5%) | 5/33 (15%) | 5/37 (14%) | 4/27 (15%)
First incidence (days) | 731 (T) | 576 | 562 | 642
Poly-3 test^e^ | P = 0.049 | P = 0.124 | P = 0.129 | P = 0.041
Adenocarcinoma^f,g^ | 0 | 0 | 3 | 0
Adenoma or Adenocarcinoma^g,h^
Overall rate | 2/50 (4%) | 6/50 (12%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 4.4% | 13.6% | 19.7% | 18.1%
Terminal rate | 2/38 (5%) | 5/33 (15%) | 6/37 (16%) | 4/27 (15%)
First incidence (days) | 731 (T) | 576 | 480 | 642
Poly-3 test | P = 0.046 | P = 0.124 | P = 0.026 | P = 0.041

(T) Terminal kill.

^a^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 14/300 (4.7% ± 1.6%), range 2%–6%; all routes: 35/550 (6.4% ± 4.4%), range 2%–18%.

^b^ Number of animals with neoplasm per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^f^ Historical incidence for inhalation studies: 8/300 (2.7% ± 3.5%), range 0%–8%; all routes: 12/550 (2.2% ± 2.8%), range 0%–8%.

^g^ Adenocarcinoma of the Harderian gland was recorded as carcinoma in the historical control database.

^h^ Historical incidence for inhalation studies: 22/300 (7.3% ± 3.7%), range 4%–14%; all routes: 47/550 (8.6% ± 4.7%), range 4%–20%.

Figure 27

Adenoma in the Harderian Gland of a Female Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The adenoma is large and involves almost the entire gland; a small area of uninvolved Harderian gland is visible on the right (H). Within the adenoma, there is a combination of cystic (asterisks) and papillary (arrowheads) growth patterns.

Figure 28

Adenocarcinoma in the Harderian Gland of a Female Mouse Exposed to 200 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The adenocarcinoma has invaded into the back of the eye.

Lung: There were significantly increased incidences of alveolar/bronchiolar epithelium hyperplasia and peribronchiolar fibrosis in all exposed groups of males and females (Table 25, Table C-4, and Table D-5). Alveolar/bronchiolar epithelium hyperplasia was characterized by a proliferation of crowded, plump, and piled-up epithelial cells of the terminal bronchioles, alveolar ducts, and adjacent alveoli (Figure 29 and Figure 30). The epithelial cells were well organized and did not display atypia. A slight increase in the prominence of fibroblasts was observed in the lamina propria of affected areas, but inflammatory cells were not noted. In lesions of marked severity, the hyperplastic cells extended into the adjacent alveolar septa and occasionally bridged adjacent bronchioles within the same lung lobule. When the hyperplasia involved less than 10%, 10% to 25%, 25% to 75%, or more than 75% of bronchioles, it was considered minimal, mild, moderate, or marked, respectively. Peribronchiolar fibrosis was characterized by a minimal increase in spindle-shaped mesenchymal cells in the lamina propria beneath the hyperplastic epithelial cells in the areas of alveolar/bron-chiolar hyperplasia. Associated with these spindle-shaped cells was an increase in pale eosinophilic fibrillar matrix that stained positive for collagen with Masson’s trichrome special stain (Figure 31 and Figure 32). The severity of fibrosis was considered minimal in all exposed groups and no inflammatory cell infiltrate was associated with the fibrosis. There were no significant changes in the incidences of neoplasms in exposed groups.

Table 25 Incidences of Nonneoplastic Lesions of the Lung in Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar/bronchiolar Epithelium, Hyperplasia^a^ | 0 | 49** (1.8)^b^ | 50** (2.4) | 48** (2.8)
Peribronchiolar, Fibrosis | 0 | 45** (1.0) | 47** (1.0) | 44** (1.0)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar/bronchiolar Epithelium, Hyperplasia | 0 | 49** (2.1) | 49** (2.3) | 50** (2.9)
Peribronchiolar, Fibrosis | 0 | 44** (1.0) | 44** (1.0) | 48** (1.0)

** Significantly different (P ≤ 0.01) from the chamber control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 29

Alveolar/Bronchiolar Epithelium Hyperplasia in the Lung of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The lesion affected the terminal bronchioles, alveolar ducts, and adjacent alveoli.

Figure 30

Alveolar/Bronchiolar Epithelium Hyperplasia in the Lung of a Male Mouse Exposed to 400 ppm p-Chloro-α,α,α-trifluorotoluene by Inhalation for Two Years (H&E)

The epithelial cells lining the terminal bronchioles and adjacent alveoli are plump, crowded, and piled up. There is a fine network of fibrous connective tissue in the lamina propria.

Figure 31

Peribronchiolar Fibrosis in the Terminal Bronchioles and Adjacent Alveoli of the Mouse Described in Figure 30

The Masson’s trichrome stain highlights the presence of fibrous connective tissue, which stains bright blue. (Compare to Figure 30).

Figure 32

A Masson’s Trichrome Stain of the Region Surrounding a Terminal Bronchiole in the Lung of a Chamber Control Male Mouse in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

There is a lack of the fine network of bright blue-stained fibrous connective tissue seen in Figure 31.

Larynx: There was a significantly increased incidence of squamous epithelium hyperplasia in 400 ppm males (Table 26 and Table C-4). Hyperplasia of the squamous epithelium was characterized by increased cellularity of the squamous epithelial cells with slight disorganization of cell layers. This change was limited to the medial aspect of the arytenoid cartilage. Nearly all cases were of minimal severity, and consisted of just one or two additional layers of squamous cells in the squamous epithelium.

Table 26 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Male
Larynx^a^ | 50 | 50 | 50 | 50
Squamous Epithelium, Hyperplasia^b^ | 3 (1.0)^c^ | 4 (1.0) | 6 (1.2) | 11* (1.1)
Stomach, Forestomach | 50 | 50 | 50 | 48
Epithelium, Hyperplasia | 5 (1.0) | 9 (1.6) | 9 (1.7) | 10 (2.2)
Inflammation | 4 (1.0) | 12* (1.2) | 7 (1.3) | 12* (1.4)
Female
Stomach, Forestomach | 50 | 50 | 50 | 50
Epithelium, Hyperplasia | 1 (1.0) | 3 (1.7) | 5 (1.0) | 14** (1.1)
Inflammation | 3 (1.0) | 5 (1.0) | 5 (1.2) | 9 (1.2)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Forestomach: There was a significantly increased incidence of epithelium hyperplasia in 400 ppm females (Table 26 and Table D-4). The incidences of epithelium hyperplasia in exposed male groups were increased compared to that in the chamber controls, but the increases were not statistically significant (Table 26 and Table C-4). There were significantly increased incidences of inflammation in 100 and 400 ppm males; and while there was a positive trend (P = 0.034) in the incidences of this lesion in females, there were no statistically significant increases in the exposed groups. Epithelium hyperplasia was characterized by focal areas of thickened squamous epithelium due to increased numbers of squamous epithelial cells. Most cases were minimal and were characterized by slight crowding of nuclei with minimal disorganization and cellular pleomorphism of basal cells. Inflammation was composed primarily of lymphocytes, with fewer neutrophils, and was present primarily within the submucosa. It was often associated with areas of hyperplasia in the overlying epithelium. Focal submucosal inflammation consisting of a cluster of up to 20 inflammatory cells was coded as minimal. Multifocal submucosal inflammation of up to 20 cells in each focus, or focal accumulations of 20 to 100 cells, was coded as mild. One moderate case consisted of two areas of more than 100 inflammatory cells each.

## Genetic Toxicology

In an earlier bacterial mutagenicity assay, p-chloro-α,α,α-trifluorotoluene (10 to 1,000 µg/plate) was not mutagenic in any of four strains of Salmonella typhimurium (TA98, TA100, TA1535, TA1537) when tested without exogenous metabolic activation or with 10% Aroclor 1254-induced hamster or rat liver S9 mix (Table E-1; Haworth et al.^33^). In a second bacterial mutagenicity assay conducted with the same lot of p-chloro-α,α,α-tri-fluorotoluene that was tested in the 2-year rodent bioassay, no evidence of mutagenicity was observed in S. typhimurium strains TA98 or TA100 or in Escherichia coli strain WP2 uvrA/pKM101, with or without induced rat liver S9 mix (Table E-2). Doses in this second assay were significantly higher than those that were achievable in the initial assay (up to 5,000 µg/plate without S9 and 6,000 µg/plate in the presence of S9).

In vivo, no significant increases in micronucleated immature (polychromatic erythrocytes, PCEs) or mature (normochromatic erythrocytes, NCEs) erythrocytes were observed in peripheral blood samples from rats in the 3-month study (Table E-3). The small increase in micronucleated immature erythrocytes observed in the male rats was within historical control ranges (<1 standard deviation of the mean) and was therefore judged not to be biologically significant. In mice from the 3-month study, small but statistically significant increases in micronucleated mature erythrocytes were seen at the highest exposure concentration (2,000 ppm), but the observed values for the female mice were within historical control ranges (<1 standard deviation of the mean) and were not considered to be biologically significant (Table E-4). For male mice, the observed response was outside the historical control range for the laboratory and was therefore judged to be positive. An exposure concentration-related increase in the percentage of immature erythrocytes in peripheral blood was seen only in female mice, suggesting that p-chloro-α,α,α-trifluorotoluene may have stimulated erythropoiesis in female mice. No significant changes in the percentage of immature erythrocytes were seen in male or female rats, or male mice.