# Materials and Methods

## Procurement and Characterization of p-Chloro-α,α,α-trifluorotoluene

p-Chloro-α,α,α-trifluorotoluene was obtained from Special Materials Company (Cherry Hill, NJ, and New York, NY) in two lots. Lot 2009-01-05 was used in the 3-month studies and lot 2010-05-24 was used in the 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix I). Reports on analyses performed in support of the p-chloro-α,α,α-trifluorotoluene studies are on file at the National Institute of Environmental Health Sciences.

Both lots were clear liquid and were identified as p-chloro-α,α,α-trifluorotoluene by proton nuclear magnetic resonance spectroscopy and Fourier transform infrared spectroscopy. Purity of both lots was determined by elemental analyses and gas chromatography (GC) with flame ionization detection (FID). Karl Fischer titration indicated a water content of 82.4 (lot 2009-01-05) or 109.8 (lot 2010-05-24) ppm. Elemental analyses of both lots for carbon and hydrogen were consistent with theoretical values. Inductively coupled plasma spectroscopic analysis of lot 2010-05-24 indicated less than 0.002% sulfur. GC/FID indicated one major peak (peak area percents of 99.68% for lot 2009-01-05, 99.57% for lot 2010-05-24) and two impurities with areas greater than or equal to 0.1% relative to the major peak area; the two peaks were identified as 3-chlorobenzotrifluoride (0.2%, lot 2009-01-05; 0.3%, lot 2010-05-24) and 2-chlorobenzotrifluoride (0.1%, lot 2009-01-05; 0.2%, lot 2010-05-24). Analysis of both lots by high performance liquid chromatography (HPLC) with an ultraviolet light/visible light detector showed that 3,4-dihydroxybenzoic acid, a peroxide scavenger, was not present. The overall purity of each lot was determined to be greater than 99.5%.

The bulk chemical was stored in the original shipping containers at room temperature. To ensure stability, periodic reanalyses of the bulk chemical were performed during the 3-month and 2-year studies by the study laboratory using GC/FID. No degradation of the bulk chemical was detected.

## Vapor Generation and Exposure System

p-Chloro-α,α,α-trifluorotoluene was pumped from a stainless steel reservoir into a heated glass column. Preheated nitrogen entered the column and assisted in vaporizing the chemical while conveying it from the generator into a vapor distribution manifold. Concentration in the manifold was determined by the chemical pump rate, dilution air flow, and nitrogen flow rates. Pressure in the distribution manifold was kept fixed to ensure constant flows through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Heated (approximately 130°F) individual Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the p-chloro-α,α,α-trifluorotoluene vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that p-chloro-α,α,α-trifluorotoluene vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table I-2 and Table I-3. Chamber and room concentrations of p-chloro-α,α,α-trifluorotoluene were monitored by an on-line gas chromatograph with FID. Samples were drawn from each exposure chamber approximately every 20 minutes for the 3-month and 2-year studies during each 6-hour exposure period using Hastelloy^®^-C stream-select and gas-sampling valves in a separate, heated oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout each exposure day for instrument drift against an on-line standard vapor of 4-chlorotoluene in nitrogen supplied by a standard generator. The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples collected with sorbent tubes, extracted with toluene containing an internal standard of 4-chlorotoluene and analyzed using an off-line gas chromatograph equipped with a FID. Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standard solutions of the test chemical containing 4-chlorotoluene as an internal standard in toluene.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.2 minutes. Based on experimental data, a T_90_ value of 15 minutes was selected for the 3-month studies, and a T_90_ value of 12 minutes was selected for the 2-year studies.

The uniformity of p-chloro-α,α,α-trifluorotoluene vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 3-month studies and approximately every 3 months during the 2-year studies. The vapor concentration was measured using the on-line gas chromato-graph. Chamber concentration uniformity was maintained throughout the studies.

The persistence of p-chloro-α,α,α-trifluorotoluene in the chambers after vapor delivery ended was determined by monitoring the vapor concentration in the 2,000 ppm chambers in the 3-month studies and the 1,000 ppm rat and 400 ppm mouse chambers in the 2-year studies with and without animals present in the chambers. In the 3-month studies, the concentration decreased to 1% of the target concentration within 24 minutes without animals present and within 30 minutes with animals present. For the 2-year rat studies, the concentration decreased to 1% of the target concentration within 24 minutes without animals present and within 46 minutes with animals present. For the 2-year mouse studies, the concentration decreased to 1% of the target concentration within 23 minutes without animals present and within 31 minutes with animals present.

Samples of the test atmosphere from the distribution lines and the low and high exposure concentration chambers for each species were collected prior to the study without animals present and at the beginning and end of one generation day with animals present during the 3-month and 2-year studies. Additional samples were collected from the generator reservoir, and all of the samples were analyzed using GC/FID to measure the stability and purity of p-chloro-α,α,α-trifluorotoluene in the generation and delivery system. To assess whether impurities or degradation products co-eluted with p-chloro-α,α,α-trifluoro-toluene or the solvent, a second GC/FID analysis of samples from the distribution line, 125 ppm and 2,000 ppm chambers (3-month studies), 100 ppm and 1,000 ppm rat chambers (2-year studies), 100 ppm and 400 ppm mouse chambers (2-year studies), and the generator reservoir was performed. The chamber atmosphere was monitored for 3,4-dihydroxybenzoic acid, a potential degradation product of p-chloro-α,α,α-trifluorotoluene, using HPLC prior to and during the 3-month and 2-year studies.

No evidence of degradation of p-chloro-α,α,α-trifluoro-toluene was noted in any part of the exposure system in any of the samples collected prior to or during the 3-month and 2-year studies. During the 3-month studies, 3-chlorobenzotrifluoride (0.2%) was the only impurity detected in atmosphere or generator reservoir samples with an area greater than 0.1% of the total peak area. During the 2-year studies, 3-chlorobenzotrifluoride (0.3%) and 2-chlorobenzotrifluoride (0.2%) were the only impurities detected in the atmosphere or generator reservoir samples with areas greater than 0.1% of the total peak area. No 3,4-dihydroxybenzoic acid was detected in the exposure chamber atmosphere samples at greater than or equal to 0.1%.

## Animal Source

Male and female Hsd:Sprague Dawley^®^ SD^®^ rats were obtained from Harlan Laboratories, Inc. (Livermore, CA), and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 3-month and 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumu-lative toxic effects of repeated exposure to p-chloro-α,α,α-trifluorotoluene and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 13 (rats) or 12 (mice) days and were 6 weeks (rats) or 5 to 6 weeks (mice) old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Groups of 10 male and 10 female rats and mice were exposed by whole body inhalation to p-chloro-α,α,α-trifluorotoluene vapor at concentrations of 0, 125, 250, 500, 1,000, or 2,000 ppm, 6 hours plus T_90_ (15 minutes) per day, 5 days per week for 14 weeks. Exposure concentrations used in the 3-month studies were selected based on the available inhalation literature. Newton et al.^27^ reported on 4-week and 3-month inhalation toxicity studies in Sprague Dawley rats. In the 4-week study, relatively little toxicity was observed at exposure concentrations up to 1,000 ppm; however, the highest concentration selected for the 3-month study was 250 ppm. In the 3-month study, a low incidence of hepatocyte hypertrophy was the only histopathologic finding reported. No prechronic mouse studies were available for use in selecting exposure concentrations. Based on the available information, 2,000 ppm was selected as the highest exposure concentration in these NTP 3-month studies for both rats and mice, with twofold exposure concentration spacing. Feed was available ad libitum except during exposure periods, and water was available ad libitum. Rats and mice were housed individually. Clinical observations were recorded on day 8, weekly thereafter, and at study termination. The animals were weighed initially, on day 8, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of p-Chloro-α,α,α-trifluorotoluene

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Hsd:Sprague Dawley^®^ SD^®^ rats B6C3F1/N mice | Hsd:Sprague Dawley^®^ SD^®^ rats B6C3F1/N mice
Animal Source
Rats: Harlan Laboratories, Inc. (Livermore, CA) Mice: Taconic Farms, Inc. (Germantown, NY) | Rats: Harlan Laboratories, Inc. (Livermore, CA) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 13 days Mice: 12 days | 12 days
Average Age When Studies Began
Rats: 6 weeks Mice: 5 to 6 weeks | Rats: 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
October 26, 2009 | Rats: January 17, 2011 Mice: January 31, 2011
Duration of Exposure
6 hours plus T_90_ (15 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 104 to 105 weeks
Date of Last Exposure
Rats: January 25 (males) or 26 (females), 2010 Mice: January 27 (males) or 28 (females), 2010 | Rats: January 13-14 (males) or 15-16 (females), 2013 Mice: January 27-29 (males) or 29-31 (females), 2013
Necropsy Dates
Rats: January 26 (males) or 27 (females), 2010 Mice: January 28 (males) or 29 (females), 2010 | Rats: January 14-15 (males) or 16-17 (females), 2013 Mice: January 28-30 (males) or January 30-February 1 (females), 2013
Average Age at Necropsy
Rats: 19 weeks Mice: 19 to 20 weeks | Rats: 110 to 111 weeks Mice: 109 to 111 weeks
Size of Study Groups
10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods, changed weekly | Same as 3-month studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed and rotated weekly | Same as 3-month studies
Cageboard
Techboard^®^ Ultra untreated paper excreta pan liner (Shepherd Specialty Papers, Watertown, TN), changed daily | Same as 3-month studies
Chamber Air Supply Filters
Single HEPA (open stock), charcoal (RSE, Inc., New Baltimore, MI), and Purafil (Environmental Systems, Lynnwood, WA), all new at study start | Same as 3-month studies, except HEPA changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE), changed weekly, excreta pans changed daily | Same as 3-month studies
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 3-month studies
Exposure Concentrations
0, 125, 250, 500, 1,000, or 2,000 ppm | Rats: 0, 100, 300, or 1,000 ppm Mice: 0, 100, 200, or 400 ppm
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on day 8, weekly thereafter, and at the end of the studies; clinical observations were recorded on day 8, weekly thereafter, and at the end of the studies. | Observed twice daily. Mice and female rats were weighed initially, weekly for 13 weeks, every 4 weeks thereafter, and at the end of the studies; clinical observations were recorded at week 5, every 4 weeks thereafter, and at the end of the studies. Male rats were weighed initially, weekly for 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at the end of the study; clinical observations were recorded at week 5, every 4 weeks through week 93, every 2 weeks thereafter, and at the end of the study.
Method of Kill
Carbon dioxide asphyxiation (70% in air) | Same as 3-month studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only). Hematology: spun hematocrit; packed cell volume; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differential Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts | None
Histopathology
Complete histopathology was performed on chamber control and 2,000 ppm rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung (with bronchus), lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. The adrenal gland, Harderian gland, kidney, liver, and thymus of rats and mice; testis with epididymis of male rats; mammary gland of female rats; and the forestomach and spleen of male and female mice were also examined in the remaining exposure groups. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung (with bronchus), lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 500, 1,000, and 2,000 ppm groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from females exposed to 0, 500, 1,000, or 2,000 ppm for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and estrous cycle length were evaluated. | None
Evaluation of Hras and Ctnnb1 Mutations in Hepatocellular Carcinomas
None | At necropsy, male and female mouse hepatocellular carcinomas (HCC) and normal liver tissues were obtained as formalin-fixed paraffin-embedded blocks. Hot-spot mutations in Hras and Ctnnb1 genes were evaluated in HCCs arising from all p-chloro-α,α,α-trifluorotoluene-exposed groups (n = 62) and those arising spontaneously in chamber controls (n = 15). In addition, age-matched non-tumor livers (n = 10) from chamber controls were analyzed. There were no differences in the incidences of mutations between male and female mice, therefore the combined data from male and female mice are presented.

At the end of the 3-month studies, blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice for hematology and clinical chemistry (rats only) analyses. For the hematology samples, blood was collected in tubes containing potassium EDTA; for the clinical chemistry samples, the blood was collected in a tube devoid of anticoagulant but containing a separator gel for serum. An ADVIA 120 (Siemans Medical Solutions Diagnostics, Tarrytown, NY) was used to determine packed cell volume; hemoglobin concentration; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; and leukocyte counts and differential. Manual hematocrit values were determined using a microcentri-fuge (Heraeus Haemofuge, Heraeus Holding GmbH; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Company, Needham Heights, MA) for comparison to ADVIA 120 values for packed cell volume. Blood smears were stained with a Romanosky-type aqueous stain in a Wescor 7120 aerospray slide stainer (Wescor, Inc., Logan, UT). Cell morphology was assessed using the blood smears. Manual leukocyte differentials were performed on the blood smears when populations were flagged by the ADVIA 120. Blood samples for clinical chemistry analyses were analyzed using a Cobas c 311 analyzer (Roche Diagnostic Corporation, Indianapolis, IN). The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 500, 1,000, or 2,000 ppm. The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on chamber control and 2,000 ppm groups of rats and mice. Table 1 lists the tissues and organs routinely examined.

The sperm motility and vaginal cytology evaluations results suggested an effect on spermatogenesis, but there was no microscopic correlation found during the routine pathology examination of the tissues from the 3-month studies. Therefore, a detailed qualitative histopathologic examination was conducted on H&E-stained slides of testes and epididymides from the chamber control and 2,000 ppm groups of male rats and mice from the 3-month studies. In rats, findings in the 2,000 ppm group prompted examination of testes and epididymides from all exposure groups. In mice, no microscopic findings were recorded in the chamber control or the 2,000 ppm groups. Hence, no other exposed groups of mice were reviewed. Tubular stages of the spermatogenic cycle were taken into account in order to identify findings.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP PPR process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^35^ and Boorman et al.^36^.

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats were exposed by whole body inhalation to p-chloro-α,α,α-trifluorotoluene vapor at concentrations of 0, 100, 300, or 1,000 ppm, and 50 male and 50 female mice were exposed to concen-trations of 0, 100, 200, or 400 ppm, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 104 to 105 weeks.

Rats and mice were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were approximately 6 weeks old and mice approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Rats and mice were housed individually. Feed was available ad libitum except during exposure periods, and water was available ad libitum. Cages were rotated weekly within the chambers; cages and chambers were changed weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

### Clinical Examinations and Pathology

All animals were observed twice daily. For mice and female rats, clinical observations were recorded at week 5, every 4 weeks thereafter, and at study termination; body weights were recorded on day 1, weekly for 13 weeks, every 4 weeks thereafter, and at study termination. For male rats, clinical observations were recorded at week 5, every 4 weeks through week 93, every 2 weeks thereafter, and at study termination; body weights were recorded on day 1, weekly for 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at study termination.

Complete necropsies and microscopic examinations were performed on all rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

At necropsy, normal liver samples and hepatocellular carcinomas (HCC) from chamber control and B6C3F1/N mice exposed to p-chloro-α,α,α-trifluorotoluene were fixed in 10% neutral buffered formalin and processed into paraffin blocks. The formalin-fixed paraffin-embedded normal liver tissues from chamber controls (n = 10; five males and five females) and HCCs arising spontaneously (n = 15; eight males and seven females) or from p-chloro-α,α,α-trifluorotoluene-exposed groups (n = 62; 100 ppm, 10 males and eight females; 200 ppm, 10 males and 10 females; 400 ppm, 12 males and 12 females) were examined for hot-spot mutations in Hras and Ctnnb1 genes (Appendix L).

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the adrenal gland, forestomach, kidney, liver, lung, and thyroid gland in male and female rats; uterus in female rats; and forestomach, Harderian gland, small intestine, kidney, larynx, liver, and lung in male and female mice.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^35^ and Boorman et al.^36^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^37^.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^38^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^39^ method for testing two groups for equality and Tarone’s^40^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-3, Table C-1, Table C-4, Table D-1, and Table D-5 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^41-43^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^41^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^41^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F_1_ mice^44^. Bailer and Portier^41^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^45^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01 N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^46^ and Williams^47; 48^. Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^49^ (as modified by Williams^50^) and Dunn^51^. Jonckheere’s test^52^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^53^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager^54^. For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^55-57^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. Historical control data for rats in this Technical Report are limited to all routes of administration because the current study is the only 2-year inhalation study in Hsd:Sprague Dawley^®^ SD^®^ rats conducted by NTP in the most recent 5-year period and include the concurrent controls and control animals from one other study.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^58^. In addition, the 3-month and 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of p-chloro-α,α,α-trifluorotoluene was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^59; 60^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^61^ and the somatic mutation theory of cancer^62; 63^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity corresponds well with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites^64^. A positive response in the Salmonella test was shown to be the most predictive in vitro (89% of the Salmonella mutagens are rodent carcinogens)^65; 66^. Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test^67; 68^. However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^69^. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.