# Introduction

Figure 1

p-Chloro-α,α,α-trifluorotoluene (CASRN 98-56-6; Chemical Formula: C_7_H_4_ClF_3_; Molecular Weight: 180.56)

Synonyms: Benzene, 1-chloro-4-(trifluoromethyl)-; p-chlorobenzotrifluoride; 4-chlorobenzotrifluoride; 1-chloro-4-(trifluoromethyl)benzene; 4-trifluoromethylchlorobenzene.

## Chemical and Physical Properties

p-Chloro-α,α,α-trifluorotoluene is part of a group of structurally related compounds, benzotrifluorides (BTFs). p-Chloro-α,α,α-trifluorotoluene is a combustible, clear, colorless liquid with an aromatic odor^1; 2^. p-Chloro-α,α,α-trifluorotoluene has a melting point of –36°C, a flash point of 43°C, a boiling point of 139°C, and a vapor pressure of 7.63 mm Hg at 25°C^1-4^. p-Chloro-α,α,α-trifluorotoluene reacts with photochemically produced hydroxyl radicals following prolonged exposure to air^5^.

## Production, Use, and Human Exposure

p-Chloro-α,α,α-trifluorotoluene is a solvent used in paints and coatings (e.g., epoxy, acrylics) and as an industrial intermediate in the production of other chemicals (e.g., herbicides, dyes, pharmaceuticals)^4^. Domestic production and import of p-chloro-α,α,α-trifluorotoluene was reported to be 10 to 50 million pounds in 1986, 1990, 1994, and 1998; in 2011, the reported production/import was 29 million pounds, over 95% of which was imported^6^. p-Chloro-α,α,α-trifluorotoluene is considered an exempt volatile organic compound with non-ozone depleting status, resulting in higher end-user applications than other solvents^4^. End-user applications of p-chloro-α,α,α-trifluorotoluene, including automobile body coating and part cleaning, likely lead to higher inhalation and dermal exposure than use in industrial settings.

Occupational exposure has been assessed by the National Institute for Occupational Safety and Health (NIOSH) in vehicle and paint manufacturing plants using industrial hygiene sampling methods across a number of job tasks in each industry^7^. The geometric mean of personal exposures was 2.1 ppm and 0.7 ppm at the vehicle and painting manufacturing plants, respectively. Most personal exposures were lower than 10 ppm, with the exception of a single interior refurbishment worker in one of the vehicle manufacturing plants (12.2 ppm). This study did not assess exposures in other occupational settings (e.g., autobody repair), which may be higher than was observed by Lee et al^7^.

Environmental exposure to p-chloro-α,α,α-trifluorotoluene may result following spillage or improper disposal in industrial settings. Industrial releases of p-chloro-α,α,α-trifluorotoluene by Occidental Chemical Corporation in the early 1990s in Niagara Falls, NY, resulted in detection of p-chloro-α,α,α-trifluorotoluene in groundwater up to 4.6 mg/L.^8^ p-Chloro-α,α,α-trifluorotolu-ene was detected in various media near the Occidental Chemical Corporation in the 1980s, including fish (0.17 to 2.0 ppm) and Niagara River sediment (up to 2 ppm) from the Bloody Run Creek, Niagara River Watershed^9; 10^. Near the Diaz Chemical Corporation in Holley, NY, groundwater levels of p-chloro-α,α,α-trifluorotoluene were reported to be 49 mg/L^11^. p-Chloro-α,α,α-trifluorotolu-ene was detected in groundwater samples in Vicenza, Italy, at concentrations up to 1 mg/L due to industrial contamination^12^. Water samples from Love Canal, NY, have qualitatively tested positive for p-chloro-α,α,α-trifluorotoluene^13^.

## Regulatory Status

The United States Environmental Protection Agency set p-chloro-α,α,α-trifluorotoluene preliminary remediation goals for noncancer endpoints for residential soil (1.2 × 10^3^ mg/kg), industrial soil (1.2 × 10^4^ mg/kg), air (73 μg/m^3^), and drinking water (7.3 × 10^2^ μg/L) contamination related to superfund sites^14^. These values were based on a chronic reference dose of 20 μg/kg body weight per day^15^ generated from an oral gavage study in rats that reported renal tube degeneration with a no-observed-adverse-effect-level of 15 mg/kg per day^16^. There is currently no federal occupational exposure guideline; however, a United States importer of p-chloro-α,α,α-trifluorotoluene has issued a permissible exposure limit of 20 ppm (8-hour time-weighted average)^17^. New York has implemented a water quality limit of 5 μg/L p-chloro-α,α,α-trifluorotoluene in groundwater^18^. No federal regulations exist for occupational exposure, drinking water, or air contamination.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Partition coefficients for blood, fat, brain, and muscle have been reported in the literature for p-chloro-α,α,α-trifluorotoluene following inhalation exposure^19^; however, no other absorption, distribution, metabolism or excretion studies have been reported for inhalation exposure.

Following a single oral gavage dose of 1 mg [^14^C] p-chloro-α,α,α-trifluorotoluene/kg body weight, expiration of the parent compound was the major route of excretion (62% to 68%, 96 hours post-gavage) in male and female Sprague Dawley rats and urinary and fecal excretion accounted for 14% to 15% and 3% to 5%, respectively^20^. Only 1% of the administered dose was detected in the carcass 96 hours post-gavage. In the same study, at a higher single oral gavage dose (104 mg/kg, female rats only), expiration accounted for 82% of the administered dose. In urine, the major compounds detected were glucuronide conjugates of hydroxyl-metabolites; mercapturic acid metabolites were also detected, accounting for less than 0.5% of the administered dose for both doses and sexes. The highest tissue concentration of radioactivity was found in abdominal adipose, with female adipose levels 17 times higher than those in males administered the same dose.

The absorption half-life of p-chloro-α,α,α-trifluorotoluene in male F344/N rats following a single oral gavage dose (0, 10, 50, or 400 mg/kg) has been determined using different vehicles^21^. The vehicle used for oral gavage influenced time to maximum blood concentration (T_max_) and the absorption rate constant; α-cyclodextrin had a larger absorption rate constant and shorter T_max_ than corn oil in all doses examined. However, maximum concentration and area under the curve were similar between vehicles and increased proportionally to the dose administered. Similarly, there was no difference in elimination rate constant, volume of distribution, or total clearance rate between dose or vehicle. Bioavailability estimated following administration was approximately 100% despite the vehicle used and suggests very little or no first pass metabolism. Following repeated dosing with p-chloro-α,α,α-trifluorotoluene in corn oil at 10, 50, 400, or 1,000 mg/kg, levels of p-chloro-α,α,α-trifluorotoluene in blood and liver were similar in male and female rats; however, male rats had much higher concentrations of p-chloro-α,α,α-trifluorotoluene in the kidney, compared to females at all doses examined.

p-Chloro-α,α,α-trifluorotoluene inhalation exposure for 13 weeks, at doses up to 250 ppm in Sprague Dawley rats, has been reported to cause increases in various cytochrome P450 (CYP) isoforms; a substantial increase in CYP2B activity was reported, along with moderate, statistically significant increases in activity for CYP2E1 (males only), CYP3A (females only), CYP1A1, CYP1A2, and total CYP^22^.

### Humans

Human partition coefficients for blood, liver, fat, brain, and kidney have been estimated based on inhalation data from rats, predicting the highest percentage of inhaled dose in fat, regardless of exposure concentration^23^. No other published data are available regarding the absorption, distribution, metabolism, or excretion of p-chloro-α,α,α-trifluorotoluene in humans.

## Toxicity

### Experimental Animals

Short-term studies of p-chloro-α,α,α-trifluorotoluene following oral dosing indicate that liver, kidney, and adrenal cortex are common target organs. Short-term oral gavage dosing of p-chloro-α,α,α-trifluorotoluene, up to 1,000 mg/kg per day, resulted in increased kidney and liver weights in rats and mice^21; 24^. Male and female F344/N rats and B6C3F_1_ mice administered 1,000 mg/kg per day for 14 days had consistently higher liver weights compared to controls, ranging from 55% to 82% higher than controls^21^. Higher liver weights were also observed in Sprague Dawley rats (1,000 mg/kg per day) following 28 days of dosing^24^. Histologic findings in the liver were not consistent between the studies, possibly due to differences in the strains/stocks of animals used. Hepatocyte hypertrophy was observed in the NTP^21^ study (all 1,000 mg/kg animals), while no histologic liver findings were reported by Macri et al.^24^. Subchronic (3-month) oral gavage dosing of Fischer 344 rats with p-chloro-α,α,α-trifluorotoluene (up to 500 mg/kg per day) also resulted in increased liver weights with accompanying centrilobular hypertrophy^25^.

In a 14-day study^21^, oral dosing of p-chloro-α,α,α-trifluorotoluene caused kidney nephropathy in all male rats (doses of 50 mg/kg per day or greater), accompanied by a dose-dependent increase in kidney α2u-globulin (five-fold higher at 1,000 mg/kg). This was consistent with the Macri et al.^24^ study that reported hyaline droplet necrosis of the proximal convoluted tubules in all 1,000 mg/kg male rats and some male rats at lower doses. Adrenal cortex cytoplasmic vacuolization was observed in male rats receiving 400 mg/kg or greater and female rats receiving 1,000 mg/kg in the NTP^21^ study and in male rats receiving 1,000 mg/kg in the Macri et al.^24^ study. Clinical chemistry endpoints including increased serum cholesterol, triglycerides (males), and lactate dehydrogenase (females) were also affected in Sprague Dawley rats^24^.

Similar to oral dosing, short-term (4-week) whole body inhalation exposure of Sprague Dawley rats to p-chloro-α,α,α-trifluorotoluene (up to 1,044 ppm) resulted in changes in clinical chemistry parameters and liver and kidney weights^26^. Increased liver weights occurred in males and females exposed to 492 ppm or greater (25% to 48%) and increased kidney weights also occurred, with less consistency, in males exposed to 492 ppm and females exposed to 492 ppm or greater. Increased incidences and severities of hepatocyte hypertrophy occurred in a concentration-dependent manner in males and females. During exposure, increased activity at exposures of 262 ppm or greater and hyperactivity and tremors at exposures of 1,044 ppm occurred in both sexes, more often in females. These findings prompted a more comprehensive 13-week neurotoxicity study involving whole body inhalation exposure of Sprague Dawley rats to p-chloro-α,α,α-trifluorotoluene concentrations of 0, 10, 31, or 252 ppm^27^. No treatment-related effects were noted in clinical observations or function assessments during the study, and organ weight changes that occurred at 4 weeks were not repeated (except increased male kidney weights). Hepatocyte hypertrophy was present in males and females (3/10) in the highest exposure concentration group.

Acute oral gavage and inhalation studies have reported neurologic and behavioral effects. A 4-hour inhalation exposure in Sprague Dawley rats, up to approximately 9,000 ppm, was reported to cause muscle spasms, labored breathing, excessive salivation, limb ataxia, and hypersensitivity to touch; upon necropsy, these animals exhibited dark lungs with white foci and hemorrhagic staining of the thymus^28^. A single oral gavage dose (~6.8 g/kg) in Sprague Dawley rats caused hypoactivity, tremors, ataxia, decreased limb tone, and loss of the righting reflex; at necropsy, lung discoloration with red foci and kidney discoloration were noted^29^. Acute dermal exposure (2 mL/kg body weight) in New Zealand White rabbits caused skin erythema and edema that resolved following exposure, as well as macroscopic effects in the kidneys and lungs (red foci) and abscesses that were noted at necropsy^30^.

### Humans

Human exposure to p-chloro-α,α,α-trifluorotoluene may cause irritation at sites of contact (skin, eye, respiratory tract, mucous membranes), and inhalation exposure may cause labored breathing, dizziness, and drowsiness according to the safety data sheet^17^. Other effects have been reported following inhalation exposure including coughing, shortness of breath, chest pain, and edema^31^.

## Reproductive and Developmental Toxicity

### Experimental Animals

One study has investigated the reproductive toxicity of p-chloro-α,α,α-trifluorotoluene^16^. Male and female Sprague Dawley rats (20/sex per group) received oral gavage doses of p-chloro-α,α,α-trifluorotoluene (up to 45 mg/kg per day) for 4 weeks prior to mating and throughout gestation and lactation until weaning of the F_1_ pups, for a total of 76 to 83 days. F_1_ pups were then dosed daily, at the same dose as their dams, beginning at weaning (postnatal day 21) and continuing for 90 days postweaning. Significant findings included increased weight gain in male pups in all dosed groups and decreased weight gain in high-dose female pups, hematologic changes (decreased erythrocytes and hemoglobin, increased mean cell volume), and increased incidences of nonneoplastic lesions in the lung. Fecundity (pups per litter and pup survival) was higher in dosed animals compared to controls, and there was no observed effect on fertility.

### Humans

No reports on the effect of p-chloro-α,α,α-trifluorotoluene on reproduction or development in humans were found in the literature.

## Carcinogenicity

### Experimental Animals

No reports on the carcinogenic potential of p-chloro-α,α,α-trifluorotoluene in experimental animals were found in the literature.

### Humans

An epidemiologic assessment of a small cohort of workers (4,000) at the Occidental Chemical Corporation plant in Niagara, NY, reported higher than expected rates of respiratory system and stomach cancers^32^. However, it is likely that this cohort of individuals was exposed to a large mixture of chemicals, with more than 80 CAS numbers listed as keywords on the submission report.

## Genetic Toxicity

There are few published reports on the genotoxicity of p-chloro-α,α,α-trifluorotoluene, but the available data indicate that the compound is not genotoxic. No evidence of mutagenicity was observed for p-chloro-α,α,α-trifluorotoluene at doses up to 1,000 µg/plate in any of several strains of Salmonella typhimurium (TA98, TA100, TA1535, TA1537, and TA1538) in tests conducted with and without Aroclor 1254-induced rat or hamster liver S9 mix^4; 33^. Bignami and Crebelli^34^ also reported negative results with p-chloro-α,α,α-trifluorotoluene in a test for induction of 8-azoguanine resistance in S. typhimurium. In addition to these two published reports, an absence of mutagenic activity was reported in S. typhimurium strains TA98, TA100, TA1535, and TA1537 using ß-glucoronidase-treated or untreated urine from mice exposed to up to 500 mg/kg p-chloro-α,α,α-trifluorotoluene for 2 days by oral gavage.^5^

Generally negative results from unreviewed, unpublished studies have been reported for p-chloro-α,α,α-trifluoro-toluene in mammalian cell test systems^5^. No induction of trifluorothymidine resistance was seen in mouse lymphoma L5178Y cells exposed to concentra-tions up to 50 nL/mL p-chloro-α,α,α-trifluorotoluene, with or without rat liver S9 mix^5^. How-ever, p-chloro-α,α,α-trifluorotoluene was reported to induce sister chromatid exchanges in L5178Y mouse lymphoma cells with and without S9 activation, but no increases in chromosomal aberrations were seen in cultured Chinese hamster ovary cells treated with p-chloro-α,α,α-trifluorotoluene, with or without rat liver S9 mix^5^. Furthermore, negative results were reported in an in vivo bone marrow chromosomal aberrations test in male and female Sprague Dawley rats administered a single dose of p-chloro-α,α,α-trifluorotoluene by oral gavage up to 5 mL/kg^5^.

## Study Rationale

p-Chloro-α,α,α-trifluorotoluene was nominated to NTP in 1981 by the National Cancer Institute (NCI) due to its high production volume and suspicion of carcinogenic potential. Subsequently, NTP conducted 14-day gavage studies in F344/N rats and B6C3F_1_ mice^21^. In 2001, public comments submitted to the NTP Center for the Evaluation of Risks to Human Reproduction, suggested an evaluation of the p-chloro-α,α,α-trifluorotoluene literature to determine if chronic toxicity testing was warranted based on increased use of p-chloro-α,α,α-trifluorotoluene as a replacement for volatile organic compounds in certain solvent applications. In 2006, a representative from Kowa American Corporation, a p-chloro-α,α,α-trifluorotoluene importer, nominated p-chloro-α,α,α-trifluorotoluene for toxicologic characterization due to expanding use and lack of occupational exposure limits from the Occupational Safety and Health Administration, the NIOSH, or the American Conference of Governmental Industrial Hygienists. Additionally, the NCI and Kowa American Corporation nominated the benzotrifluoride (BTF) compound class to NTP. NTP evaluated various BTF compounds for potential testing, including benzotrifluoride and 3,4-dichlorobenzotrifluoride. Benzotrifluoride had no available production or import data for the United States, and the use of 3,4-dichlorobenzotrifluoride was restricted to industrial settings with less potential for exposure compared to p-chloro-α,α,α-trifluorotoluene. After evaluating the exposure and use information and the toxicology literature for several BTF compounds, NTP proposed and subsequently conducted inhalation prechronic and chronic toxicity and carcinogenicity studies of p-chloro-α,α,α-trifluorotoluene.