# Appendix M Summary of Peer Review Panel Comments

On July 13, 2017, the draft Technical Report on the toxicology and carcinogenesis studies of p-chloro-α,α,α-trifluorotoluene received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. G.K. Roberts, NIEHS, introduced the toxicology and carcinogenicity studies of p-chloro-α,α,α-trifluorotoluene by discussing the uses of the chemical and the rationale for the studies, describing the experimental design of the 3-month and 2-year studies, reporting on survival and body weight effects, and commenting on chemical-related neoplasms and nonneoplastic lesions in rats and mice. The proposed conclusions for the 2-year studies were some evidence of carcinogenic activity in male and female Hsd:Sprague Dawley^®^ SD^®^ rats and clear evidence of carcinogenic activity in male and female B6C3F1/N mice.

Dr. Gordon, the first reviewer, stated that the study design was excellent, and that based on the 3-month studies, the appropriate choices were made for the 2-year exposure concentrations for both rodent species. He also approved of the generation and monitoring of the exposure chamber concentrations and the pathologic survey of neoplastic and nonneoplastic changes. His only methodological concern was why the sperm endpoints were not included in the 2-year studies, because positive findings were observed for male reproductive endpoints in the 3-month rat studies. He found the data presentation very clear in both text and tables. He felt that appropriate conclusions were delineated, except that the correct conclusion for carcinogenesis in the female rats was somewhere between some and clear evidence. He suggested several additions to the report.

Dr. A.E. Brix, the NIEHS study pathologist, said that in the 2-year studies, the animals were too old and there were so many background changes, it would not be possible to detect subtle changes in male reproductive endpoints.

Dr. Conner, the second reviewer, stated that the design and conduct of the studies was appropriate for the questions raised. He recommended the inclusion of an estimate of dose, even if it is not precise. He felt that the conclusion for C-cell adenoma in male and female rats should have been equivocal evidence rather than some evidence. He also suggested that the conclusion for increased incidences of stromal polyp in the uterus of female rats should have been equivocal evidence rather than some evidence.

Dr. Roberts said it was not feasible to take accurate measurements during exposure, which would be needed for an accurate estimate of dose, due to several factors. Dr. Conner reiterated that that information is important in the regulatory world, and an estimate of dose, even with caveats, would be useful. Dr. Roberts discussed the reasons for the conclusions Dr. Conner mentioned.

Dr. Ludewig, the third reviewer, said that the studies were very well-planned and well-executed. She agreed with the NTP findings with respect to neoplasms. She said she would like to see if there were any difference in the chamber control animals from this inhalation study and controls from other types of studies, because the housing conditions for the inhalation studies were different. She noted a decrease in mammary gland adenomas and carcinomas in the exposed animals compared to chamber controls, indicating a hormonal aspect. She suggested further discussion of mode of action parameters in the report. She noted that the word “obesogen” was not used in the report, despite the clear evidence of body weight gain. She suggested some reference as a trigger for future research.

Dr. Brix said that before labeling p-chloro-α,α,α-trifluorotoluene an obesogen, further studies would need to be conducted to determine whether the body weight gain was due to fat versus increased hypertrophy or liver neoplasms. Dr. Roberts noted that p-chloro-α,α,α-trifluoro-toluene was included in Tox21 evaluations. Regarding the housing used, she said that differences in controls from inhalation studies compared to controls from other routes was one reason there had been so much focus on the concurrent controls. Dr. N.J. Walker, NIEHS, added that it was always an issue in inhalation studies.

Dr. Peterson, the fourth reviewer, concurred that the studies were well-conducted, with appropriate study design and clear reasoning for the concentrations used in the 2-year studies. Overall, he agreed with the conclusions.

Dr. Gordon asked Dr. Conner which conclusions he felt should be changed from some evidence to equivocal evidence. Dr. Conner reiterated changing the conclusion from some evidence to equivocal evidence for the thyroid gland C-cell tumors and uterine stromal polyps, but said he would defer to the NTP calls and would not present a motion to change them.

Dr. Cattley asked for a motion to accept the NTP conclusions as written. Dr. Gordon moved and Dr. Peterson seconded the motion. The panel voted unanimously (6 yes votes) to accept the conclusions as written.