# Appendix L Evaluation of Hras and Ctnnb1 Mutations in Hepatocellular Carcinomas from B6C3F1/N Mice Chronically Exposed To p-Chloro-α,α,α-trifluorotoluene

## L.1 Introduction

Hepatocellular adenoma and hepatocellular carcinoma (HCC) are the most common primary liver tumors that arise either spontaneously or due to chemical exposure in the B6C3F1/N mice and occur more commonly in males than in females^100^. Evaluation of genetic mutations in cancer genes from HCCs from control and exposed groups can provide some insight into the mechanisms of chemical-induced carcinogenesis. Previous studies have shown that Ctnnb1 (β-catenin) mutations and Hras mutations are common in mouse hepatocellular tumors^72; 101-103^. Examination of genetic mutations in the hepatocellular tumors of mice resulting from chronic whole body inhalation exposure to p-chloro-α,α,α-trifluorotoluene might provide some understanding of p-chloro-α,α,α-trifluorotoluene-induced hepatocellular tumorigenesis.

## L.2 Materials and Methods

### L.2.1 Animals and Tissue Sampling

HCCs arising either spontaneously or due to chemical exposure as well as chamber control normal liver samples from B6C3F1/N mice were obtained from the current p-chloro-α,α,α-trifluorotoluene 2-year bioassay. Male and female B6C3F1/N mice were exposed by whole body inhalation to p-chloro-α,α,α-trifluorotoluene at concentrations of 0, 100, 200, or 400 ppm for 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 104 to 105 weeks. At necropsy, hepatocellular tumors were fixed in 10% neutral buffered formalin and processed into paraffin blocks, sectioned, and stained with hematoxylin and eosin for microscopic analysis. The formalin-fixed paraffin-embedded (FFPE) normal non-tumor liver tissue from chamber controls (n = 10; five males, five females) and HCCs from chamber control (spontaneous HCC) (n = 15; eight males, seven females) and p-chloro-α,α,α-trifluorotoluene-exposed mice (n = 62) (100 ppm, 10 males and eight females; 200 ppm, 10 males and 10 females; 400 ppm, 12 males and 12 females) were used for mutation analyses. The HCCs chosen for molecular biology analysis were based on their overall size and viability (minimal to no necrosis, autolysis, or hemorrhage observed microscopically) in order to maximize the amount and quality of DNA obtained from FFPE tissue sections. DNA quality was measured using a NanoDrop^®^ spectrophotometer (Thermo Fischer Scientific, Inc., Wilmington, DE) to calculate the ratio of absorbances at 260 and 280 nm, with Qubit 3.0 for double stranded DNA mass, and DNA samples with a purity range of 1.7 to 2.0 were used for analysis.

### L.2.2 DNA Extraction, Polymerase Chain Reaction (PCR), Sanger Sequencing, and Mutation Analysis

HCCs representing all p-chloro-α,α,α-trifluorotoluene-exposed groups (n = 62) and spontaneous HCCs from B6C3F1/N mice from chamber controls (n = 15) were evaluated for hot-spot mutations in Hras and Ctnnb1 genes that are relevant in hepatocellular carcinogenesis. In addition, age-matched non-tumor livers from chamber control mice (n = 10, five males and five females) were also analyzed for mutations. FFPE sections at 10 µm thickness were collected into screwcap tubes for DNA extraction. DNA was isolated from these FFPE-dissected tissue sections with the DNeasy^®^ Blood and Tissue Kit (QIAGEN, Valencia, CA). Amplification reactions were carried out by a semi-nested PCR using primer sets designed for Hras and Ctnnb1 genes for mice (Table L-1). Controls lacking template DNA were run with all sets of reactions. PCR products were purified using an ExoSAP PCR purification protocol. The purified PCR products were cycled with a Terminal Ready Reaction Mix-BigDye^®^ (PerkinElmer Applied Biosystems, Foster City, CA), and the extension products were purified with the DyeEx 2.0 Spin Kit (QIAGEN). The lyophilized PCR products were sequenced with an automatic sequencer (PerkinElmer Applied Biosystems ABI Model 3100). The resulting electropherograms were compared to identify mutations in HCCs from the chamber control groups and p-chloro-α,α,α-trifluorotoluene-exposed groups. The mutations were confirmed by sequencing with both forward and reverse primers, and the positive mutations were verified by repeat analysis, starting from amplification of the original DNA extracts.

Table L-1 Primers Used to Amplify the Hot-Spot Regions of Mouse Hras and Ctnnb1 Genes

Exon | Codon | Primer | Strand | Sequence
2 | Hras-61 | MH61OS | Sense | 5′-CCACTAAGCCTGTTGTGTTTTGCAG-3′
| | MH611s | Sense | 5′-GGACTCCTAGCGGAAACAGG-3′
| | MH61OA | Antisense | 5′-CTGTACTGATGGATGTCCTCGAAGGA-3′
| | MH611A | Antisense | 5′-GGTGTTGTTGATGGCAAATACA-3′
3 | Ctnnb1-8-55 | MBCF17130 | Sense | 5′-GATGGAGTTGGACATGGC-3′
| | MBCOR17294 | Antisense | 5′-ACTTGGGAGGTGTCAACA-3′
| | MBCIR17257 | Antisense | 5′-TTCTTCCTCAGGGTTGCC-3′

### L.2.3 Statistical Analysis of Mutation Incidences in Hepatocellular Tumors

To compare total mutation incidences in each exposed group to the incidences in the chamber control groups, one-sided Fisher exact test was used. Exact one-sided Cochran-Armitage trend test was used to test for exposure concentration-related trends in the incidences of mutations across all exposure groups.

## L.3 Results

In this study, the incidence of Hras mutations in mouse HCCs examined from p-chloro-α,α,α-trifluorotoluene-exposed groups was 37% (23/62) and were located within codon 61 mainly C to A or A to T transversions (Table L-2). There were significant trend and pairwise differences for Hras mutation incidence in the negative direction between HCCs occurring either spontaneously in chamber controls or resulting from chronic exposure to p-chloro-α,α,α-trifluorotoluene. There were no statistically significant differences in Ctnnb1 mutations in mouse HCCs resulting from chronic exposure to p-chloro-α,α,α-trifluorotoluene compared to the chamber control group. Four of the HCCs arising spontaneously harbored Ctnnb1 mutations, all of which were point mutations in codons 15-46 and contained a mixture of transitions and transversions similar to those observed in the HCCs from p-chloro-α,α,α-trifluorotoluene-exposed groups. The deletion of codons 27-35 were noted only in the HCCs (n = 5) resulting from the p-chloro-α,α,α-trifluorotoluene-exposed groups and none of the spontaneous HCCs had deletions in Ctnnb1 gene. There were no differences in the incidences of Hras or Ctnnb1 mutations in HCCs from male and female mice (data not presented) and hence the combined data from both male and female mice are presented in Table L-2.

Table L-2 Summary of Hras and Ctnnb1 Mutations in Non-tumor Liver Tissue and Hepatocellular Carcinomas (HCCs) from B6C3F1/N Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

Tissue | Dose (ppm) | Mutation Frequency | | Hras Codon 61 (CAA, Glu) | | | Ctnnb1 (Codon 15-46)
Tissue | Dose (ppm) | Hras^b^ (Codon 61) | Ctnnb1^b^ (Codon 15-46) | AAA (Lys) | GCA (Arg) | CTA, CTT (Leu) | Point mutation | Deletion of Codon 27-35
Non-tumor Liver | 0 | 0/10 (0) | 0/10 (0) | 0 | 0 | 0 | 0 | 0
HCCs | 0 | 11/15 (73)^#N^ | 4/15 (27) | 5 | 3 | 3 | 4 | 0^#^
| 100 | 7/18 (39) | 5/18 (28) | 2 | 3 | 2 | 5 | 0
| 200 | 9/20 (45) | 10/20 (50) | 4 | 3 | 2 | 8 | 2
| 400 | 7/24 (29)** | 6/24 (25) | 4 | 2 | 1 | 3 | 3
Historical Spontaneous HCCs^c^ | | 289/545 (53) | 5/111 (4.5) | 174 | 83 | 32 | 5 | 0
p-Chloro-α,α,α-trifluorotoluene-treated combined HCCs | | 23/62 (37) | 21/62 (34) | 10 | 8 | 5 | 16 | 5

** Significantly different (P < 0.01) from the spontaneous hepatocellular carcinomas (HCCs) in the chamber controls by the Fisher exact test.

^#^ Significant (P < 0.05) exposure concentration-related trend. N indicates a negative trend.

^a^ Male and female B6C3F1/N mice were exposed to 0, 100, 200, or 400 ppm p-chloro-α,α,α-trifluorotoluene by whole body inhalation for 2 years. Silent mutations were not included. Non-tumor Liver: 0 ppm (5 males + 5 females); HCCs: 0 ppm (8 males + 7 females), 100 ppm (10 males + 8 females), 200 ppm (10 males + 10 females), 400 ppm (12 males + 12 females).

^b^ Number of tissues with mutations/number of tissues assayed (% with mutation).

^c^ Historical database for Hras and Ctnnb1 mutations in spontaneous HCCs (Sills et al.^104^; Hayashi et al.^105^; unpublished data).

## L.4 Discussion

The Hras mutations in HCCs arising either spontaneously or due to chemical exposure are frequently localized within codon 61^72; 73^. There was a statistically significant trend and pairwise differences in the negative direction for Hras mutations between spontaneous HCCs in chamber control mice and HCCs resulting from chronic exposure to p-chloro-α,α,α-trifluorotoluene. p-Chloro-α,α,α-trifluorotoluene has been shown to increase CYP1A1 and CYP1A2 activity by twofold and CYP2B activity by fivefold^22^. CYP2B activation via constitutive androstane receptor is a well-known mechanism of tumor promotion activity in the liver of rodents^92^. p-Chloro-α,α,α-trifluorotoluene is nongenotoxic (Ames assay negative, chromosomal aberration assay negative) and may not directly cause mutations and initiate carcinogenesis. However, further mechanistic studies are needed to better understand p-chloro-α,α,α-trifluorotoluene-induced hepatocellular carcinogenesis.