# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and evaluated for the presence of pathogens. Samples were tested in-house or sent to the IDEXX BioResearch (formerly, at the time of testing, Research Animal Diagnostic Laboratory (RADIL)), University of Missouri (Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point except for the 18-month collection which consisted of 4 male rats and 5 female rats.

Table K-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
Multiplex Fluorescent Immunoassay
Kilham’s rat virus (KRV) | 3 weeks, study termination
Mycoplasma pulmonis | 3 weeks, study termination
Parvo NS-1 | 3 weeks, study termination
Pneumonia virus of mice (PVM) | 3 weeks, study termination
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | 3 weeks, study termination
Rat minute virus (RMV) | 3 weeks, study termination
Rat parvovirus (RPV) | 3 weeks, study termination
Rat theilovirus (RTV) | 3 weeks, study termination
Sendai | 3 weeks, study termination
Theiler’s murine encephalomyelitis virus (TMEV) | 3 weeks, study termination
Toolan’s H-1 virus (H-1) | 3 weeks, study termination
Two-year Study
Multiplex Fluorescent Immunoassay
Encephalitozoon cuniculi | 6 months
H-1 | 3 weeks, 6, 12, and 18 months, study termination
KRV | 3 weeks, 6, 12, and 18 months, study termination
M. pulmonis | 3 weeks, 6, 12, and 18 months, study termination
Parvo NS-1 | 3 weeks, 6, 12, and 18 months, study termination
PVM | 3 weeks, 6, 12, and 18 months, study termination
RCV/SDA | 3 weeks, 6, 12, and 18 months, study termination
RMV | 3 weeks, 6, 12, and 18 months, study termination
RPV | 3 weeks, 6, 12, and 18 months, study termination
RTV | 3 weeks, 6, 12, and 18 months, study termination
Sendai | 3 weeks, 6, 12, and 18 months, study termination
Immunofluorescence Assay
Pneumocystis carnii | 6 months
M. pulmonis | 12 months
RTV | 12 months
Mice
Three-month Study
Multiplex Fluorescent Immunoassay
Ectromelia virus | 3 weeks, study termination
Epizootic diarrhea of infant mice (EDIM) | 3 weeks, study termination
Lymphocytic choriomeningitis virus (LCMV) | 3 weeks, study termination
M. pulmonis | 3 weeks, study termination
Mouse hepatitis virus (MHV) | 3 weeks, study termination
Mouse norovirus (MNV) | 3 weeks, study termination
Mouse parvovirus (MPV) | 3 weeks, study termination
Minute virus of mice (MVM) | 3 weeks, study termination
Parvo NS-1 | 3 weeks, study termination
PVM | 3 weeks, study termination
Reovirus 3 (REO) | 3 weeks, study termination
Theiler’s murine encephalomyelitis virus — mouse poliovirus, strain GDVII (TMEV GDVII) | 3 weeks, study termination
Sendai | 3 weeks, study termination
Two-year Study
Multiplex Fluorescent Immunoassay
Ectromelia virus | 3 weeks, 6, 12, and 18 months, study termination
EDIM | 3 weeks, 6, 12, and 18 months, study termination
LCMV | 3 weeks, 6, 12, and 18 months, study termination
M. pulmonis | 3 weeks, 6, 12, and 18 months, study termination
MHV | 3 weeks, 6, 12, and 18 months, study termination
MNV | 3 weeks, 6, 12, and 18 months, study termination
MPV | 3 weeks, 6, 12, and 18 months, study termination
MVM | 3 weeks, 6, 12, and 18 months, study termination
Parvo NS-1 | 3 weeks, 6, 12, and 18 months, study termination
PVM | 3 weeks, 6, 12, and 18 months, study termination
REO | 3 weeks, 6, 12, and 18 months, study termination
TMEV GDVII | 3 weeks, 6, 12, and 18 months, study termination
Sendai | 3 weeks, 6, 12, and 18 months, study termination
Immunofluorescence Assay
Sendai | 18 months
Polymerase Chain Reaction
Helicobacter species | 18 months

## K.2 Results

All test results were negative.