# Appendix J Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table J-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table J-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU | –
Niacin | 23 mg | –
Folic acid | 1.1 mg | –
α-Pantothenic acid | 10 mg | α-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table J-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.7 ± 0.53 | 13.9–16.5 | 29
Crude fat (% by weight) | 8.6 ± 0.33 | 8.0–9.2 | 29
Crude fiber (% by weight) | 9.6 ± 0.61 | 8.4–11.1 | 29
Ash (% by weight) | 4.9 ± 0.13 | 4.7–5.2 | 29
Amino Acids (% of total diet)
Arginine | 0.794 ± 0.070 | 0.67–0.97 | 26
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 26
Glycine | 0.700 ± 0.038 | 0.62–0.80 | 26
Histidine | 0.344 ± 0.074 | 0.27–0.68 | 26
Isoleucine | 0.546 ± 0.041 | 0.43–0.66 | 26
Leucine | 1.092 ± 0.063 | 0.96–1.24 | 26
Lysine | 0.700 ± 0.110 | 0.31–0.86 | 26
Methionine | 0.408 ± 0.043 | 0.26–0.49 | 26
Phenylalanine | 0.621 ± 0.048 | 0.47–0.72 | 26
Threonine | 0.508 ± 0.040 | 0.43–0.61 | 26
Tryptophan | 0.153 ± 0.028 | 0.11–0.20 | 26
Tyrosine | 0.413 ± 0.063 | 0.28–0.54 | 26
Valine | 0.663 ± 0.040 | 0.55–0.73 | 26
Essential Fatty Acids (% of total diet)
Linoleic | 3.92 ± 0.307 | 2.99–4.55 | 26
Linolenic | 0.31 ± 0.030 | 0.21–0.35 | 26
Vitamins
Vitamin A (IU/kg) | 3,766 ± 66 | 2,110–5,450 | 29
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 77 ± 24.82 | 7.81–124.0 | 26
Thiamine (ppm)^b^ | 8.3 ± 1.50 | 6.4–12.3 | 29
Riboflavin (ppm) | 8.1 ± 2.91 | 4.20–17.50 | 26
Niacin (ppm) | 78.9 ± 8.52 | 66.4–98.2 | 26
Pantothenic acid (ppm) | 26.7 ± 11.63 | 17.4–81.0 | 26
Pyridoxine (ppm)^b^ | 9.7 ± 2.09 | 6.44–14.3 | 26
Folic acid (ppm) | 1.59 ± 0.45 | 1.15–3.27 | 26
Biotin (ppm) | 0.32 ± 0.10 | 0.20–0.704 | 26
Vitamin B_12_ (ppb) | 54.9 ± 37.2 | 18.3–174.0 | 26
Choline (ppm)^b^ | 2,665 ± 631 | 1,160–3,790 | 26
Minerals
Calcium (%) | 0.892 ± 0.038 | 0.810–0.973 | 29
Phosphorus (%) | 0.558 ± 0.020 | 0.520–0.594 | 29
Potassium (%) | 0.669 ± 0.030 | 0.626–0.733 | 26
Chloride (%) | 0.386 ± 0.037 | 0.300–0.474 | 26
Sodium (%) | 0.193 ± 0.024 | 0.160–0.283 | 26
Magnesium (%) | 0.216 ± 0.057 | 0.185–0.490 | 26
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 190.5 ± 38.0 | 135–311 | 26
Manganese (ppm) | 50.7 ± 9.72 | 21.0–73.1 | 26
Zinc (ppm) | 58.2 ± 26.89 | 43.3–184.0 | 26
Copper (ppm) | 7.44 ± 2.60 | 3.21–16.3 | 26
Iodine (ppm) | 0.514 ± 0.195 | 0.158–0.972 | 26
Chromium (ppm) | 0.674 ± 0.265 | 0.330–1.380 | 26
Cobalt (ppm) | 0.235 ± 0.157 | 0.094–0.864 | 26

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table J-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.21 ± 0.052 | 0.15–0.42 | 29
Cadmium (ppm) | 0.07 ± 0.084 | 0.015–0.50 | 29
Lead (ppm) | 0.2 ± 0.252 | 0.06–1.19 | 29
Mercury (ppm) | <0.02 | – | 29
Selenium (ppm) | 0.17 ± 0.057 | 0.029–0.34 | 29
Aflatoxins (ppb) | <5.00 | – | 29
Nitrate nitrogen (ppm)^c^ | 15.48 ± 6.051 | 10.0–28.0 | 29
Nitrite nitrogen (ppm)^c^ | 0.61 | – | 29
BHA (ppm)^d^ | <1.0 | – | 29
BHT (ppm)^d^ | <1.0 | – | 29
Aerobic plate count (CFU/g) | 15.86 ± 29.70 | 10–170 | 29
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0–3.0 | 29
Escherichia coli (MPN/g) | <10 | – | 29
Salmonella (MPN/g) | Negative | – | 29
Total nitrosoamines (ppb)^e^ | 10.22 ± 4.99 | 1.6–19.9 | 29
N-Nitrosodimethylamine (ppb)^e^ | 2.4 ± 1.61 | 0.0–7.4 | 29
N-Nitrosopyrrolidine (ppb)^e^ | 7.99 ± 4.82 | 1.01–18.6 | 29
Pesticides (ppm)
α-BHC | <0.01 | – | 29
β-BHC | <0.02 | – | 29
γ-BHC | <0.01 | – | 29
δ-BHC | <0.01 | – | 29
Heptachlor | <0.01 | – | 29
Aldrin | <0.01 | – | 29
Heptachlor epoxide | <0.01 | – | 29
DDE | <0.01 | – | 29
DDD | <0.01 | – | 29
DDT | <0.01 | – | 29
HCB | <0.01 | – | 29
Mirex | <0.01 | – | 29
Methoxychlor | <0.05 | – | 29
Dieldrin | <0.01 | – | 29
Endrin | <0.01 | – | 29
Telodrin | <0.01 | – | 29
Chlordane | <0.05 | – | 29
Toxaphene | <0.10 | – | 29
Estimated PCBs | <0.20 | – | 29
Ronnel | <0.01 | – | 29
Ethion | <0.02 | – | 29
Trithion | <0.05 | – | 29
Diazinon | <0.10 | – | 29
Methyl chlorpyrifos | 0.137 ± 0.131 | 0.020–0.553 | 29
Methyl parathion | <0.02 | – | 29
Ethyl parathion | <0.02 | – | 29
Malathion | 0.101 ± 0.102 | 0.020–0.395 | 29
Endosulfan I | <0.01 | – | 29
Endosulfan II | <0.01 | – | 29
Endosulfan sulfate | <0.03 | – | 29

^a^ All samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.