# Appendix I Chemical Characterization and Generation of Chamber Concentrations

## I.1 Procurement and Characterization of p-Chloro-α,α,α-trifluorotoluene

p-Chloro-α,α,α-trifluorotoluene was obtained from Special Materials Company (Cherry Hill, NJ, and New York, NY) in two lots. Lot 2009-01-05 was used in the 3-month studies and lot 2010-05-24 was used in the 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the p-chloro-α,α,α-trifluorotoluene studies are on file at the National Institute of Environmental Health Sciences.

Both lots were clear liquid, were identified as p-chloro-α,α,α-trifluorotoluene by the analytical chemistry laboratory using proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using Fourier transform infrared (FTIR) spectroscopy. NMR spectra were consistent with a p-chloro-α,α,α-trifluorotoluene standard (Sigma Aldrich, Lot 08507BO) and the structure of p-chloro-α,α,α-trifluorotoluene. FTIR spectra were consistent with the literature spectra^99^ and the structure of p-chloro-α,α,α-trifluorotoluene. FTIR and proton NMR spectra are presented in Figure I-1 and Figure I-2, respectively.

For lots 2009-01-05 and 2010-05-24, the analytical chemistry laboratory determined the water content using Karl Fischer titration, conducted elemental analyses to determine the carbon and hydrogen content, and for lot 2010-05-24, determined the sulfur content using inductively coupled plasma (ICP) spectroscopy. The purity was determined by the study laboratory using gas chromatography (GC) with flame ionization detection (FID). The presence of 3,4-dihydroxybenzoic acid was determined using high performance liquid chromatography (HPLC) with an ultraviolet light/visible light detector. The HPLC system consisted of an Agilent Zorbax Eclipse XDB-Phenyl column (4.6 mm × 150 mm), with monitoring at 240 nm, and mobile phases of water:methanol (10:90, 10:90, 0:100, and 10:90) with a flow rate of 1 mL/minute.

Karl Fischer titration indicated a water content of 82.4 (lot 2009-01-05) or 109.8 (lot 2010-05-24) ppm. Elemental analyses of both lots for carbon and hydrogen were consistent with theoretical values. ICP analysis of lot 2010-05-24 indicated <0.002% sulfur. GC/FID by system A (Table I-1), relative to an independent standard purchased from Aldrich Chemical Co. (St. Louis, MO), indicated a relative purity of 100.3% (lot 2009-01-05) or 99.6% (lot 2010-05-24). GC/FID by system B indicated one major peak (peak area percents of 99.68% for lot 2009-01-05, 99.57% for lot 2010-05-24) and two impurities with areas ≥0.1% relative to the major peak area: 3-chlorobenzotrifluoride (0.2%, lot 2009-01-05; 0.3%, lot 2010-05-24) and 2-chlorobenzotrifluoride (0.1%, lot 2009-01-05; 0.2%, lot 2010-05-24). No 3,4-dihydroxybenzoic acid was detected by HPLC. The overall purity of each lot was determined to be greater than 99.5%.

The bulk chemical was stored in the original shipping containers at room temperature. To ensure stability, periodic reanalyses of the bulk chemical were performed during the 3-month and 2-year studies by the study laboratory using the same GC/FID (systems A and B) assays used in the initial bulk chemical purity assays, and no degradation of the bulk chemical was detected.

## I.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure I-3. p-Chloro-α,α,α-trifluorotoluene was pumped from a stainless steel 8 gallon reservoir into a heated vaporizer glass column filled with glass beads and completely wrapped with heat tape. A waste collection flask was connected to the bottom of the column to collect residual chemical not completely vaporized in the generator column. Preheated nitrogen entered the column from below, vaporized the chemical, and carried the vapor from the generator cabinet to the distribution manifold through a heated chemical transport line. The nitrogen-chemical mixture was diluted with heated air before entering the distribution manifold. Concentration in the manifold was determined by the chemical pump rate, dilution air flow rates, and nitrogen flow rate. Pressure in the distribution manifold was kept fixed to ensure constant flows through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Individual heated (approximately 130°F) Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the p-chloro-α,α,α-trifluorotoluene vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration. Conditioned air was defined as the mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature of the resultant mixture of air was adjusted by passage over a temperature-controlled radiator after sequential treatment with Purafil, charcoal, and HEPA filters. Target dewpoint temperatures of the wet and dry ducts were 60° and 40°F, respectively. Air for the ducts was obtained from the building air supply and was either passed over chillers to lower the dewpoint (dry duct) or injected with steam to raise it (wet duct).

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc., Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI, Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that p-chloro-α,α,α-trifluorotoluene vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## I.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table I-2 and Table I-3. Chamber and room concentrations of p-chloro-α,α,α-trifluorotoluene were monitored by an on-line gas chromatograph (system C, Table I-1). Samples were drawn from each exposure chamber approximately every 20 minutes for the 3-month and 2-year studies during each 6-hour exposure period using Hastelloy^®^-C stream-select and gas-sampling valves (VALCO Instruments Company, Houston, TX) in a separate, heated oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout each exposure day for instrument drift against an on-line standard vapor of 4-chlorotoluene in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples collected with sorbent tubes (ORBO^™^-52; Supelco Inc., Bellefonte, PA), extracted with toluene containing an internal standard of 4-chlorotoluene and analyzed using an off-line gas chromatograph equipped with a FID (system D). Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standard solutions of the test chemical containing 4-chlorotoluene as an internal standard in toluene.

## I.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.2 minutes. For rats and mice in the 3-month studies, T_90_ values ranged from 8 to 15 minutes without animals present and from 10 to 15 minutes with animals; T_10_ values were 8 to 11 minutes without animals present and 9 to 12 minutes with animals. For rats and mice in the 2-year studies, T_90_ values ranged from 9 to 10 minutes without animals present and from 10 to 12 minutes with animals; T_10_ values ranged from 9 to 10 minutes without animals present and from 11 to 13 minutes with animals. A T_90_ value of 15 minutes was selected for the 3-month studies, and a T_90_ value of 12 minutes was selected for the 2-year studies.

The uniformity of p-chloro-α,α,α-trifluorotoluene vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 3-month studies and approximately every 3 months during the 2-year studies. The vapor concentration was measured using the on-line gas chromatograph (system C, Table I-1) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Prior to the 3-month and 2-year studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. During the 3-month and 2-year studies, concentrations were measured at the regular monitoring port and from sample ports at levels where animals were present. Chamber concentration uniformity was maintained throughout the studies.

The persistence of p-chloro-α,α,α-trifluorotoluene in the chambers after vapor delivery ended was determined by monitoring the vapor concentration in the 2,000 ppm chambers in the 3-month studies and the 1,000 ppm rat and 400 ppm mouse chambers in the 2-year studies with and without animals present in the chambers. In the 3-month studies, the concentration decreased to 1% of the target concentration within 24 minutes without animals present and within 30 minutes with animals present. For the 2-year rat studies, the concentration decreased to 1% of the target concentration within 24 minutes without animals present and within 46 minutes with animals present. For the 2-year mouse studies, the concentration decreased to 1% of the target concentration within 23 minutes without animals present and within 31 minutes with animals present.

Samples of the test atmosphere from the distribution lines and the low and high exposure concentration chambers for each species were collected prior to the study without animals present and at the beginning and end of one generation day with animals present during the 3-month and 2-year studies. The atmosphere samples were collected with adsorbent gas sampling tubes containing silica gel (ORBO^™^-52; Supelco, Inc.) followed by a tube containing activated coconut charcoal (ORBO^™^-32), and extracted with methylene chloride. Additional samples were collected from the generator reservoir, and all of the samples were analyzed using GC/FID by system B to measure the stability and purity of p-chloro-α,α,α-trifluorotoluene in the generation and delivery system. To assess whether impurities or degradation products co-eluted with p-chloro-α,α,α-trifluorotoluene or the solvent, a second GC/FID analysis of samples from the distribution line, 125 ppm and 2,000 ppm chambers (3-month studies), 100 ppm and 1,000 ppm rat chambers (2-year studies), 100 ppm and 400 ppm mouse chambers (2-year studies), and the generator reservoir was performed using system B. 3,4-Dihydroxybenzoic acid was measured in atmosphere samples collected in ORBO^™^-52 tubes followed by ORBO^™^-32 tubes prior to and during the 3-month and 2-year studies.

No evidence of degradation of p-chloro-α,α,α-trifluorotoluene was noted in any part of the exposure system in any of the samples collected prior to or during the 3-month and 2-year studies. During the 3-month studies, 3-chlorobenzotrifluoride (0.2%) was the only impurity detected in atmosphere or generator reservoir samples with an area greater than 0.1% of the total peak area. During the 2-year studies, 3-chlorobenzotrifluoride (0.3%) and 2-chlorobenzotrifluoride (0.2%) were the only impurities detected in the atmosphere or generator reservoir samples with areas greater than 0.1% of the total peak area. No 3,4-dihydroxybenzoic acid was detected in the exposure chamber atmosphere samples at ≥ 0.1%.

Table I-1 Gas Chromatography Systems Used in the Inhalation Studies of p-Chloro-α,α,α-trifluorotoluene^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-WAXETR, 30 m × 530 µm, 1 µm film (J&W Scientific, Folsom, CA) | Helium at 6 psi head pressure | 40°C for 1 minute, then 10°C/minute to 120°C, then 25°C/minute to 230°C
System B
Flame ionization | DB-5MS UI, 30 m × 250 µm, 0.25 µm film (J&W Scientific) | Helium at 12 psi head pressure | 40°C for 4 minutes, then 8°C/minute to 260°C, held for 5 minutes
System C
Flame ionization | Rtx^®^-5, 15 m × 0.53 mm, 1.5 µm film (Restek, Bellefonte, PA) | Nitrogen at 25 mL/minute | Isothermal at 80°C
System D
Flame ionization | DB-WAXETR, 30 m × 530 µm, 1 µm film (J&W Scientific) | Helium at 6 psi head pressure | 80°C for 5 minutes, then 10°C/minute to 120°C, then 25°C/minute to 230°C, held for 1 minute

^a^ The gas chromatographs were manufactured by Hewlett-Packard (Palo Alto, CA).

Table I-2 Summary of Chamber Concentrations in the Three-month Inhalation Studies of p-Chloro-α,α,α-trifluorotoluene

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 125 | 1,196 | 124.6 ± 2.9
| 250 | 1,199 | 249.9 ± 5.0
| 500 | 1,202 | 495.4 ± 11.8
| 1,000 | 1,203 | 996.2 ± 21.0
| 2,000 | 1,215 | 1,984.9 ± 41.2
Mouse Chambers
| 125 | 1,233 | 124.6 ± 2.9
| 250 | 1,236 | 250.0 ± 5.0
| 500 | 1,239 | 495.2 ± 11.8
| 1,000 | 1,240 | 996.2 ± 21.0
| 2,000 | 1,252 | 1,984.4 ± 40.9

^a^ Mean ± standard deviation.

Table I-3 Summary of Chamber Concentrations in the Two-year Inhalation Studies of p-Chloro-α,α,α-trifluorotoluene

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 100 | 7,905 | 100 ± 2
| 300 | 7,967 | 300 ± 4
| 1,000 | 8,031 | 999 ± 15
Mouse Chambers
| 100 | 8,081 | 100 ± 3
| 200 | 7,718 | 201 ± 3
| 400 | 7,841 | 401 ± 7

^a^ Mean ± standard deviation.

Figure I-1

Fourier Transform Infrared Absorption Spectrum of p-Chloro-α,α,α-trifluorotoluene

Figure I-2

Proton Nuclear Magnetic Resonance Spectrum of p-Chloro-α,α,α-trifluorotoluene

Figure I-3

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of p-Chloro-α,α,α-trifluorotoluene