# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 393 ± 7 | 412 ± 11 | 401 ± 7 | 376 ± 6
L. Cauda epididymis | 0.273 ± 0.0146 | 0.283 ± 0.0066 | 0.256 ± 0.0065 | 0.212 ± 0.0065**
L. Epididymis | 0.648 ± 0.0280 | 0.669 ± 0.0147 | 0.625 ± 0.0164 | 0.555 ± 0.0128**
L. Testis | 1.920 ± 0.0896 | 2.069 ± 0.0361 | 1.976 ± 0.0503 | 1.978 ± 0.0233
Spermatid measurements
Spermatid heads (10^6^/testis) | 270.92 ± 22.197 | 303.18 ± 19.790 | 263.56 ± 10.265 | 265.95 ± 13.848
Spermatid heads (10^6^/g testis) | 138.97 ± 7.762 | 146.82 ± 10.025 | 133.51 ± 4.364 | 134.67 ± 7.351
Epididymal spermatozoal measurements
Sperm motility (%) | 76.9 ± 3.06 | 74.9 ± 3.33 | 68.7 ± 1.51* | 68.4 ± 1.67*
Sperm (10^6^/cauda epididymis) | 158.6 ± 7.14 | 164.8 ± 9.11 | 144.0 ± 10.22 | 123.6 ± 5.62**
Sperm (10^6^/g cauda epididymis) | 587.5 ± 21.28 | 582.3 ± 30.21 | 562.7 ± 37.98 | 583.2 ± 23.31

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (left cauda epididymis and left epididymis weights) or Shirley’s test (sperm/cauda epididymis).

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (body and left testis weights) or Dunn’s test (spermatid measurements and sperm/g cauda epididymis).

Table H-2 Estrous Cycle Characterization for Female Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 9
Necropsy body wt (g) | 240 ± 5 | 259 ± 5* | 267 ± 9** | 294 ± 8**
Number of estrous cycles | 2.2 ± 0.25 | 2.0 ± 0.26 | 1.9 ± 0.18 | 1.3 ± 0.33^b^
Estrous cycle length (days) | 5.5 ± 0.87 | 4.6 ± 0.22 | 4.7 ± 0.11 | 4.3 ± 0.33^b^
Estrous stages (% of cycle)^b^
Diestrus | 55.0 | 53.1 | 48.1 | 78.5
Proestrus | 10.6 | 5.6 | 7.5 | 0.7
Estrus | 33.8 | 37.5 | 42.5 | 14.6
Metestrus | 0.0 | 3.1 | 1.9 | 6.3

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (estrous cycle number and length). Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated that 2,000 ppm females spent significantly more time in extended diestrus (P < 0.001) than the chamber control group.

^b^ Estrous cyclicity samples were evaluated for 9 females exposed to 2,000 ppm; however, in 6 of 9 animals estrous cycles were longer than 16 days or unclear and were not included in these analyses.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months

Stage | Comparison | P value | Trend^a^
Overall Tests | Overall | <0.001 | –
Overall Tests | 500 ppm vs. Chamber Controls | 0.722 | –
Overall Tests | 1,000 ppm vs. Chamber Controls | 0.91 | –
Overall Tests | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | Overall | 0.008 | –
Extended Estrus | 500 ppm vs. Chamber Controls | 0.315 | –
Extended Estrus | 1,000 ppm vs. Chamber Controls | 0.064 | –
Extended Estrus | 2,000 ppm vs. Chamber Controls | 0.008 | N
Extended Diestrus | Overall | <0.001 | –
Extended Diestrus | 500 ppm vs. Chamber Controls | 0.233 | N
Extended Diestrus | 1,000 ppm vs. Chamber Controls | 0.498 | N
Extended Diestrus | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Metestrus | Overall | 0.917 | –
Extended Metestrus | 500 ppm vs. Chamber Controls | 1 | –
Extended Metestrus | 1,000 ppm vs. Chamber Controls | 1 | –
Extended Metestrus | 2,000 ppm vs. Chamber Controls | 0.362 | –
Extended Proestrus | Overall | 1 | –
Extended Proestrus | 500 ppm vs. Chamber Controls | 1 | –
Extended Proestrus | 1,000 ppm vs. Chamber Controls | 1 | –
Extended Proestrus | 2,000 ppm vs. Chamber Controls | 1 | –
Skipped Estrus | Overall | 0.216 | –
Skipped Estrus | 500 ppm vs. Chamber Controls | 0.154 | N
Skipped Estrus | 1,000 ppm vs. Chamber Controls | 0.152 | N
Skipped Estrus | 2,000 ppm vs. Chamber Controls | 0.539 | N
Skipped Diestrus | Overall | 1 | –
Skipped Diestrus | 500 ppm vs. Chamber Controls | 1 | –
Skipped Diestrus | 1,000 ppm vs. Chamber Controls | 1 | –
Skipped Diestrus | 2,000 ppm vs. Chamber Controls | 1 | –
Summary of Significant Groups
Overall Tests | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | 2,000 ppm vs. Chamber Controls | 0.008 | N
Extended Diestrus | 2,000 ppm vs. Chamber Controls | <0.001 | –

^a^ N indicates that the exposed group had fewer departures from normal than did the chamber control group. Having no N indicates that the exposed group had more departures from normal than did the chamber control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 33.9 ± 0.59 | 36.9 ± 0.81** | 38.6 ± 0.83** | 36.8 ± 0.37**
L. Cauda epididymis | 0.017 ± 0.0006 | 0.019 ± 0.0011 | 0.018 ± 0.0005 | 0.021 ± 0.0023
L. Epididymis | 0.042 ± 0.0009 | 0.044 ± 0.0012 | 0.045 ± 0.0018 | 0.044 ± 0.0017
L. Testis | 0.103 ± 0.0020 | 0.108 ± 0.0015 | 0.104 ± 0.0041 | 0.103 ± 0.0017
Spermatid measurements
Spermatid heads (10^6^/testis) | 19.72 ± 1.004 | 22.31 ± 0.656 | 19.99 ± 1.324 | 17.72 ± 1.321
Spermatid heads (10^6^/g testis) | 191.87 ± 8.230 | 206.29 ± 7.450 | 192.82 ± 11.952 | 172.12 ± 12.644
Epididymal spermatozoal measurements
Sperm motility (%) | 79.9 ± 0.89 | 67.1 ± 3.33** | 63.2 ± 1.42** | 60.1 ± 1.31**
Sperm (10^6^/cauda epididymis) | 11.3 ± 0.55 | 14.8 ± 0.66* | 14.2 ± 1.29 | 15.0 ± 1.15*
Sperm (10^6^/g cauda epididymis) | 679.0 ± 33.92 | 787.8 ± 37.63 | 794.9 ± 58.81 | 779.1 ± 65.92

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body weights) or Shirley’s test (sperm motility).

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid measurements and sperm/g cauda epididymis).

Table H-5 Estrous Cycle Characterization for Female Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 28.2 ± 0.41 | 32.2 ± 0.72** | 33.7 ± 0.79** | 29.7 ± 0.74**
Number of estrous cycles | 2.5 ± 0.22 | 2.2 ± 0.20 | 2.2 ± 0.13 | 2.4 ± 0.22
Estrous cycle length (days) | 4.1 ± 0.10 | 4.5 ± 0.16 | 4.6 ± 0.14* | 5.3 ± 0.65**
Estrous stages (% of cycle)
Diestrus | 36.9 | 32.5 | 28.8 | 30.0
Proestrus | 0.0 | 2.5 | 4.4 | 6.9
Estrus | 47.5 | 48.1 | 44.4 | 45.0
Metestrus | 15.6 | 16.3 | 21.3 | 16.9

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body weights) or Dunn’s test (estrous cycle length).

^a^ Necropsy body weights, number of estrous cycles, and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (number of estrous cycles). Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated that all exposed groups spent significantly more time in extended estrus (P ≤ 0.001) than the chamber control group.

Table H-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Exposed to p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months

Stage | Comparison | P value | Trend^a^
Overall Tests | Overall | <0.001 | –
Overall Tests | 500 ppm vs. Chamber Controls | <0.001 | –
Overall Tests | 1,000 ppm vs. Chamber Controls | <0.001 | –
Overall Tests | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | Overall | <0.001 | –
Extended Estrus | 500 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | 1,000 ppm vs. Chamber Controls | 0.001 | –
Extended Estrus | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Diestrus | Overall | 0.091 | –
Extended Diestrus | 500 ppm vs. Chamber Controls | 0.311 | –
Extended Diestrus | 1,000 ppm vs. Chamber Controls | 0.223 | –
Extended Diestrus | 2,000 ppm vs. Chamber Controls | 0.061 | –
Extended Metestrus | Overall | 0.174 | –
Extended Metestrus | 500 ppm vs. Chamber Controls | 0.223 | –
Extended Metestrus | 1,000 ppm vs. Chamber Controls | 0.082 | –
Extended Metestrus | 2,000 ppm vs. Chamber Controls | 0.607 | –
Extended Proestrus | Overall | 1 | –
Extended Proestrus | 500 ppm vs. Chamber Controls | 1 | –
Extended Proestrus | 1,000 ppm vs. Chamber Controls | 1 | –
Extended Proestrus | 2,000 ppm vs. Chamber Controls | 1 | –
Skipped Estrus | Overall | 0.998 | –
Skipped Estrus | 500 ppm vs. Chamber Controls | 1 | –
Skipped Estrus | 1,000 ppm vs. Chamber Controls | 0.934 | –
Skipped Estrus | 2,000 ppm vs. Chamber Controls | 0.869 | –
Skipped Diestrus | Overall | 0.988 | –
Skipped Diestrus | 500 ppm vs. Chamber Controls | 0.805 | –
Skipped Diestrus | 1,000 ppm vs. Chamber Controls | 0.934 | –
Skipped Diestrus | 2,000 ppm vs. Chamber Controls | 0.804 | –
Summary of Significant Groups
Overall Tests | 500 ppm vs. Chamber Controls | <0.001 | –
Overall Tests | 1,000 ppm vs. Chamber Controls | <0.001 | –
Overall Tests | 2,000 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | 500 ppm vs. Chamber Controls | <0.001 | –
Extended Estrus | 1,000 ppm vs. Chamber Controls | 0.001 | –
Extended Estrus | 2,000 ppm vs. Chamber Controls | <0.001 | –

^a^ N indicates that the exposed group had fewer departures from normal than did the chamber control group. Having no N indicates that the exposed group had more departures from normal than did the chamber control group.

Figure H-1

Vaginal Cytology Plots for Female Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

I = insufficient number of cells to determine stage, D = diestrus, P = proestrus, E = estrus, M = metestrus.

Figure H-2

Vaginal Cytology Plots for Female Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

I = insufficient number of cells to determine stage, D = diestrus, P = proestrus, E = estrus, M = metestrus.