# Appendix G Organ Weights and Organ-Weight-to-Body Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 393 ± 7 | 426 ± 5* | 414 ± 11 | 412 ± 11 | 401 ± 7 | 376 ± 6
Heart
Absolute | 1.32 ± 0.03 | 1.48 ± 0.03* | 1.41 ± 0.04 | 1.40 ± 0.04 | 1.37 ± 0.04 | 1.34 ± 0.03
Relative | 3.36 ± 0.04 | 3.47 ± 0.05 | 3.41 ± 0.08 | 3.40 ± 0.06 | 3.41 ± 0.07 | 3.56 ± 0.08
R. Kidney
Absolute | 1.28 ± 0.04 | 1.46 ± 0.02** | 1.48 ± 0.03** | 1.57 ± 0.04** | 1.61 ± 0.04** | 1.58 ± 0.06**
Relative | 3.24 ± 0.05 | 3.44 ± 0.06 | 3.57 ± 0.06** | 3.82 ± 0.07** | 4.00 ± 0.05** | 4.20 ± 0.14**
Liver
Absolute | 12.22 ± 0.38 | 13.74 ± 0.21* | 14.41 ± 0.56** | 16.56 ± 0.65** | 19.34 ± 0.49** | 22.02 ± 0.69**
Relative | 31.03 ± 0.56 | 32.32 ± 0.50 | 34.79 ± 0.83** | 40.18 ± 1.10** | 48.25 ± 1.26** | 58.48 ± 1.29**
Lung
Absolute | 2.05 ± 0.07 | 2.30 ± 0.08 | 2.04 ± 0.06 | 2.17 ± 0.07 | 2.27 ± 0.10 | 2.22 ± 0.15
Relative | 5.23 ± 0.18 | 5.41 ± 0.18 | 4.94 ± 0.12 | 5.26 ± 0.12 | 5.65 ± 0.23 | 5.93 ± 0.43
R. Testis
Absolute | 1.800 ± 0.173 | 2.020 ± 0.015 | 1.991 ± 0.039 | 1.922 ± 0.138 | 2.055 ± 0.046 | 1.999 ± 0.029
Relative | 4.564 ± 0.427 | 4.751 ± 0.048 | 4.830 ± 0.114 | 4.717 ± 0.373 | 5.124 ± 0.106 | 5.328 ± 0.108*
Thymus
Absolute | 0.309 ± 0.024 | 0.369 ± 0.027 | 0.342 ± 0.030 | 0.351 ± 0.031 | 0.312 ± 0.022 | 0.305 ± 0.024
Relative | 0.788 ± 0.061 | 0.865 ± 0.060 | 0.817 ± 0.051 | 0.845 ± 0.056 | 0.778 ± 0.051 | 0.809 ± 0.060
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy body wt | 240 ± 5 | 249 ± 5 | 255 ± 6 | 259 ± 5* | 267 ± 9** | 294 ± 8**
Heart
Absolute | 0.91 ± 0.02 | 0.96 ± 0.02 | 0.97 ± 0.02 | 0.99 ± 0.03* | 1.00 ± 0.03* | 1.10 ± 0.02**
Relative | 3.79 ± 0.06 | 3.86 ± 0.10 | 3.79 ± 0.05 | 3.84 ± 0.08 | 3.75 ± 0.08 | 3.75 ± 0.11
R. Kidney
Absolute | 0.84 ± 0.01 | 0.89 ± 0.02 | 0.94 ± 0.03* | 0.94 ± 0.02* | 0.94 ± 0.04* | 1.06 ± 0.03**
Relative | 3.51 ± 0.05 | 3.58 ± 0.05 | 3.67 ± 0.06 | 3.64 ± 0.06 | 3.50 ± 0.07 | 3.62 ± 0.08
Liver
Absolute | 7.07 ± 0.19 | 7.47 ± 0.26 | 7.93 ± 0.21 | 8.82 ± 0.23** | 11.10 ± 0.51** | 16.95 ± 0.52**
Relative | 29.50 ± 0.39 | 30.00 ± 0.72 | 31.15 ± 0.48 | 34.05 ± 0.51** | 41.58 ± 1.27** | 57.75 ± 1.47**
Lung
Absolute | 1.73 ± 0.05 | 1.83 ± 0.06 | 1.83 ± 0.08 | 1.86 ± 0.06 | 1.90 ± 0.10 | 2.01 ± 0.15
Relative | 7.24 ± 0.31 | 7.38 ± 0.23 | 7.22 ± 0.30 | 7.18 ± 0.21 | 7.15 ± 0.35 | 6.85 ± 0.53
Thymus
Absolute | 0.254 ± 0.012 | 0.258 ± 0.013 | 0.265 ± 0.014 | 0.241 ± 0.017 | 0.257 ± 0.015 | 0.238 ± 0.020
Relative | 1.062 ± 0.049 | 1.037 ± 0.049 | 1.038 ± 0.049 | 0.925 ± 0.056 | 0.964 ± 0.050 | 0.804 ± 0.059**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by William’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 33.9 ± 0.6 | 34.2 ± 1.0 | 35.8 ± 0.9 | 36.9 ± 0.8** | 38.6 ± 0.8** | 36.8 ± 0.4**
Heart
Absolute | 0.15 ± 0.00 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01* | 0.17 ± 0.01* | 0.16 ± 0.00*
Relative | 4.41 ± 0.08 | 4.60 ± 0.14 | 4.46 ± 0.09 | 4.50 ± 0.19 | 4.33 ± 0.10 | 4.43 ± 0.05
R. Kidney
Absolute | 0.29 ± 0.01 | 0.30 ± 0.01 | 0.31 ± 0.01 | 0.32 ± 0.01* | 0.36 ± 0.01** | 0.38 ± 0.01**
Relative | 8.65 ± 0.14 | 8.86 ± 0.19 | 8.74 ± 0.20 | 8.75 ± 0.23 | 9.36 ± 0.23* | 10.28 ± 0.22**
Liver
Absolute | 1.30 ± 0.04 | 1.44 ± 0.06 | 1.65 ± 0.07** | 2.09 ± 0.07** | 3.07 ± 0.07** | 3.60 ± 0.05**
Relative | 38.43 ± 0.87 | 42.11 ± 1.30 | 46.01 ± 1.36** | 56.73 ± 1.84** | 79.75 ± 1.16** | 97.85 ± 1.59**
Lung
Absolute | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.21 ± 0.01
Relative | 6.05 ± 0.10 | 6.10 ± 0.16 | 6.22 ± 0.22 | 6.21 ± 0.23 | 5.58 ± 0.10 | 5.58 ± 0.15
R. Testis
Absolute | 0.106 ± 0.003 | 0.111 ± 0.003 | 0.115 ± 0.003 | 0.114 ± 0.002 | 0.109 ± 0.004 | 0.109 ± 0.002
Relative | 3.134 ± 0.078 | 3.271 ± 0.109 | 3.223 ± 0.111 | 3.087 ± 0.078 | 2.834 ± 0.125 | 2.976 ± 0.067
Thymus
Absolute | 0.038 ± 0.002 | 0.041 ± 0.003 | 0.044 ± 0.002 | 0.043 ± 0.003 | 0.043 ± 0.002 | 0.032 ± 0.002
Relative | 1.121 ± 0.056 | 1.196 ± 0.074 | 1.242 ± 0.044 | 1.173 ± 0.065 | 1.108 ± 0.053 | 0.859 ± 0.053*
Female
Necropsy body wt | 28.2 ± 0.4 | 29.9 ± 0.8 | 31.0 ± 0.7** | 32.2 ± 0.7** | 33.7 ± 0.8** | 29.7 ± 0.7**
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.01 | 0.14 ± 0.00 | 0.14 ± 0.00
Relative | 4.87 ± 0.12 | 4.83 ± 0.09 | 4.70 ± 0.10 | 4.54 ± 0.13* | 4.26 ± 0.08** | 4.58 ± 0.07**
R. Kidney
Absolute | 0.20 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01* | 0.23 ± 0.01**
Relative | 6.97 ± 0.20 | 6.98 ± 0.13 | 7.01 ± 0.17 | 6.55 ± 0.17 | 6.48 ± 0.12 | 7.69 ± 0.29*
Liver
Absolute | 1.23 ± 0.05 | 1.33 ± 0.05 | 1.51 ± 0.05* | 1.81 ± 0.08** | 2.44 ± 0.08** | 2.61 ± 0.14**
Relative | 43.51 ± 1.66 | 44.28 ± 0.91 | 48.73 ± 0.79 | 56.18 ± 1.98** | 72.49 ± 1.95** | 87.58 ± 3.36**
Lung
Absolute | 0.22 ± 0.00 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.00
Relative | 7.68 ± 0.15 | 7.79 ± 0.21 | 7.34 ± 0.21 | 7.06 ± 0.15* | 6.70 ± 0.16* | 7.37 ± 0.21*
Thymus
Absolute | 0.055 ± 0.002 | 0.058 ± 0.001 | 0.060 ± 0.004 | 0.065 ± 0.003 | 0.062 ± 0.001 | 0.041 ± 0.004**
Relative | 1.956 ± 0.100 | 1.938 ± 0.054 | 1.925 ± 0.108 | 2.011 ± 0.068 | 1.858 ± 0.044 | 1.371 ± 0.102**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).