# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
Hematology
n | 10 | 9 | 10 | 10 | 10 | 10
Hematocrit (spun) (%) | 51.1 ± 0.5 | 50.8 ± 0.4 | 49.8 ± 0.4 | 49.6 ± 0.4 | 49.9 ± 0.4 | 50.7 ± 0.5
Packed cell volume (%) | 50.8 ± 0.6 | 50.3 ± 0.5 | 49.8 ± 0.4 | 49.2 ± 0.5 | 50.0 ± 0.5 | 50.8 ± 0.6
Hemoglobin (g/dL) | 16.0 ± 0.1 | 15.9 ± 0.2 | 15.7 ± 0.1 | 15.6 ± 0.1 | 15.6 ± 0.1 | 16.0 ± 0.2
Erythrocytes (10^6^/μL) | 8.92 ± 0.09 | 9.07 ± 0.08 | 8.88 ± 0.12 | 8.73 ± 0.09 | 8.67 ± 0.11 | 8.78 ± 0.11
Reticulocytes (10^3^/μL) | 229 ± 8 | 222 ± 5 | 220 ± 7 | 228 ± 6 | 235 ± 7 | 247 ± 9
Mean cell volume (fL) | 56.9 ± 0.4 | 55.5 ± 0.4 | 56.2 ± 0.5 | 56.4 ± 0.4 | 57.7 ± 0.4 | 57.9 ± 0.4
Mean cell hemoglobin (pg) | 18.0 ± 0.1 | 17.5 ± 0.2 | 17.7 ± 0.2 | 17.8 ± 0.1 | 18.0 ± 0.1 | 18.2 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 31.6 ± 0.2 | 31.5 ± 0.1 | 31.6 ± 0.2 | 31.6 ± 0.1 | 31.3 ± 0.1 | 31.5 ± 0.2
Platelets (10^3^/μL) | 813 ± 46 | 872 ± 27 | 846 ± 39 | 874 ± 45 | 831 ± 55 | 722 ± 42
Leukocytes (10^3^/μL) | 10.30 ± 0.56 | 11.18 ± 0.76 | 10.76 ± 0.40 | 11.97 ± 0.78 | 11.10 ± 0.81 | 7.70 ± 0.47
Segmented neutrophils (10^3^/μL) | 1.06 ± 0.04 | 1.27 ± 0.12 | 1.17 ± 0.10 | 1.41 ± 0.11** | 1.32 ± 0.05** | 1.66 ± 0.08**
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 8.73 ± 0.53 | 9.28 ± 0.70 | 9.09 ± 0.40 | 9.96 ± 0.69 | 9.05 ± 0.75 | 5.49 ± 0.42**
Monocytes (10^3^/μL) | 0.29 ± 0.02 | 0.37 ± 0.03 | 0.29 ± 0.02 | 0.35 ± 0.03 | 0.45 ± 0.05* | 0.38 ± 0.04
Basophils (10^3^/μL) | 0.030 ± 0.003 | 0.043 ± 0.005 | 0.040 ± 0.004 | 0.046 ± 0.006 | 0.052 ± 0.011 | 0.029 ± 0.004
Eosinophils (10^3^/μL) | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.01
Large unstained cells (10^3^/μL) | 0.094 ± 0.008 | 0.100 ± 0.008 | 0.099 ± 0.008 | 0.115 ± 0.011 | 0.131 ± 0.018 | 0.070 ± 0.006
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL) | 16.9 ± 0.8 | 14.5 ± 0.5 | 15.6 ± 0.6 | 17.0 ± 0.4 | 17.2 ± 0.6 | 18.4 ± 0.9
Creatinine (mg/dL) | 0.40 ± 0.02 | 0.39 ± 0.01 | 0.36 ± 0.02 | 0.35 ± 0.02 | 0.38 ± 0.01 | 0.45 ± 0.03
Glucose (mg/dL) | 117 ± 5 | 120 ± 5 | 114 ± 2 | 120 ± 6 | 114 ± 2 | 117 ± 6
Total protein (g/dL) | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.2 ± 0.1 | 7.4 ± 0.1 | 7.7 ± 0.1
Albumin (g/dL) | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.1 | 4.4 ± 0.1 | 4.4 ± 0.1 | 4.7 ± 0.1
Globulin (g/dL) | 2.7 ± 0.0 | 2.8 ± 0.1 | 2.8 ± 0.1 | 2.8 ± 0.1 | 3.0 ± 0.1** | 3.0 ± 0.1**
Albumin/globulin ratio | 1.7 ± 0.0 | 1.7 ± 0.0 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.5 ± 0.1** | 1.6 ± 0.0*
Cholesterol (mg/dL) | 132 ± 6 | 135 ± 4 | 137 ± 6 | 149 ± 5* | 182 ± 6** | 268 ± 15**
Triglycerides (mg/dL) | 71 ± 6 | 82 ± 5 | 74 ± 4 | 96 ± 8* | 118 ± 11** | 137 ± 6**
Alanine aminotransferase (IU/L) | 55 ± 2 | 53 ± 2 | 52 ± 2 | 52 ± 2 | 59 ± 3 | 73 ± 4*
Alkaline phosphatase (IU/L) | 165 ± 6 | 192 ± 9* | 229 ± 10** | 261 ± 15** | 238 ± 13** | 247 ± 17**
Creatine kinase (IU/L) | 247 ± 55 | 230 ± 55 | 158 ± 22 | 151 ± 18 | 143 ± 16 | 151 ± 15
Sorbitol dehydrogenase (IU/L) | 13 ± 1 | 12 ± 1 | 14 ± 1 | 15 ± 0 | 16 ± 1 | 18 ± 1**
Bile salts (µmol/L) | 22.4 ± 5.7 | 17.9 ± 3.8 | 8.5 ± 2.4 | 17.7 ± 3.3 | 11.1 ± 1.5 | 7.2 ± 1.1
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Hematology
Hematocrit (spun) (%) | 48.3 ± 0.3 | 47.0 ± 0.5 | 47.2 ± 0.4 | 47.5 ± 0.2 | 46.7 ± 0.7 | 46.9 ± 0.5
Packed cell volume (%) | 47.7 ± 0.6 | 46.8 ± 0.4 | 47.0 ± 0.5 | 46.9 ± 0.4 | 46.5 ± 0.6 | 46.9 ± 0.6
Hemoglobin (g/dL) | 15.3 ± 0.2 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.0 ± 0.1 | 14.9 ± 0.2 | 15.0 ± 0.1
Erythrocytes (10^6^/μL) | 8.19 ± 0.12 | 8.14 ± 0.07 | 8.14 ± 0.10 | 7.98 ± 0.09 | 7.87 ± 0.09 | 8.02 ± 0.08
Reticulocytes (10^3^/μL) | 234 ± 13 | 239 ± 13 | 255 ± 16 | 262 ± 15 | 241 ± 15 | 222 ± 14
Mean cell volume (fL) | 58.3 ± 0.4 | 57.4 ± 0.3 | 57.7 ± 0.3 | 58.8 ± 0.5 | 59.1 ± 0.6 | 58.5 ± 0.4
Mean cell hemoglobin (pg) | 18.7 ± 0.2 | 18.5 ± 0.1 | 18.5 ± 0.2 | 18.9 ± 0.2 | 19.0 ± 0.2 | 18.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.1 ± 0.2 | 32.3 ± 0.1 | 32.1 ± 0.2 | 32.1 ± 0.2 | 32.1 ± 0.1 | 32.0 ± 0.2
Platelets (10^3^/μL) | 840 ± 60^b^ | 823 ± 36 | 889 ± 35^b^ | 849 ± 71 | 866 ± 64 | 763 ± 42
Leukocytes (10^3^/μL) | 9.05 ± 0.81 | 7.75 ± 0.44 | 8.01 ± 0.39 | 10.03 ± 0.80 | 9.47 ± 0.69 | 5.96 ± 0.38*
Segmented neutrophils (10^3^/μL) | 1.05 ± 0.09 | 1.09 ± 0.10 | 1.31 ± 0.14 | 1.30 ± 0.06 | 1.17 ± 0.12 | 1.18 ± 0.07
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 7.51 ± 0.73 | 6.22 ± 0.33 | 6.24 ± 0.31 | 8.16 ± 0.72 | 7.83 ± 0.59 | 4.34 ± 0.29**
Monocytes (10^3^/μL) | 0.22 ± 0.02 | 0.22 ± 0.03 | 0.22 ± 0.02 | 0.28 ± 0.04 | 0.26 ± 0.03 | 0.26 ± 0.03
Basophils (10^3^/μL) | 0.036 ± 0.005 | 0.026 ± 0.003 | 0.032 ± 0.002 | 0.037 ± 0.006 | 0.031 ± 0.004 | 0.019 ± 0.003*
Eosinophils (10^3^/μL) | 0.14 ± 0.02 | 0.12 ± 0.02 | 0.14 ± 0.01 | 0.16 ± 0.02 | 0.09 ± 0.01 | 0.11 ± 0.01
Large unstained cells (10^3^/μL) | 0.082 ± 0.014 | 0.065 ± 0.007 | 0.068 ± 0.006 | 0.087 ± 0.011 | 0.078 ± 0.007 | 0.044 ± 0.005*
Clinical Chemistry
Urea nitrogen (mg/dL) | 15.8 ± 1.0 | 15.6 ± 0.6 | 15.8 ± 0.4 | 16.0 ± 0.5 | 14.0 ± 0.5 | 13.9 ± 0.8
Creatinine (mg/dL) | 0.40 ± 0.01 | 0.41 ± 0.01 | 0.42 ± 0.01 | 0.40 ± 0.00 | 0.39 ± 0.01 | 0.36 ± 0.05
Glucose (mg/dL) | 123 ± 3 | 131 ± 4 | 125 ± 3 | 116 ± 3 | 115 ± 2 | 124 ± 5
Total protein (g/dL) | 7.3 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.1 ± 0.1 | 7.5 ± 0.1 | 7.7 ± 0.1**
Albumin (g/dL) | 5.0 ± 0.1 | 4.9 ± 0.1 | 4.9 ± 0.1 | 4.8 ± 0.1 | 5.0 ± 0.1 | 4.9 ± 0.1
Globulin (g/dL) | 2.3 ± 0.1 | 2.1 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.5 ± 0.1 | 2.8 ± 0.1**
Albumin/globulin ratio | 2.2 ± 0.1 | 2.3 ± 0.1 | 2.2 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.0 | 1.8 ± 0.0**
Cholesterol (mg/dL) | 110 ± 6 | 117 ± 2 | 128 ± 3* | 141 ± 5** | 189 ± 6** | 261 ± 10**
Triglycerides (mg/dL) | 51 ± 4 | 53 ± 6 | 44 ± 4 | 58 ± 4 | 83 ± 5** | 115 ± 9**
Alanine aminotransferase (IU/L) | 49 ± 1 | 48 ± 2 | 48 ± 3 | 50 ± 1 | 51 ± 2 | 62 ± 4**
Alkaline phosphatase (IU/L) | 121 ± 6 | 147 ± 12 | 185 ± 10** | 201 ± 12** | 227 ± 12** | 216 ± 15**
Creatine kinase (IU/L) | 146 ± 9 | 173 ± 21 | 180 ± 22 | 134 ± 11 | 134 ± 19 | 221 ± 38
Sorbitol dehydrogenase (IU/L) | 11 ± 1 | 10 ± 0 | 12 ± 1 | 12 ± 0 | 13 ± 1 | 18 ± 2**
Bile salts (µmol/L) | 12.5 ± 5.5 | 16.0 ± 2.5 | 13.6 ± 4.0 | 33.8 ± 6.5** | 33.5 ± 6.0** | 14.7 ± 3.1**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table F-2 Hematology Data for Mice in the Three-month Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 125 ppm | 250 ppm | 500 ppm | 1,000 ppm | 2,000 ppm
Male
n | 10 | 10 | 10 | 9 | 10 | 10
Hematocrit (spun) (%) | 48.8 ± 0.3 | 49.7 ± 0.2 | 49.0 ± 0.1 | 48.6 ± 0.5 | 48.6 ± 0.4 | 46.4 ± 0.5**
Packed cell volume (%) | 46.1 ± 0.3 | 46.9 ± 0.3 | 46.0 ± 0.2 | 45.9 ± 0.4 | 46.1 ± 0.4 | 43.7 ± 0.4**
Hemoglobin (g/dL) | 16.2 ± 0.1 | 16.4 ± 0.1 | 16.2 ± 0.1 | 16.1 ± 0.1 | 16.0 ± 0.1 | 15.0 ± 0.1**
Erythrocytes (10^6^/µL) | 10.59 ± 0.05 | 10.81 ± 0.07 | 10.67 ± 0.05 | 10.52 ± 0.14 | 10.41 ± 0.04 | 9.80 ± 0.07**
Reticulocytes (10^3^/µL) | 296 ± 6 | 315 ± 5 | 285 ± 6 | 288 ± 13 | 264 ± 6** | 258 ± 8**
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 43.5 ± 0.2 | 43.4 ± 0.2 | 43.2 ± 0.2 | 43.6 ± 0.4 | 44.2 ± 0.4 | 44.6 ± 0.2*
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 35.3 ± 0.1 | 35.1 ± 0.1 | 35.1 ± 0.2 | 35.1 ± 0.3 | 34.9 ± 0.3 | 34.3 ± 0.1**
Platelets (10^3^/µL) | 1,180 ± 28 | 1,243 ± 35 | 1,245 ± 39 | 1,351 ± 28** | 1,433 ± 28** | 1,577 ± 44**
Leukocytes (10^3^/µL) | 3.14 ± 0.53 | 2.17 ± 0.31 | 2.04 ± 0.22 | 2.71 ± 0.30 | 3.23 ± 0.32 | 2.58 ± 0.30
Segmented neutrophils (10^3^/µL) | 0.44 ± 0.08 | 0.26 ± 0.04 | 0.26 ± 0.03 | 0.31 ± 0.04 | 0.45 ± 0.06 | 0.76 ± 0.21
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.56 ± 0.44 | 1.79 ± 0.26 | 1.68 ± 0.18 | 2.26 ± 0.25 | 2.66 ± 0.25 | 1.71 ± 0.17
Monocytes (10^3^/µL) | 0.05 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.06 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.010 ± 0.004 | 0.010 ± 0.003 | 0.007 ± 0.002 | 0.010 ± 0.003 | 0.011 ± 0.002 | 0.005 ± 0.002
Eosinophils (10^3^/µL) | 0.06 ± 0.02 | 0.07 ± 0.01 | 0.05 ± 0.01 | 0.07 ± 0.02 | 0.05 ± 0.01 | 0.05 ± 0.01
Large unstained cells (10^3^/µL) | 0.022 ± 0.008 | 0.014 ± 0.003 | 0.013 ± 0.003 | 0.013 ± 0.004 | 0.023 ± 0.004 | 0.022 ± 0.004
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (spun) (%) | 50.6 ± 0.3 | 51.2 ± 0.3 | 50.4 ± 0.6 | 50.2 ± 0.4 | 49.2 ± 0.2** | 47.4 ± 0.4**
Packed cell volume (%) | 51.6 ± 0.2 | 52.2 ± 0.4 | 51.6 ± 0.4 | 51.6 ± 0.6 | 50.2 ± 0.2** | 48.0 ± 0.5**
Hemoglobin (g/dL) | 16.5 ± 0.1 | 16.6 ± 0.1 | 16.5 ± 0.1 | 16.5 ± 0.1 | 16.2 ± 0.1 | 15.2 ± 0.2**
Erythrocytes (10^6^/µL) | 10.69 ± 0.05 | 10.76 ± 0.06 | 10.62 ± 0.09 | 10.62 ± 0.11 | 10.27 ± 0.03** | 9.74 ± 0.12**
Reticulocytes (10^3^/µL) | 276 ± 17 | 292 ± 8 | 275 ± 16 | 270 ± 14 | 258 ± 10 | 283 ± 13
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.0 ± 0.0* | 0.1 ± 0.0 | 0.1 ± 0.0
Mean cell volume (fL) | 48.3 ± 0.1 | 48.5 ± 0.2 | 48.6 ± 0.1 | 48.6 ± 0.3 | 48.9 ± 0.2* | 49.3 ± 0.2**
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.8 ± 0.1** | 15.6 ± 0.0*
Mean cell hemoglobin concentration (g/dL) | 32.0 ± 0.1 | 31.9 ± 0.2 | 31.9 ± 0.1 | 32.0 ± 0.2 | 32.3 ± 0.1 | 31.6 ± 0.1
Platelets (10^3^/µL) | 1,099 ± 29 | 1,101 ± 24 | 1,163 ± 53 | 1,209 ± 53 | 1,228 ± 33* | 1,415 ± 25**
Leukocytes (10^3^/µL) | 3.46 ± 0.35 | 3.46 ± 0.45 | 2.96 ± 0.38 | 3.18 ± 0.33 | 2.97 ± 0.28 | 2.70 ± 0.17
Segmented neutrophils (10^3^/µL) | 0.53 ± 0.09 | 0.47 ± 0.05 | 0.44 ± 0.06 | 0.44 ± 0.10 | 0.38 ± 0.04 | 0.64 ± 0.09
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.76 ± 0.28 | 2.83 ± 0.38 | 2.40 ± 0.31 | 2.63 ± 0.27 | 2.46 ± 0.24 | 1.92 ± 0.11
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.013 ± 0.002 | 0.018 ± 0.005 | 0.007 ± 0.003 | 0.010 ± 0.003 | 0.011 ± 0.003 | 0.013 ± 0.003
Eosinophils (10^3^/µL) | 0.08 ± 0.01 | 0.07 ± 0.02 | 0.07 ± 0.02 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01
Large unstained cells (10^3^/µL) | 0.027 ± 0.005 | 0.038 ± 0.012 | 0.023 ± 0.008 | 0.017 ± 0.006 | 0.016 ± 0.005 | 0.028 ± 0.005

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.