# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

p-Chloro-α,α,α-trifluorotoluene was tested in two independent bacterial gene mutation assays. In the first assay, testing procedures followed protocols reported by Haworth et al.^33^ Briefly, a commercially obtained sample of p-chloro-α,α,α-trifluorotoluene was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37ºC. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37ºC.

In the second assay, a sample of the same lot of p-chloro-α,α,α-trifluorotoluene that was used in the 2-year bioassay was sent to the testing laboratory for assessment of mutagenicity in S. typhimurium strains TA98 and TA100 and Escherichia coli strain WP2 uvrA/pKM101. Incubation in either buffer or S9 mix (from induced Sprague Dawley rat liver) and plating on minimal glucose agar plates was carried out as described above. Histidine-independent (for the S. typhimurium strains) or tryptophan-independent (for the E. coli strain) mutant colonies arising on these plates were counted following incubation for 2 days at 37ºC.

For all strains, each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of the test article. The high dose was limited by toxicity and all trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any single strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

## E.2 Peripheral Blood Micronucleus Test Protocol

At the termination of the 3-month toxicity studies with p-chloro-α,α,α-trifluorotoluene, blood samples (~200 μL) were collected from male and female rats and mice, placed in EDTA-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlow^PLUS^ Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a -80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (polychromatic erythrocytes, PCEs, reticulocytes) and mature erythrocytes (normochromatic erythrocytes, NCEs) using a flow cytometer^96^; both the mature and the immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71-positive cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24 to 48 hours, before the rat spleen appreciably alters the percentage of micronucleated reticulocytes in circulation^97^. In mice, both the immature and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 reticulocytes and 1 × 10^6^ erythrocytes were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (%PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques^98^, it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025.

In the micronucleus test, a positive result is preferably based on the presence of both a significant trend as well as at least one significantly elevated dose group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a significant trend or a single significant dose group generally results in an equivocal call. The absence of both a trend and a significant dose group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

In an earlier bacterial mutagenicity assay, p-chloro-α,α,α-trifluorotoluene (10 to 1,000 µg/plate) was not mutagenic in any of four strains of S. typhimurium (TA98, TA100, TA1535, TA1537) when tested without exogenous metabolic activation or with 10% Aroclor 1254-induced hamster or rat liver S9 mix (Table E-1; Haworth et al.^33^). In a second bacterial mutagenicity assay conducted with the same lot of p-chloro-α,α,α-trifluorotoluene that was tested in the 2-year rodent bioassay, no evidence of mutagenicity was observed in S. typhimurium strains TA98 or TA100 or in E. coli strain WP2 uvrA/pKM101, with or without induced rat liver S9 mix (Table E-2). Doses in this second assay were significantly higher than those that were achievable in the initial assay (up to 5,000 µg/plate without S9 and 6,000 µg/plate in the presence of S9).

In vivo, no significant increases in micronucleated immature or mature erythrocytes were observed in peripheral blood samples from rats in the 3-month study (Table E-3). The small increase in micronucleated immature erythrocytes observed in the male rats was within historical control ranges (<1 standard deviation of the mean) and was therefore judged not to be biologically significant. In mice from the 3-month study, small but statistically significant increases in micronucleated mature erythrocytes were seen at the highest exposure concentration (2,000 ppm), but the observed values for the female mice were within historical control ranges (<1 standard deviation of the mean) and were not considered to be biologically significant (Table E-4). For male mice, the observed response was outside the historical control range for the laboratory and was therefore judged to be positive. An exposure concentration-related increase in the percentage of immature erythrocytes in peripheral blood was seen only in female mice, suggesting that p-chloro-α,α,α-trifluorotoluene may have stimulated erythropoiesis in female mice. No significant changes in the percentage of immature erythrocytes were seen in male or female rats or male mice.

Table E-1 Mutagenicity of p-Chloro-α,α,α-trifluorotoluene in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 10% hamster S9 | With 10% rat S9 | With 10% rat S9
TA100
| 0 | 111 ± 6 | 92 ± 13 | 99 ± 3 | 98 ± 7 | 111 ± 13 | 123 ± 5
| 10 | 113 ± 5 | 90 ± 11 | 104 ± 3 | 96 ± 10 | 115 ± 6 | 101 ± 8
| 33 | 105 ± 5 | – | – | – | – | –
| 33.3 | – | 99 ± 8 | 106 ± 4 | 88 ± 10 | 101 ± 1 | 103 ± 11
| 100 | 100 ± 5 | 103 ± 16 | 98 ± 4 | 106 ± 4 | 102 ± 4 | 88 ± 2
| 333.3 | 110 ± 1 | 82 ± 4^b^ | 74 ± 5 | 101 ± 3 | 73 ± 2 | 72 ± 11^b^
| 1,000 | Toxic | Toxic | 64 ± 6^b^ | 92 ± 9 | 64 ± 5^b^ | 67 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 483 ± 7 | 416 ± 11 | 1,119 ± 120 | 2,115 ± 15 | 1,075 ± 30 | 549 ± 71
TA98
| 0 | 29 ± 1 | 34 ± 5 | 47 ± 8 | 33 ± 2 | 40 ± 3 | 43 ± 1
| 10 | 31 ± 7 | 29 ± 2 | 52 ± 4 | 37 ± 2 | 53 ± 1 | 39 ± 3
| 33.3 | 21 ± 2 | 29 ± 1 | 50 ± 9 | 35 ± 3 | 44 ± 6 | 35 ± 4
| 100 | 22 ± 4 | 25 ± 7 | 48 ± 5 | 33 ± 4 | 32 ± 3 | 38 ± 4
| 333.3 | 22 ± 2 | 8 ± 1^b^ | 28 ± 5 | 33 ± 3 | 22 ± 3 | 30 ± 5^b^
| 1,000 | Toxic | Toxic | 35 ± 2^b^ | 25 ± 6 | 22 ± 4^b^ | 27 ± 2^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 691 ± 10 | 671 ± 58 | 570 ± 58 | 1,271 ± 8 | 574 ± 22 | 365 ± 23
TA1535
| 0 | 32 ± 2 | 20 ± 4 | 12 ± 2 | 10 ± 2 | 14 ± 1 | 8 ± 2
| 10 | 38 ± 1 | 16 ± 1 | 16 ± 2 | 15 ± 1 | 15 ± 1 | 12 ± 0
| 33.3 | 33 ± 4 | 14 ± 2 | 12 ± 2 | 12 ± 3 | 16 ± 3 | 9 ± 1
| 100 | 36 ± 4 | 15 ± 3 | 15 ± 3 | 10 ± 2 | 12 ± 2 | 14 ± 1
| 333.3 | 28 ± 2^b^ | 13 ± 3^b^ | 8 ± 1 | 9 ± 3 | 11 ± 3 | 8 ± 2^b^
| 1,000 | Toxic | 8 ± 0^b^ | 7 ± 1^b^ | 11 ± 1 | 11 ± 3^b^ | 11 ± 2^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 412 ± 9 | 346 ± 14 | 257 ± 14 | 266 ± 10 | 314 ± 15 | 167 ± 5
TA1537
| 0 | 16 ± 4 | 5 ± 2 | 16 ± 2 | 8 ± 1 | 16 ± 2 | 6 ± 1
| 10 | 10 ± 3 | 7 ± 2 | 23 ± 1 | 6 ± 0 | 19 ± 1 | 6 ± 1
| 33.3 | 11 ± 1 | 3 ± 1 | 21 ± 2 | 6 ± 1 | 16 ± 0 | 7 ± 0
| 100 | 9 ± 2 | 4 ± 1 | 19 ± 1 | 6 ± 1 | 15 ± 1 | 6 ± 1
| 333.3 | 8 ± 0 | 4 ± 1 | 15 ± 1 | 6 ± 2 | 10 ± 4 | 5 ± 1
| 1,000 | 3 ± 3^b^ | Toxic | 15 ± 3^b^ | 3 ± 1^b^ | 7 ± 1^b^ | 1 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 329 ± 159 | 847 ± 54 | 459 ± 52 | 411 ± 10 | 495 ± 53 | 239 ± 25

^a^ Study was performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol and these data are presented by Haworth et al.^33^. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Mutagenicity of p-Chloro-α,α,α-trifluorotoluene in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100
| DMSO | 104.7 ± 2.7 | 96.7 ± 9.3 | 114.0 ± 1.5 | 105.7 ± 9.6
| 125 | 86.3 ± 13.7 | 86.7 ± 6.6 | – | –
| 250 | 66.0 ± 4.0 | 74.7 ± 2.0 | 96.7 ± 10.7 | 100.7 ± 8.3
| 500 | 67.0 ± 6.1^b^ | 43.3 ± 6.4^b^ | 76.0 ± 7.2 | 78.3 ± 2.2
| 1,000 | 53.3 ± 6.0^b^ | 45.0 ± 8.9^b^ | 75.3 ± 1.9^b^ | 69.7 ± 8.6^b^
| 2,000 | 28.7 ± 1.9^b^ | 53.7 ± 13.7^b^ | 53.0 ± 17.5^b^ | 46.0 ± 4.0^b^
| 3,000 | – | – | 36.7 ± 19.9^b^ | 32.7 ± 6.7^b^
| 5,000 | 6.0 ± 2.3^b^ | 5.5 ± 2.5^b^ | – | –
| 6,000 | – | – | Toxic | 21.3 ± 5.8^b^
Trial summary | – | Negative | Negative | Negative | Negative
Positive controlc | – | 589.7 ± 35.5 | 666.0 ± 30.0 | 664.7 ± 54.5 | 653.0 ± 30.4
TA98
| DMSO | 17.0 ± 2.3 | 11.0 ± 1.2 | 21.0 ± 2.9 | 16.7 ± 3.0
| 125 | 11.0 ± 1.7 | 14.7 ± 4.6
| 250 | 12.3 ± 1.3 | 10.3 ± 2.0 | 18.3 ± 2.4 | 20.3 ± 4.4
| 500 | 9.0 ± 2.6 | 10.0 ± 1.7^b^ | 19.7 ± 2.3 | 14.0 ± 8.4
| 1,000 | 10.7 ± 2.3 | 9.3 ± 2.8^b^ | 11.3 ± 2.6 | 17.0 ± 1.0^b^
| 2,000 | 11.0 ± 2.0^b^ | 12.3 ± 1.2^b^ | 13.0 ± 2.5 | 18.0 ± 3.1^b^
| 3,000 | – | – | 18.0 ± 1.5 | 17.3 ± 2.7^b^
| 5,000 | Toxic | Toxic | – | –
| 6,000 | – | – | 16.3 ± 1.5 | 3.3 ± 0.9^b^
Trial summary | – | Negative | Negative | Negative | Negative
Positive control | – | 664.0 ± 15.7 | 698.0 ± 26.4 | 1,378.3 ± 89.5 | 1,611.7 ± 116.2
Escherichia coli WP2 uvrA/pKM101
| DMSO | 97.3 ± 15.6 | 109.7 ± 4.4 | 147.0 ± 21.1 | 170.3 ± 5.8
| 125 | 83.7 ± 9.3 | 122.7 ± 11.3 | – | –
| 250 | 71.3 ± 3.5 | 108.0 ± 2.1 | 179.3 ± 18.4 | 155.7 ± 11.3
| 500 | 72.3 ± 1.3 | 106.0 ± 4.0^b^ | 122.7 ± 4.8 | 125.0 ± 15.0
| 1,000 | 73.7 ± 2.6 | 78.7 ± 20.9^b^ | 93.3 ± 7.7^b^ | 119.0 ± 12.2^b^
| 2,000 | 62.3 ± 8.1^b^ | 84.3 ± 10.7^b^ | 95.3 ± 7.5^b^ | 120.3 ± 5.0^b^
| 3,000 | – | – | 78.7 ± 17.6^b^ | 97.7 ± 20.8^b^
| 5,000 | 13.0 ± 3.6^b^ | 29.5 ± 24.5^b^ | – | –
| 6,000 | – | – | 45.0 ± 20.5^b^ | 106.7 ± 25.7^b^
Trial summary | – | Negative | Negative | Negative | Negative
Positive control | – | 1,518.7 ± 61.0 | 2,208.0 ± 27.5 | 994.3 ± 2.7 | 1,321.3 ± 5.6

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates. Dimethyl sulfoxide (DMSO) was the solvent control.

^b^ Slight toxicity

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluroene (TA98), and 4-nitroquinoline N-oxide (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene, except benzo(a)pyrene was used for TA100.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Treatment with p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months^a^

| Exposure Concentration (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P value^d^ | PCEs^b^ (%) | P value^d^
Male
Air^e^ | 0 | 5 | 0.52 ± 0.05 | – | 0.14 ± 0.02 | – | 0.916 ± 0.04 | –
p-Chloro-α,α,α-trifluorotoluene
| 125 | 5 | 0.53 ± 0.06 | 0.4831 | 0.14 ± 0.02 | 0.7538 | 0.838 ± 0.05 | 1.0000
| 250 | 5 | 0.52 ± 0.04 | 0.5629 | 0.10 ± 0.01 | 0.8340 | 0.945 ± 0.05 | 0.9999
| 500 | 5 | 0.67 ± 0.10 | 0.1856 | 0.11 ± 0.02 | 0.8632 | 0.902 ± 0.08 | 1.0000
| 1,000 | 5 | 0.60 ± 0.11 | 0.1904 | 0.10 ± 0.02 | 0.8758 | 0.925 ± 0.05 | 0.9985
| 2,000 | 5 | 0.71 ± 0.05 | 0.0585 | 0.13 ± 0.04 | 0.7864 | 1.062 ± 0.07 | 0.1852
| – | – | P = 0.023^f^ | – | P = 0.590^f^ | – | P = 0.037^f^ | –
Female
Air | 0 | 5 | 0.49 ± 0.13 | – | 0.09 ± 0.01 | – | 0.847 ± 0.07 | –
p-Chloro-α,α,α-trifluorotoluene
| 125 | 5 | 0.60 ± 0.15 | 0.2167 | 0.06 ± 0.00 | 1.0000 | 0.895 ± 0.07 | 1.0000
| 250 | 5 | 0.77 ± 0.09 | 0.1872 | 0.13 ± 0.04 | 1.0000 | 1.038 ± 0.18 | 0.8613
| 500 | 5 | 0.62 ± 0.08 | 0.2014 | 0.11 ± 0.03 | 1.0000 | 1.113 ± 0.05 | 0.2213
| 1,000 | 5 | 0.53 ± 0.06 | 0.2069 | 0.10 ± 0.02 | 1.0000 | 1.020 ± 0.05 | 0.9798
| 2,000 | 5 | 0.61 ± 0.04 | 0.2115 | 0.16 ± 0.06 | 0.9229 | 1.072 ± 0.10 | 0.6569
| – | – | P = 0.525^f^ | – | P = 0.112^g^ | – | P = 0.099^g^ | –

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^96^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by William’s test.

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’s test (males) or Dunn’s test (females).

^e^ Chamber control.

^f^ Exposure concentration-related trend significant at P ≤ 0.025 by linear regression.

^g^ Exposure concentration-related trend significant at P ≤ 0.025 by Jonckheere’s test.

Table E-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with p-Chloro-α,α,α-trifluorotoluene by Inhalation for Three Months^a^

| Exposure Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P value^d^ | PCEs^b^ (%) | P value^d^
Male
Air^e^ | 0 | 5 | 2.18 ± 0.13 | – | 1.46 ± 0.03 | – | 1.543 ± 0.06 | –
p-Chloro-α,α,α-trifluorotoluene
| 125 | 5 | 2.31 ± 0.13 | 1.0000 | 1.44 ± 0.03 | 0.5848 | 1.595 ± 0.04 | 1.0000
| 250 | 5 | 2.46 ± 0.21 | 1.0000 | 1.45 ± 0.04 | 0.6700 | 1.464 ± 0.06 | 0.6653
| 500 | 5 | 2.21 ± 0.09 | 1.0000 | 1.42 ± 0.02 | 0.7043 | 1.285 ± 0.07 | 0.7099
| 1,000 | 5 | 2.43 ± 0.16 | 0.8739 | 1.48 ± 0.05 | 0.5151 | 1.516 ± 0.09 | 0.7318
| 2,000 | 5 | 2.93 ± 0.55 | 0.4432 | 1.80 ± 0.09 | 0.0000 | 1.715 ± 0.09 | 0.1610
| – | – | P = 0.105^f^ | – | P = 0.000^g^ | – | P = 0.096^g^ | –
Female
Air | 0 | 5 | 1.74 ± 0.19 | – | 1.07 ± 0.02 | – | 0.985 ± 0.10 | –
p-Chloro-α,α,α-trifluorotoluene
| 125 | 5 | 2.15 ± 0.22 | 0.2655 | 1.07 ± 0.04 | 0.8172 | 1.169 ± 0.10 | 0.1569
| 250 | 5 | 1.90 ± 0.20 | 0.3173 | 1.04 ± 0.03 | 0.8874 | 1.392 ± 0.11 | 0.0156
| 500 | 5 | 1.79 ± 0.07 | 0.3400 | 0.94 ± 0.03 | 0.9102 | 1.336 ± 0.16 | 0.0161
| 1,000 | 5 | 1.94 ± 0.14 | 0.3515 | 1.04 ± 0.03 | 0.8880 | 1.395 ± 0.08 | 0.0073
| 2,000 | 5 | 1.69 ± 0.16 | 0.3609 | 1.19 ± 0.03 | 0.0085 | 1.614 ± 0.09 | 0.0004
| – | – | P = 0.832^g^ | – | P = 0.007^g^ | – | P = 0.001^g^ | –

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^96^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s test (males) or William’s test (females).

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’s test.

^e^ Chamber control.

^f^ Exposure concentration-related trend significant at P ≤ 0.025 by Jonckheere’s test.

^g^ Exposure concentration-related trend significant at P ≤ 0.025 by linear regression.