# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | 1 | –
Moribund | 7 | 12 | 9 | 16
Natural deaths | 5 | 5 | 1 | 7
Survivors
Died last week of study | – | – | 2 | 1
Terminal kill | 38 | 33 | 37 | 26
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (47) | (49) | (48) | (47)
Intestine large, cecum | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (48) | (50) | (48) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatoblastoma | – | – | 1 (2%) | 8 (16%)
Hepatocellular adenoma | 9 (18%) | 9 (18%) | 9 (18%) | 9 (18%)
Hepatocellular adenoma, multiple | 3 (6%) | 5 (10%) | 15 (30%) | 25 (50%)
Hepatocellular carcinoma | 5 (10%) | 5 (10%) | 5 (10%) | 6 (12%)
Hepatocellular carcinoma, multiple | 2 (4%) | 3 (6%) | 7 (14%) | 28 (56%)
Osteosarcoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Mesentery | (9) | (13) | (15) | (12)
Hemangiosarcoma | 1 (11%) | 2 (15%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (11%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Salivary glands | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Rhabdomyosarcoma | – | – | 1 (2%) | –
Sarcoma, metastatic, skin | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Hemangioma | – | – | – | 1 (2%)
Squamous cell papilloma | 1 (2%) | 2 (4%) | 1 (2%) | 3 (6%)
Stomach, glandular | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Tongue | (0) | (0) | (0) | (1)
Squamous cell papilloma | – | – | – | 1 (100%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (49) | (50)
Adenoma | – | 1 (2%) | – | –
Parathyroid gland | (36) | (29) | (30) | (34)
Pituitary gland | (50) | (50) | (50) | (50)
Parts distalis, adenoma | 4 (8%) | 4 (8%) | – | 3 (6%)
Pars intermedia, adenoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Thyroid gland | (50) | (50) | (49) | (49)
Follicular cell, adenoma | – | 1 (2%) | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (48) | (46) | (49) | (48)
Ovary | (50) | (50) | (50) | (50)
Cystadenoma | 2 (4%) | 1 (2%) | 2 (4%) | –
Granulosa cell tumor benign | – | – | – | 1 (2%)
Granulosa-theca tumor malignant | 1 (2%) | – | – | –
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | – | – | – | 1 (2%)
Luteoma | 2 (4%) | – | 1 (2%)
Teratoma benign | – | 1 (2%) | – | –
Tubulostromal adenoma | – | – | 1 (2%) | 1 (2%)
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%)
Polyp stromal | – | – | 1 (2%) | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Lymph node | (2) | (3) | (4) | (7)
Lymph node, bronchial | (48) | (48) | (50) | (49)
Alveolar/bronchioles carcinoma, metastatic, lung | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Lymph node, mandibular | (47) | (42) | (49) | (46)
Sarcoma, metastatic, skin | 1 (2%) | – | – | –
Lymph node, mediastinal | (48) | (49) | (49) | (47)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (49) | (49) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%)
Thymus | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Sarcoma, metastatic, bone | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (49) | (50) | (50) | (50)
Adenocarcinoma | – | 1 (2%) | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Subcutaneous tissue, fibrosarcoma | – | – | – | 2 (4%)
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, rhabdomyosarcoma | – | 1 (2%) | – | –
Subcutaneous tissue, sarcoma, multiple | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | – | 2 (4%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Rib, sarcoma | – | – | – | 1 (2%)
Vertebra, osteosarcoma | – | 1 (2%) | – | 1 (2%)
Skeletal muscle | (4) | (3) | (1) | (3)
Hemangiosarcoma | – | 1 (33%) | – | –
Rhabdomyosarcoma | 1 (25%) | – | – | –
Rhabdomyosarcoma, multiple | 1 (25%) | – | – | –
Sarcoma, metastatic, bone | – | – | – | 1 (33%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Plasma cell tumor malignant | – | 1 (2%) | – | –
Peripheral nerve | (1) | (2) | (1) | (2)
Spinal cord | (1) | (2) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (49) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 4 (8%) | 5 (10%) | 6 (12%)
Alveolar/bronchiolar carcinoma | – | – | 2 (4%) | 2 (4%)
Alveolar/bronchiolar carcinoma, multiple | – | 1 (2%) | – | 1 (2%)
Fibrosarcoma, metastatic, skin | – | – | – | 1 (2%)
Hemangiosarcoma | – | 1 (2%) | – | –
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 2 (4%) | 1 (2%) | 3 (6%)
Osteosarcoma, metastatic, bone | – | 1 (2%) | – | –
Osteosarcoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Mediastinum, sarcoma, metastatic, bone | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Pleura | (0) | (0) | (0) | (2)
Trachea | (50) | (50) | (50) | (49)
Special Senses System
Ear | (1) | (0) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, Harderian gland | – | – | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Adenocarcinoma | – | – | 3 (6%) | –
Adenoma | 2 (4%) | 6 (12%) | 6 (12%) | 8 (16%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Renal tubule, adenoma | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 1 (2%) | 1 (2%) | 3 (6%)
Lymphoma malignant | 9 (18%) | 6 (12%) | 11 (22%) | 3 (6%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 38 | 37 | 41 | 49
Total primary neoplasms | 57 | 65 | 77 | 124
Total animals with benign neoplasms | 24 | 28 | 31 | 40
Total benign neoplasms | 31 | 37 | 44 | 62
Total animals with malignant neoplasms | 24 | 22 | 26 | 42
Total malignant neoplasms | 26 | 28 | 33 | 62
Total animals with metastatic neoplasms | 3 | 4 | 2 | 10
Total metastatic neoplasms | 4 | 4 | 2 | 15
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Harderian Gland: Adenoma
Overall rate^a^ | 2/50 (4%) | 6/50 (12%) | 6/50 (12%) | 8/50 (16%)
Adjusted rate^b^ | 4.4% | 13.6% | 13.5% | 18.1%
Terminal rate^c^ | 2/38 (5%) | 5/33 (15%) | 5/37 (14%) | 4/27 (15%)
First incidence (days) | 731 (T) | 576 | 562 | 642
Poly-3 test^d^ | P = 0.049 | P = 0.124 | P = 0.129 | P = 0.041
Harderian Gland: Adenocarcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 0.0% | 6.6% | 0.0%
Terminal rate | 0/38 (0%) | 0/33 (0%) | 1/37 (3%) | 0/27 (0%)
First incidence (days) | –^e^ | – | 480 | –
Poly-3 test | P = 0.515 | –^f^ | P = 0.119 | –
Harderian Gland: Adenoma or Adenocarcinoma
Overall rate | 2/50 (4%) | 6/50 (12%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 4.4% | 13.6% | 19.7% | 18.1%
Terminal rate | 2/38 (5%) | 5/33 (15%) | 6/37 (16%) | 4/27 (15%)
First incidence (days) | 731 (T) | 576 | 480 | 642
Poly-3 test | P = 0.046 | P = 0.124 | P = 0.026 | P = 0.041
Liver: Hepatocellular Adenoma
Overall rate | 12/50 (24%) | 14/50 (28%) | 24/50 (48%) | 34/50 (68%)
Adjusted rate | 26.1% | 31.9% | 54.5% | 72.6%
Terminal rate | 9/38 (24%) | 11/33 (33%) | 24/37 (65%) | 18/27 (67%)
First incidence (days) | 544 | 685 | 731 (T) | 530
Poly-3 test | P < 0.001 | P = 0.355 | P = 0.004 | P < 0.001
Liver: Hepatocellular Carcinoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 12/50 (24%) | 34/50 (68%)
Adjusted rate | 15.3% | 18.1% | 26.9% | 75.9%
Terminal rate | 4/38 (11%) | 5/33 (15%) | 9/37 (24%) | 23/27 (85%)
First incidence (days) | 664 | 578 | 576 | 642
Poly-3 test | P < 0.001 | P = 0.472 | P = 0.136 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 18/50 (36%) | 18/50 (36%) | 29/50 (58%) | 46/50 (92%)
Adjusted rate | 38.8% | 40.4% | 65.0% | 97.6%
Terminal rate | 13/38 (34%) | 13/33 (39%) | 26/37 (70%) | 27/27 (100%)
First incidence (days) | 544 | 578 | 576 | 530
Poly-3 test | P < 0.001 | P = 0.523 | P = 0.008 | P < 0.001
Liver: Hepatoblastoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 8/50 (16%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 18.3%
Terminal rate | 0/38 (0%) | 0/33 (0%) | 1/37 (3%) | 4/27 (15%)
First incidence (days) | – | – | 731 (T) | 673
Poly-3 test | P < 0.001 | – | P = 0.495 | P = 0.003
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 12/50 (24%) | 36/50 (72%)
Adjusted rate | 15.3% | 18.1% | 26.9% | 79.8%
Terminal rate | 4/38 (11%) | 5/33 (15%) | 9/37 (24%) | 23/27 (85%)
First incidence (days) | 664 | 578 | 576 | 642
Poly-3 test | P < 0.001 | P = 0.472 | P = 0.136 | P < 0.001
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 18/50 (36%) | 18/50 (36%) | 29/50 (58%) | 46/50 (92%)
Adjusted rate | 38.8% | 40.4% | 65.0% | 97.6%
Terminal rate | 13/38 (34%) | 13/33 (39%) | 26/37 (70%) | 27/27 (100%)
First incidence (days) | 544 | 578 | 576 | 530
Poly-3 test | P < 0.001 | P = 0.523 | P = 0.008 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 11.1% | 9.0% | 11.2% | 13.7%
Terminal rate | 5/38 (13%) | 3/33 (9%) | 3/37 (8%) | 3/27 (11%)
First incidence (days) | 731 (T) | 224 | 562 | 628
Poly-3 test | P = 0.360 | P = 0.509N | P = 0.624 | P = 0.482
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.3% | 4.5% | 6.8%
Terminal rate | 0/38 (0%) | 1/33 (3%) | 2/37 (5%) | 1/27 (4%)
First incidence (days) | – | 731 (T) | 731 (T) | 570
Poly-3 test | P = 0.059 | P = 0.493 | P = 0.232 | P = 0.114
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 7/50 (14%) | 9/50 (18%)
Adjusted rate | 11.1% | 11.2% | 15.7% | 20.1%
Terminal rate | 5/38 (13%) | 4/33 (12%) | 5/37 (14%) | 4/27 (15%)
First incidence (days) | 731 (T) | 224 | 562 | 570
Poly-3 test | P = 0.110 | P = 0.622 | P = 0.371 | P = 0.187
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 8.8% | 9.1% | 0.0% | 6.8%
Terminal rate | 3/38 (8%) | 3/33 (9%) | 0/37 (0%) | 1/27 (4%)
First incidence (days) | 664 | 564 | – | 530
Poly-3 test | P = 0.326N | P = 0.627 | P = 0.064N | P = 0.518N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 1/50 (2%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.2% | 4.6% | 2.3% | 7.0%
Terminal rate | 1/38 (3%) | 1/33 (3%) | 1/37 (3%) | 3/27 (11%)
First incidence (days) | 731 (T) | 703 | 731 (T) | 731 (T)
Poly-3 test | P = 0.226 | P = 0.488 | P = 0.755 | P = 0.290
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 6.6% | 4.6% | 2.3% | 9.1%
Terminal rate | 2/38 (5%) | 1/33 (3%) | 1/37 (3%) | 1/28 (4%)
First incidence (days) | 676 | 597 | 731 (T) | 480
Poly-3 test | P = 0.365 | P = 0.514N | P = 0.315N | P = 0.485
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 1/50 (2%) | 5/50 (10%)
Adjusted rate | 6.6% | 6.8% | 2.3% | 11.3%
Terminal rate | 2/38 (5%) | 2/33 (6%) | 1/37 (3%) | 2/27 (7%)
First incidence (days) | 676 | 597 | 731 (T) | 480
Poly-3 test | P = 0.265 | P = 0.648 | P = 0.315N | P = 0.341
All Organs: Histiocytic Sarcoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 4.3% | 2.3% | 2.2% | 6.9%
Terminal rate | 0/38 (0%) | 0/33 (0%) | 0/37 (0%) | 2/27 (7%)
First incidence (days) | 493 | 488 | 562 | 673
Poly-3 test | P = 0.311 | P = 0.516N | P = 0.513N | P = 0.470
All Organs: Malignant Lymphoma
Overall rate | 9/50 (18%) | 6/50 (12%) | 11/50 (22%) | 3/50 (6%)
Adjusted rate | 19.6% | 13.5% | 24.8% | 6.9%
Terminal rate | 7/38 (18%) | 3/33 (9%) | 8/37 (22%) | 2/27 (7%)
First incidence (days) | 502 | 576 | 641 | 570
Poly-3 test | P = 0.107N | P = 0.312N | P = 0.366 | P = 0.071N
All Organs: Benign Neoplasms
Overall rate | 24/50 (48%) | 28/50 (56%) | 31/50 (62%) | 40/50 (80%)
Adjusted rate | 51.5% | 60.2% | 69.5% | 85.0%
Terminal rate | 19/38 (50%) | 21/33 (64%) | 29/37 (78%) | 23/27 (85%)
First incidence (days) | 544 | 224 | 562 | 530
Poly-3 test | P < 0.001 | P = 0.259 | P = 0.056 | P < 0.001
All Organs: Malignant Neoplasms
Overall rate | 24/50 (48%) | 22/50 (44%) | 26/50 (52%) | 42/50 (84%)
Adjusted rate | 49.1% | 46.5% | 55.7% | 87.9%
Terminal rate | 14/38 (37%) | 10/33 (30%) | 18/37 (49%) | 24/27 (89%)
First incidence (days) | 493 | 488 | 480 | 374
Poly-3 test | P < 0.001 | P = 0.480N | P = 0.328 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 38/50 (76%) | 37/50 (74%) | 41/50 (82%) | 49/50 (98%)
Adjusted rate | 77.1% | 74.9% | 87.9% | 99.5%
Terminal rate | 27/38 (71%) | 22/33 (67%) | 33/37 (89%) | 27/27 (100%)
First incidence (days) | 493 | 224 | 480 | 374
Poly-3 test | P < 0.001 | P = 0.489N | P = 0.126 | P < 0.001

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Liver Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 11/50 | 6/50 | 0/50 | 14/50
2,3-Butanedione (August 2009) | 6/50 | 5/50 | 1/50 | 12/50
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 12/50 | 7/50 | 0/50 | 18/50
CIMSTAR 3800 (May 2008) | 14/50 | 10/50 | 1/50 | 20/50
Cobalt metal (May 2006) | 19/50 | 10/50 | 0/50 | 25/50
TRIM VX (August 2009) | 9/50 | 7/50 | 1/50 | 15/50
Total (%) | 71/300 (23.7%) | 45/300 (15.0%) | 3/300 (1.0%) | 104/300 (34.7%)
Mean ± standard deviation | 23.7% ± 8.9% | 15.0% ± 4.2% | 1.0% ± 1.1% | 34.7% ± 9.4%
Range | 12%–38% | 10%–20% | 0%–2% | 24%–50%
Overall Historical Incidence: All Routes
Total (%) | 141/549 (25.7%) | 71/549 (12.9%) | 3/549 (0.6%) | 189/549 (34.4%)
Mean ± standard deviation | 25.8% ± 15.9% | 12.9% ± 5.1% | 0.6% ± 0.9% | 34.5% ± 15.8%
Range | 10%–67% | 4%–20% | 0%–2% | 16%–73%

^a^ Data as of August 2016.

Table D-4 Historical Incidence of Harderian Gland Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Adenocarcinoma | Adenoma or Adenocarcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 3/50 | 4/50 | 7/50
2,3-Butanedione (August 2009) | 3/50 | 1/50 | 4/50
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 2/50 | 0/50 | 2/50
CIMSTAR 3800 (May 2008) | 2/50 | 0/50 | 2/50
Cobalt metal (May 2006) | 3/50 | 0/50 | 3/50
TRIM VX (August 2009) | 1/50 | 3/50 | 4/50
Total (%) | 14/300 (4.7%) | 8/300 (2.7%) | 22/300 (7.3%)
Mean ± standard deviation | 4.7% ± 1.6% | 2.7% ± 3.5% | 7.3% ± 3.7%
Range | 2%–6% | 0%–8% | 4%–14%
Overall Historical Incidence: All Routes
Total (%) | 35/550 (6.4%) | 12/550 (2.2%) | 47/550 (8.6%)
Mean ± standard deviation | 6.4% ± 4.4% | 2.2% ± 2.8% | 8.6% ± 4.7%
Range | 2%–18% | 0%–8% | 4%–20%

^a^ Data as of August 2016.

Table D-5 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | 1 | –
Moribund | 7 | 12 | 9 | 16
Natural deaths | 5 | 5 | 1 | 7
Survivors
Died last week of study | – | – | 2 | 1
Terminal kill | 38 | 33 | 37 | 26
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (47) | (49) | (48) | (47)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | – | 2 (4%) | 1 (2%)
Epithelium, hyperplasia | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (48) | (50) | (48) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Basophilic focus | 1 (2%) | 4 (8%) | 6 (12%) | 1 (2%)
Clear cell focus | 3 (6%) | 3 (6%) | 5 (10%) | 5 (10%)
Cyst | – | – | 1 (2%) | –
Eosinophilic focus | 4 (8%) | 8 (16%) | 24 (48%) | 31 (62%)
Fatty change | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | 1 (2%) | –
Inflammation | 1 (2%) | – | 2 (4%) | –
Mixed cell focus | 10 (20%) | 5 (10%) | 6 (12%) | 5 (10%)
Bile duct, hyperplasia | – | 1 (2%) | – | –
Capsule, inflammation, suppurative | – | – | 1 (2%) | –
Centrilobular, hepatocyte, hypertrophy | – | 4 (8%) | 5 (10%) | 40 (80%)
Hepatocyte, multinucleated | – | 2 (4%) | 2 (4%) | 25 (50%)
Hepatocyte, necrosis | 2 (4%) | 1 (2%) | 3 (6%) | 10 (20%)
Mesentery | (9) | (13) | (15) | (12)
Fat, necrosis | 8 (89%) | 9 (69%) | 15 (100%) | 12 (100%)
Pancreas | (50) | (50) | (50) | (50)
Acinus, atrophy | 1 (2%) | 1 (2%) | 4 (8%) | 2 (4%)
Acinus, hypertrophy | – | 2 (4%) | – | 1 (2%)
Duct, cyst | – | – | 2 (4%) | –
Salivary glands | (50) | (50) | (50) | (50)
Infiltration cellular, mononuclear cell | – | – | – | 1 (2%)
Duct, hyperplasia | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Inflammation | 3 (6%) | 5 (10%) | 5 (10%) | 9 (18%)
Mineralization | – | – | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | 3 (6%) | 5 (10%) | 14 (28%)
Epithelium, ulcer | – | 1 (2%) | – | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Hyperplasia, mast cell | – | – | – | 1 (2%)
Inflammation | – | 1 (2%) | – | –
Tongue | (0) | (0) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | 2 (4%) | 2 (4%) | 2 (4%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 14 (28%) | 13 (26%) | 8 (16%) | 12 (24%)
Inflammation | 2 (4%) | 3 (6%) | 5 (10%) | 5 (10%)
Necrosis | – | 1 (2%) | 1 (2%) | 2 (4%)
Thrombosis | – | 2 (4%) | – | 2 (4%)
Endocardium, fibrosis | – | – | – | 1 (2%)
Valve, angiectasis | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Cyst | – | – | 1 (2%) | –
Degeneration | 2 (4%) | – | – | 1 (2%)
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Hypertrophy | 12 (24%) | 12 (24%) | 10 (20%) | 16 (32%)
Vacuolization cytoplasmic | 2 (4%) | 2 (4%) | 2 (4%) | 3 (6%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 6 (12%) | 6 (12%) | 8 (16%) | 1 (2%)
Vacuolization cytoplasmic | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (49) | (50)
Hyperplasia | – | – | – | 1 (2%)
Parathyroid gland | (36) | (29) | (30) | (34)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, angiectasis | – | 2 (4%) | – | 1 (2%)
Pars distalis, hyperplasia | 12 (24%) | 4 (8%) | 5 (10%) | 6 (12%)
Thyroid gland | (50) | (50) | (49) | (49)
Follicular cell, hyperplasia | – | 2 (4%) | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (48) | (46) | (49) | (48)
Ovary | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Cyst | 8 (16%) | 8 (16%) | 7 (14%) | 4 (8%)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | –
Thrombosis | – | 1 (2%) | – | –
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (50) | (50) | (50)
Angiectasis | – | 2 (4%) | – | –
Hyperplasia, reticulum cell | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Neovascularization | – | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 47 (94%) | 48 (96%) | 46 (92%) | 45 (90%)
Serosa, cyst | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 1 (2%) | – | –
Hyperplasia | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Necrosis | 1 (2%) | – | 1 (2%) | –
Lymph node | (2) | (3) | (4) | (7)
Iliac, angiectasis | – | – | – | 2 (29%)
Iliac, ectasia | – | 1 (33%) | – | 1 (14%)
Lumbar, ectasia | – | – | 1 (25%) | –
Renal, angiectasis | – | 1 (33%) | – | –
Renal, ectasia | – | – | – | 2 (29%)
Lymph node, bronchial | (48) | (48) | (50) | (49)
Hyperplasia | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Lymph node, mandibular | (47) | (42) | (49) | (46)
Hyperplasia, lymphoid | 2 (4%) | – | 2 (4%) | 2 (4%)
Lymph node, mediastinal | (48) | (49) | (49) | (47)
Angiectasis | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | 1 (2%)
Infiltration cellular | 1 (2%) | – | – | –
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (49) | (49) | (50)
Angiectasis | – | 2 (4%) | 1 (2%) | –
Ectasia | 1 (2%) | – | – | –
Erythrophagocytosis | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 3 (6%) | 1 (2%) | 2 (4%) | 2 (4%)
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 14 (28%) | 12 (24%) | 13 (26%) | 16 (32%)
Lymphoid follicle, hyperplasia | 17 (34%) | 18 (36%) | 15 (30%) | 19 (38%)
Red pulp, hyperplasia, mast cell | – | – | – | 1 (2%)
Thymus | (50) | (50) | (50) | (50)
Atrophy | 10 (20%) | 9 (18%) | 11 (22%) | 13 (26%)
Ectopic parathyroid gland | 20 (40%) | 13 (26%) | 13 (26%) | 18 (36%)
Hyperplasia, lymphoid | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Integumentary System
Mammary gland | (49) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 7 (14%) | 2 (4%) | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Dysplasia | – | 1 (2%) | – | –
Inflammation | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Ulcer | 1 (2%) | – | – | –
Epidermis, hyperplasia | 1 (2%) | – | – | –
Eyelid, sebaceous gland, hyperplasia | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 13 (26%) | 15 (30%) | 6 (12%) | 10 (20%)
Vertebra, fracture | – | – | 1 (2%) | –
Skeletal muscle | (4) | (3) | (1) | (3)
Degeneration | – | 1 (33%) | – | 1 (33%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | – | 3 (6%) | – | –
Degeneration | – | 1 (2%) | 1 (2%) | 1 (2%)
Gliosis | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | 2 (4%) | –
Peripheral nerve | (1) | (2) | (1) | (2)
Degeneration | – | 1 (50%) | 1 (100%) | 2 (100%)
Spinal cord | (1) | (2) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (49) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Squamous epithelium, hyperplasia | 9 (18%) | 9 (18%) | 5 (10%) | 5 (10%)
Squamous epithelium, inflammation | 1 (2%) | 4 (8%) | 1 (2%) | 2 (4%)
Squamous epithelium, ulcer | – | 2 (4%) | – | –
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | 3 (6%) | – | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | 3 (6%)
Pigmentation | – | – | – | 1 (2%)
Thrombosis | – | 3 (6%) | 2 (4%) | 1 (2%)
Alveolar/bronchiolar epithelium, hyperplasia | – | 49 (98%) | 49 (98%) | 50 (100%)
Alveolar epithelium, hyperplasia | – | 2 (4%) | 2 (4%) | –
Alveolus, infiltration cellular, histiocyte | – | 3 (6%) | 3 (6%) | 2 (4%)
Peribronchiolar, fibrosis | – | 44 (88%) | 44 (88%) | 48 (96%)
Nose | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Inflammation, suppurative | 5 (10%) | 5 (10%) | 5 (10%) | 6 (12%)
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Ulcer | – | 1 (2%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 15 (30%) | 14 (28%) | 14 (28%) | 8 (16%)
Respiratory epithelium, accumulation, hyaline droplet | 21 (42%) | 26 (52%) | 24 (48%) | 25 (50%)
Respiratory epithelium, atrophy | – | 1 (2%) | – | –
Respiratory epithelium, metaplasia, squamous | 1 (2%) | 1 (2%) | 1 (2%) | 5 (10%)
Pleura | (0) | (0) | (0) | (2)
Inflammation | – | – | – | 2 (100%)
Trachea | (50) | (50) | (50) | (49)
Special Senses System
Ear | (1) | (0) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Cataract | 1 (2%) | – | 2 (4%) | 1 (2%)
Inflammation | – | 1 (2%) | 2 (4%) | 2 (4%)
Cornea, hyperplasia | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | 1 (2%) | – | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Amyloid deposition | – | 1 (2%) | – | –
Infarct | 7 (14%) | 4 (8%) | 5 (10%) | 4 (8%)
Inflammation, suppurative | – | – | – | 1 (2%)
Metaplasia, osseous | 1 (2%) | – | – | 2 (4%)
Necrosis | – | – | 1 (2%) | –
Nephropathy | 17 (34%) | 17 (34%) | 15 (30%) | 19 (38%)
Pigmentation | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Hyperplasia, lymphoid | – | – | – | 1 (2%)