# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 8 | 5 | 11 | 12
Natural deaths | 2 | 5 | 4 | 10
Survivors
Terminal kill | 40 | 40 | 35 | 28
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (50) | (49) | (44) | (44)
Intestine large, cecum | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (49)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Adenocarcinoma | 1 (2%) | – | – | 1 (2%)
Adenoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 2 (4%) | 1 (2%) | 1 (2%)
Hepatoblastoma | 1 (2%) | 1 (2%) | 1 (2%) | 10 (20%)
Hepatoblastoma, multiple | – | – | – | 5 (10%)
Hepatocellular adenoma | 16 (32%) | 9 (18%) | 12 (24%) | 8 (16%)
Hepatocellular adenoma, multiple | 9 (18%) | 15 (30%) | 19 (38%) | 21 (42%)
Hepatocellular carcinoma | 6 (12%) | 14 (28%) | 9 (18%) | 5 (10%)
Hepatocellular carcinoma, multiple | 2 (4%) | 5 (10%) | 7 (14%) | 30 (60%)
Hepatocholangiocarcinoma | 3 (6%) | 2 (4%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Mesentery | (6) | (5) | (2) | (5)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (20%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (20%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 2 (33%) | – | – | –
Mast cell tumor malignant | – | 1 (20%) | – | –
Pancreas | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | – | – | –
Salivary glands | (50) | (50) | (50) | (49)
Stomach, forestomach | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, mammary gland | 1 (2%) | – | – | –
Hemangioma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Squamous cell papilloma | 1 (2%) | – | – | 1 (2%)
Squamous cell papilloma, multiple | – | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (49) | (49)
Adenoma | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Tongue | (1) | (0) | (0) | (0)
Squamous cell papilloma | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | – | – | –
Sarcoma, metastatic, skin | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | 1 (2%) | – | –
Parathyroid gland | (36) | (28) | (39) | (38)
Pituitary gland | (50) | (50) | (50) | (49)
Pars distalis, adenoma | – | – | 1 (2%) | –
Pars intermedia, schwannoma malignant | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Follicular cell, adenoma | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Penis | (0) | (0) | (1) | (0)
Preputial gland | (50) | (50) | (49) | (50)
Hemangiosarcoma | – | – | 1 (2%) | –
Prostate | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Testes | (50) | (50) | (50) | (50)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Mast cell tumor malignant | – | 1 (2%) | – | –
Lymph node | (4) | (0) | (3) | (4)
Pancreatic, hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (25%)
Pancreatic, hepatocholangiocarcinoma, metastatic, liver | 1 (25%) | – | – | –
Lymph node, bronchial | (49) | (47) | (47) | (48)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | – | – | –
Lymph node, mandibular | (36) | (41) | (43) | (45)
Lymph node, mediastinal | (46) | (47) | (44) | (42)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | – | – | –
Lymph node, mesenteric | (49) | (50) | (49) | (49)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Hemangiosarcoma | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Mast cell tumor malignant | – | 1 (2%) | 1 (2%) | –
Thymus | (48) | (48) | (48) | (48)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | – | – | –
Integumentary System
Mammary gland | (2) | (1) | (3) | (1)
Adenocarcinoma | 1 (50%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | 2 (4%) | – | – | –
Subcutaneous tissue, sarcoma | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Skeletal muscle | (2) | (1) | (1) | (2)
Hepatoblastoma, metastatic, liver | 1 (50%) | – | – | 1 (50%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (50%) | – | – | –
Mast cell tumor malignant | – | 1 (100%) | – | –
Rhabdomyosarcoma | 1 (50%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, pituitary gland | 1 (2%) | – | – | –
Peripheral nerve | (0) | (0) | (1) | (0)
Spinal cord | (0) | (0) | (1) | (0)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Adenocarcinoma, metastatic, mammary gland | 1 (2%) | – | – | –
Alveolar/bronchiolar adenoma | 8 (16%) | 11 (22%) | 9 (18%) | 3 (6%)
Alveolar/bronchiolar adenoma, multiple | 3 (6%) | – | – | –
Alveolar/bronchiolar carcinoma | 4 (8%) | 3 (6%) | 3 (6%) | 3 (6%)
Alveolar/bronchiolar carcinoma, multiple | 2 (4%) | 1 (2%) | – | –
Hemangiosarcoma | 1 (2%) | – | – | –
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | 5 (10%)
Hepatoblastoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 5 (10%) | 5 (10%) | 5 (10%) | 8 (16%)
Hepatocholangiocarcinoma, metastatic, liver | 2 (4%) | 1 (2%) | – | –
Mediastinum, sarcoma, metastatic, skin | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Mast cell tumor malignant | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenocarcinoma | 1 (2%) | 3 (6%) | – | –
Adenoma | 5 (10%) | 4 (8%) | 4 (8%) | 8 (16%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Mast cell tumor malignant | – | – | 1 (2%) | –
Renal tubule, adenoma | – | – | – | 1 (2%)
Urethra | (0) | (0) | (0) | (1)
Urinary bladder | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 1 (2%) | –
Lymphoma malignant | 6 (12%) | 1 (2%) | 5 (10%) | 3 (6%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 44 | 47 | 46 | 49
Total primary neoplasms | 78 | 82 | 86 | 106
Total animals with benign neoplasms | 32 | 28 | 35 | 34
Total benign neoplasms | 44 | 41 | 50 | 45
Total animals with malignant neoplasms | 25 | 32 | 27 | 44
Total malignant neoplasms | 34 | 41 | 36 | 61
Total animals with metastatic neoplasms | 9 | 8 | 6 | 16
Total metastatic neoplasms | 47 | 12 | 8 | 24
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Harderian Gland: Adenoma
Overall rate^a^ | 5/50 (10%) | 4/50 (8%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate^b^ | 10.7% | 8.4% | 8.9% | 18.9%
Terminal rate^c^ | 3/40 (8%) | 4/40 (10%) | 3/35 (9%) | 6/28 (21%)
First incidence (days) | 640 | 729 (T) | 631 | 643
Poly-3 test^d^ | P = 0.125 | P = 0.491N | P = 0.526N | P = 0.216
Harderian Gland: Adenocarcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 2.2% | 6.3% | 0.0% | 0.0%
Terminal rate | 1/40 (3%) | 2/40 (5%) | 0/35 (0%) | 0/28 (0%)
First incidence (days) | 729 (T) | 721 | –^e^ | –
Poly-3 test | P = 0.166N | P = 0.315 | P = 0.508N | P = 0.520N
Harderian Gland: Adenoma or Adenocarcinoma
Overall rate | 6/50 (12%) | 7/50 (14%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate | 12.9% | 14.8% | 8.9% | 18.9%
Terminal rate | 4/40 (10%) | 6/40 (15%) | 3/35 (9%) | 6/28 (21%)
First incidence (days) | 640 | 721 | 631 | 643
Poly-3 test | P = 0.302 | P = 0.512 | P = 0.396N | P = 0.314
Small Intestine: Adenoma or Adenocarcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.2% | 0.0% | 2.3% | 7.0%
Terminal rate | 1/40 (3%) | 0/40 (0%) | 1/35 (3%) | 2/28 (7%)
First incidence (days) | 729 (T) | – | 729 (T) | 415
Poly-3 test | P = 0.084 | P = 0.495N | P = 0.752 | P = 0.277
Liver: Hepatocellular Adenoma
Overall rate | 25/50 (50%) | 24/50 (48%) | 31/50 (62%) | 29/50 (58%)
Adjusted rate | 53.0% | 50.2% | 68.1% | 64.3%
Terminal rate | 23/40 (58%) | 21/40 (53%) | 27/35 (77%) | 18/28 (64%)
First incidence (days) | 424 | 660 | 551 | 477
Poly-3 test | P = 0.079 | P = 0.473N | P = 0.096 | P = 0.181
Liver: Hepatocellular Carcinoma
Overall rate | 8/50 (16%) | 19/50 (38%) | 16/50 (32%) | 35/50 (70%)
Adjusted rate | 17.0% | 38.6% | 34.1% | 75.3%
Terminal rate | 6/40 (15%) | 12/40 (30%) | 8/35 (23%) | 22/28 (79%)
First incidence (days) | 488 | 605 | 523 | 548
Poly-3 test | P < 0.001 | P = 0.015 | P = 0.046 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 30/50 (60%) | 36/50 (72%) | 40/50 (80%) | 48/50 (96%)
Adjusted rate | 62.6% | 72.9% | 84.3% | 98.6%
Terminal rate | 26/40 (65%) | 27/40 (68%) | 30/35 (86%) | 28/28 (100%)
First incidence (days) | 424 | 605 | 523 | 477
Poly-3 test | P < 0.001 | P = 0.189 | P = 0.011 | P < 0.001
Liver: Hepatoblastoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 15/50 (30%)
Adjusted rate | 2.1% | 2.1% | 2.3% | 34.6%
Terminal rate | 0/40 (0%) | 1/40 (3%) | 1/35 (3%) | 8/28 (29%)
First incidence (days) | 591 | 729 (T) | 729 (T) | 638
Poly-3 test | P < 0.001 | P = 0.757N | P = 0.749 | P < 0.001
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 9/50 (18%) | 20/50 (40%) | 16/50 (32%) | 41/50 (82%)
Adjusted rate | 19.0% | 40.6% | 34.1% | 86.4%
Terminal rate | 6/40 (15%) | 13/40 (33%) | 8/35 (23%) | 24/28 (86%)
First incidence (days) | 488 | 605 | 523 | 548
Poly-3 test | P < 0.001 | P = 0.016 | P = 0.074 | P < 0.001
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 31/50 (62%) | 37/50 (74%) | 40/50 (80%) | 48/50 (96%)
Adjusted rate | 64.1% | 74.9% | 84.3% | 98.6%
Terminal rate | 26/40 (65%) | 28/40 (70%) | 30/35 (86%) | 28/28 (100%)
First incidence (days) | 424 | 605 | 523 | 477
Poly-3 test | P < 0.001 | P = 0.169 | P = 0.017 | P < 0.001
Liver: Hepatocholangiocarcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 6.3% | 4.2% | 0.0% | 0.0%
Terminal rate | 0/40 (0%) | 1/40 (3%) | 0/35 (0%) | 0/28 (0%)
First incidence (days) | 591 | 531 | – | –
Poly-3 test | P = 0.044N | P = 0.495N | P = 0.131N | P = 0.143N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 11/50 (22%) | 11/50 (22%) | 9/50 (18%) | 3/50 (6%)
Adjusted rate | 23.8% | 23.2% | 20.1% | 7.2%
Terminal rate | 10/40 (25%) | 11/40 (28%) | 8/35 (23%) | 3/28 (11%)
First incidence (days) | 723 | 729 (T) | 647 | 729 (T)
Poly-3 test | P = 0.023N | P = 0.570N | P = 0.433N | P = 0.031N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 6/50 (12%) | 4/50 (8%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 13.0% | 8.4% | 6.8% | 7.1%
Terminal rate | 6/40 (15%) | 3/40 (8%) | 3/35 (9%) | 2/28 (7%)
First incidence (days) | 729 (T) | 698 | 729 (T) | 632
Poly-3 test | P = 0.229N | P = 0.352N | P = 0.262N | P = 0.289N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 17/50 (34%) | 14/50 (28%) | 11/50 (22%) | 6/50 (12%)
Adjusted rate | 36.8% | 29.5% | 24.6% | 14.2%
Terminal rate | 16/40 (40%) | 13/40 (33%) | 10/35 (29%) | 5/28 (18%)
First incidence (days) | 723 | 698 | 647 | 632
Poly-3 test | P = 0.009N | P = 0.297N | P = 0.150N | P = 0.013N
Spleen: Hemangiosarcoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.2% | 4.2% | 6.7% | 2.4%
Terminal rate | 1/40 (3%) | 2/40 (5%) | 2/35 (6%) | 1/28 (4%)
First incidence (days) | 729 (T) | 729 (T) | 647 | 729 (T)
Poly-3 test | P = 0.564 | P = 0.509 | P = 0.294 | P = 0.738
All Organs: Hemangiosarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 4.3% | 6.3% | 11.2% | 4.8%
Terminal rate | 1/40 (3%) | 3/40 (8%) | 4/35 (11%) | 2/28 (7%)
First incidence (days) | 424 | 729 (T) | 647 | 729 (T)
Poly-3 test | P = 0.490 | P = 0.504 | P = 0.196 | P = 0.651
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 6/50 (12%) | 2/50 (4%)
Adjusted rate | 4.3% | 6.3% | 13.4% | 4.8%
Terminal rate | 1/40 (3%) | 3/40 (8%) | 5/35 (14%) | 2/28 (7%)
First incidence (days) | 424 | 729 (T) | 647 | 729 (T)
Poly-3 test | P = 0.460 | P = 0.504 | P = 0.117 | P = 0.651
All Organs: Malignant Lymphoma
Overall rate | 6/50 (12%) | 1/50 (2%) | 5/50 (10%) | 3/50 (6%)
Adjusted rate | 12.7% | 2.1% | 11.1% | 7.0%
Terminal rate | 3/40 (8%) | 0/40 (0%) | 3/35 (9%) | 0/28 (0%)
First incidence (days) | 612 | 691 | 551 | 606
Poly-3 test | P = 0.396N | P = 0.055N | P = 0.533N | P = 0.293N
All Organs: Benign Neoplasms
Overall rate | 32/50 (64%) | 28/50 (56%) | 35/50 (70%) | 34/50 (68%)
Adjusted rate | 67.4% | 58.6% | 76.3% | 74.8%
Terminal rate | 28/40 (70%) | 25/40 (63%) | 29/35 (83%) | 22/28 (79%)
First incidence (days) | 424 | 660 | 551 | 477
Poly-3 test | P = 0.113 | P = 0.246N | P = 0.227 | P = 0.282
All Organs: Malignant Neoplasms
Overall rate | 25/50 (50%) | 32/50 (64%) | 27/50 (54%) | 44/50 (88%)
Adjusted rate | 50.0% | 64.0% | 56.0% | 90.2%
Terminal rate | 15/40 (38%) | 22/40 (55%) | 16/35 (46%) | 24/28 (86%)
First incidence (days) | 424 | 531 | 444 | 415
Poly-3 test | P < 0.001 | P = 0.113 | P = 0.348 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 44/50 (88%) | 47/50 (94%) | 46/50 (92%) | 49/50 (98%)
Adjusted rate | 88.0% | 94.0% | 94.6% | 99.0%
Terminal rate | 34/40 (85%) | 37/40 (93%) | 33/35 (94%) | 28/28 (100%)
First incidence (days) | 424 | 531 | 444 | 415
Poly-3 test | P = 0.021 | P = 0.243 | P = 0.207 | P = 0.030

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 30/50 | 15/50 | 2/50 | 39/50
2,3-Butanedione (August 2009) | 17/50 | 17/50 | 1/50 | 32/50
p-Chloro-α,α,α-trifluorotoluene (January 2011) | 25/50 | 8/50 | 1/50 | 31/50
CIMSTAR 3800 (May 2008) | 24/50 | 11/50 | 0/50 | 32/50
Cobalt metal (May 2006) | 28/50 | 25/50 | 2/50 | 39/50
TRIM VX (August 2009) | 23/50 | 21/50 | 0/50 | 34/50
Total (%) | 147/300 (49.0%) | 97/300 (32.3%) | 6/300 (2.0%) | 207/300 (69.0%)
Mean ± standard deviation | 49.0% ± 9.0% | 32.3% ± 12.6% | 2.0% ± 1.8% | 69.0% ± 7.2%
Range | 34%–60% | 16%–50% | 0%–4% | 62%–78%
Overall Historical Incidence: All Routes
Total (%) | 302/550 (54.9%) | 165/550 (30.0%) | 18/550 (3.3%) | 395/550 (71.8%)
Mean ± standard deviation | 54.9% ± 12.4% | 30.0% ± 10.0% | 3.3% ± 2.4% | 71.8% ± 8.1%
Range | 34%–78% | 16%–50% | 0%–8% | 62%–84%

^a^ Data as of August 2016.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 8 | 5 | 11 | 12
Natural deaths | 2 | 5 | 4 | 10
Survivors
Terminal kill | 40 | 40 | 35 | 28
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (50) | (49) | (44) | (44)
Inflammation | – | 1 (2%) | – | –
Epithelium, vacuolization cytoplasmic | – | 1 (2%) | 1 (2%) | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | 2 (4%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (49)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Necrosis | – | – | 1 (2%) | –
Thrombosis | – | – | 1 (2%) | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Perforation | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia | – | – | 1 (2%) | 1 (2%)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Perforation | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia | 1 (2%) | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Basophilic focus | 4 (8%) | 10 (20%) | 10 (20%) | 1 (2%)
Clear cell focus | 15 (30%) | 16 (32%) | 23 (46%) | 15 (30%)
Cyst | – | 1 (2%) | – | –
Eosinophilic focus | 11 (22%) | 14 (28%) | 18 (36%) | 21 (42%)
Fatty change | – | – | 1 (2%) | –
Fibrosis | – | – | 1 (2%) | –
Hepatodiaphragmatic nodule | – | – | 1 (2%) | –
Inflammation | 3 (6%) | 1 (2%) | – | –
Intrahepatocellular erythrocytes | – | 1 (2%) | 6 (12%) | 15 (30%)
Mixed cell focus | 15 (30%) | 15 (30%) | 13 (26%) | 11 (22%)
Pigmentation | – | 1 (2%) | – | –
Regeneration | 2 (4%) | – | – | –
Centrilobular, hepatocyte, hypertrophy | – | 8 (16%) | 19 (38%) | 49 (98%)
Hepatocyte, multinucleated | 2 (4%) | 8 (16%) | 19 (38%) | 49 (98%)
Hepatocyte, necrosis | 3 (6%) | 4 (8%) | 3 (6%) | 15 (30%)
Mesentery | (6) | (5) | (2) | (5)
Angiectasis | – | 1 (20%) | – | –
Thrombosis | – | 1 (20%) | – | –
Fat, necrosis | 4 (67%) | 2 (40%) | 1 (50%) | 4 (80%)
Pancreas | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | – | – | –
Acinus, atrophy | 1 (2%) | – | 2 (4%) | 3 (6%)
Acinus, hypertrophy | – | 1 (2%) | – | –
Duct, cyst | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (49)
Atrophy | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (48)
Inflammation | 4 (8%) | 12 (24%) | 7 (14%) | 12 (25%)
Mineralization | 2 (4%) | – | 1 (2%) | 1 (2%)
Epithelium, cyst, squamous | – | – | – | 1 (2%)
Epithelium, hyperplasia | 5 (10%) | 9 (18%) | 9 (18%) | 10 (21%)
Epithelium, ulcer | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Stomach, glandular | (50) | (50) | (49) | (49)
Hyperplasia | – | – | – | 1 (2%)
Inflammation | 1 (2%) | | 1 (2%) | 2 (4%)
Mineralization | – | 1 (2%) | – | 2 (4%)
Tongue | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | – | – | 2 (4%) | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 10 (20%) | 14 (28%) | 13 (26%) | 11 (22%)
Inflammation | 1 (2%) | 1 (2%) | 3 (6%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Hyperplasia | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Hypertrophy | 20 (40%) | 34 (68%) | 24 (48%) | 17 (34%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Islets, pancreatic | (50) | (49) | (50) | (50)
Hyperplasia | 4 (8%) | 1 (2%) | 5 (10%) | –
Necrosis | 1 (2%) | – | – | –
Parathyroid gland | (36) | (28) | (39) | (38)
Pituitary gland | (50) | (50) | (50) | (49)
Thyroid gland | (50) | (50) | (50) | (50)
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Exfoliated germ cell | 1 (2%) | 4 (8%) | – | 2 (4%)
Granuloma sperm | 2 (4%) | 2 (4%) | 1 (2%) | 2 (4%)
Penis | (0) | (0) | (1) | (0)
Congestion | – | – | 1 (100%) | –
Preputial gland | (50) | (50) | (49) | (50)
Ectasia | 2 (4%) | 5 (10%) | 6 (12%) | 4 (8%)
Inflammation | 2 (4%) | 1 (2%) | 2 (4%) | –
Prostate | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | 1 (2%) | 1 (2%)
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | 1 (2%) | 2 (4%) | –
Inflammation | – | – | 2 (4%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Germinal epithelium, degeneration | 7 (14%) | 10 (20%) | 10 (20%) | 8 (16%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | 1 (2%) | –
Fibrosis | – | – | 1 (2%) | –
Hyperplasia | 24 (48%) | 26 (52%) | 27 (54%) | 27 (54%)
Necrosis | – | – | – | 1 (2%)
Lymph node | (4) | (0) | (3) | (4)
Pancreatic, angiectasis | – | – | – | 1 (25%)
Lymph node, bronchial | (49) | (47) | (47) | (48)
Ectasia | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | –
Lymph node, mandibular | (36) | (41) | (43) | (45)
Hyperplasia, lymphoid | 2 (6%) | 1 (2%) | – | –
Lymph node, mediastinal | (46) | (47) | (44) | (42)
Necrosis, fatty | – | 1 (2%) | – | –
Lymph node, mesenteric | (49) | (50) | (49) | (49)
Angiectasis | 1 (2%) | – | – | 1 (2%)
Ectasia | 1 (2%) | – | – | –
Hematopoietic cell proliferation | – | 2 (4%) | 1 (2%) | –
Hyperplasia, lymphoid | 3 (6%) | 2 (4%) | – | 1 (2%)
Infiltration cellular, histiocyte | – | – | 2 (4%) | –
Inflammation | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 17 (34%) | 16 (32%) | 10 (20%) | 18 (36%)
Lymphoid follicle, hyperplasia | 8 (16%) | 4 (8%) | 6 (12%) | 4 (8%)
Red pulp, infiltration cellular, mast cell | – | – | 1 (2%) | –
Thymus | (48) | (48) | (48) | (48)
Atrophy | 21 (44%) | 20 (42%) | 15 (31%) | 22 (46%)
Ectopic parathyroid gland | 12 (25%) | 9 (19%) | 15 (31%) | 9 (19%)
Integumentary System
Mammary gland | (2) | (1) | (3) | (1)
Skin | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 2 (4%) | 1 (2%) | 3 (6%)
Ulcer | – | – | 1 (2%) | 3 (6%)
Epidermis, hyperplasia | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 2 (4%) | – | 2 (4%) | 2 (4%)
Skeletal muscle | (2) | (1) | (1) | (2)
Degeneration | – | – | 1 (100%) | –
Inflammation | – | – | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Degeneration | – | – | 2 (4%) | –
Gliosis | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | 2 (4%) | –
Peripheral nerve | (0) | (0) | (1) | (0)
Degeneration | – | – | 1 (100%) | –
Spinal cord | (0) | (0) | (1) | (0)
Inflammation | – | – | 1 (100%) | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Epiglottis, inflammation | – | – | 1 (2%) | –
Squamous epithelium, hyperplasia | 3 (6%) | 4 (8%) | 6 (12%) | 11 (22%)
Squamous epithelium, inflammation | – | 1 (2%) | 3 (6%) | 2 (4%)
Squamous epithelium, necrosis | – | – | – | 1 (2%)
Squamous epithelium, ulcer | – | – | 1 (2%) | 2 (4%)
Lung | (50) | (50) | (50) | (50)
Hemorrhage | 2 (4%) | – | 1 (2%) | –
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Inflammation | – | 2 (4%) | – | 2 (4%)
Metaplasia, osseous | – | – | 1 (2%) | –
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Thrombosis | – | 2 (4%) | 1 (2%) | 1 (2%)
Alveolar/bronchiolar epithelium, hyperplasia | – | 49 (98%) | 50 (100%) | 48 (96%)
Alveolar epithelium, hyperplasia | 2 (4%) | 1 (2%) | 1 (2%) | 3 (6%)
Alveolus, infiltration cellular, histiocyte | 2 (4%) | 2 (4%) | 3 (6%) | 3 (6%)
Bronchiole, epithelium, hyperplasia | 2 (4%) | – | – | –
Peribronchiolar, fibrosis | – | 45 (90%) | 47 (94%) | 44 (88%)
Pleura, inflammation | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Inflammation, suppurative | 1 (2%) | 3 (6%) | 5 (10%) | 4 (8%)
Necrosis | – | – | – | 1 (2%)
Polyp, inflammatory | – | – | 1 (2%) | –
Olfactory epithelium, accumulation, hyaline droplet | 11 (22%) | 9 (18%) | 7 (14%) | 13 (26%)
Olfactory epithelium, atrophy | – | – | 1 (2%) | –
Olfactory epithelium, hyperplasia | – | – | 1 (2%) | –
Olfactory epithelium, mineralization | – | 1 (2%) | – | –
Respiratory epithelium, accumulation, hyaline droplet | 9 (18%) | 8 (16%) | 3 (6%) | 12 (24%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | 2 (4%) | 1 (2%)
Turbinate, atrophy | – | – | – | 1 (2%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | 2 (4%)
Cataract | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation | – | 3 (6%) | 1 (2%) | 1 (2%)
Cornea, hyperplasia | 2 (4%) | – | – | –
Retina, pigmentation, melanin | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 5 (10%) | 1 (2%) | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | 1 (2%) | 2 (4%)
Infarct | 6 (12%) | 4 (8%) | 6 (12%) | 4 (8%)
Metaplasia, osseous | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Nephropathy | 43 (86%) | 41 (82%) | 38 (76%) | 41 (82%)
Pigmentation | – | 1 (2%) | – | 4 (8%)
Pelvis, dilatation | – | – | – | 1 (2%)
Urethra | (0) | (0) | (0) | (1)
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.