# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 22 | 27 | 18 | 18
Natural deaths | 5 | 1 | 7 | 2
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 22 | 21 | 25 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (49) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Leiomyoma | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Cholangiocarcinoma | – | 2 (4%) | – | –
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocellular adenoma | 2 (4%) | 2 (4%) | 1 (2%) | 4 (8%)
Hepatocellular carcinoma | – | – | 1 (2%)
Mesentery | (1) | (1) | (1) | (2)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (50%)
Schwannoma malignant, metastatic, skeletal muscle | – | 1 (100%) | – | –
Yolk sac carcinoma, metastatic, ovary | – | – | 1 (100%) | –
Pancreas | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Acinus, adenoma | – | 1 (2%) | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tooth | (0) | (1) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | 2 (4%) | 1 (2%)
Capsule, schwannoma malignant, metastatic, skeletal muscle | – | 1 (2%) | – | –
Adrenal medulla | (49) | (50) | (50) | (50)
Pheochromocytoma benign | – | 3 (6%) | 4 (8%) | 6 (12%)
Pheochromocytoma malignant | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Carcinoma | 1 (2%) | – | – | –
Parathyroid gland | (45) | (44) | (48) | (42)
Adenoma | – | – | 2 (4%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 18 (36%) | 14 (28%) | 16 (32%) | 5 (10%)
Pars intermedia, adenoma | – | – | – | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, c-cell, adenoma | – | – | – | 3 (6%)
C-cell, adenoma | 2 (4%) | 8 (16%) | 8 (16%) | 11 (22%)
C-cell, carcinoma | – | 2 (4%) | – | 1 (2%)
Follicular cell, adenoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (49) | (50)
Adenoma | – | – | 1 (2%) | –
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor benign | 3 (6%) | – | – | –
Granulosa-theca tumor benign | – | – | 1 (2%) | –
Thecoma benign | 1 (2%) | – | – | –
Yolk sac carcinoma | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | 1 (2%) | 1 (2%) | – | 5 (10%)
Adenoma | – | 1 (2%) | – | –
Leiomyosarcoma | – | – | – | 1 (2%)
Polyp stromal | 7 (14%) | 7 (14%) | 12 (24%) | 10 (20%)
Polyp stromal, multiple | – | 1 (2%) | 4 (8%) | 2 (4%)
Sarcoma stromal | – | – | 1 (2%)
Schwannoma malignant | – | – | – | 1 (2%)
Squamous cell carcinoma | 1 (2%) | – | – | –
Yolk sac carcinoma, metastatic, ovary | – | – | 1 (2%) | –
Cervix, polyp stromal | – | 1 (2%) | – | –
Vagina | (46) | (48) | (48) | (38)
Granular cell tumor benign | 1 (2%) | 2 (4%) | – | –
Paraganglioma | – | – | 1 (2%) | –
Schwannoma malignant | 1 (2%) | – | 1 (2%) | 1 (3%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (6) | (5) | (3)
Deep cervical, carcinoma, metastatic, thyroid gland | – | – | – | 1 (33%)
Lymph node, bronchial | (32) | (27) | (22) | (20)
Lymph node, mandibular | (49) | (50) | (50) | (50)
Lymph node, mediastinal | (50) | (50) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Carcinoma, metastatic, thyroid gland | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, skeletal muscle | – | 1 (2%) | – | –
Yolk sac carcinoma, metastatic, ovary | – | – | 1 (2%) | –
Thymus | (50) | (48) | (49) | (49)
Thymoma benign | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenocarcinoma | 5 (10%) | 3 (6%) | 3 (6%) | 1 (2%)
Adenocarcinoma, multiple | – | 1 (2%) | – | –
Adenoma | 4 (8%) | 4 (8%) | – | 1 (2%)
Fibroadenoma | 17 (34%) | 20 (40%) | 20 (40%) | 13 (26%)
Fibroadenoma, multiple | 3 (6%) | 8 (16%) | 11 (22%) | 5 (10%)
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | – | – | – | 1 (2%)
Sebaceous gland, adenoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibroma | – | 1 (2%) | – | –
Subcutaneous tissue, fibrous histiocytoma | – | 1 (2%) | – | –
Subcutaneous tissue, hibernoma | – | – | 1 (2%) | –
Subcutaneous tissue, lipoma | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (3) | (6) | (1) | (3)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (33%)
Lipoma | – | – | – | 1 (33%)
Liposarcoma | 1 (33%) | – | – | –
Schwannoma malignant | – | 1 (17%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | 1 (2%) | 1 (2%) | – | –
Granular cell tumor benign | – | 1 (2%) | – | –
Cranial nerve, schwannoma malignant | 1 (2%) | 1 (2%) | – | –
Peripheral nerve | (1) | (4) | (2) | (1)
Spinal cord | (1) | (4) | (1) | (1)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Basal cell carcinoma, metastatic, skin | 1 (2%) | – | – | –
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | | 1 (2%)
Cystic keratinizing epithelioma | – | 1 (2%) | 1 (2%) | –
Fibrous histiocytoma, metastatic, skin | – | 1 (2%) | – | –
Yolk sac carcinoma, metastatic, ovary | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Schwannoma malignant | – | – | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (0) | (1) | (1) | (2)
Carcinoma | – | 1 (100%) | – | 1 (50%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Renal tubule, adenoma | 1 (2%) | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | – | – | 2 (4%) | –
Lymphoma malignant | – | – | 1 (2%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 41 | 42 | 43 | 42
Total primary neoplasms | 73 | 96 | 98 | 83
Total animals with benign neoplasms | 39 | 42 | 41 | 38
Total benign neoplasms | 60 | 80 | 86 | 70
Total animals with malignant neoplasms | 11 | 13 | 12 | 12
Total malignant neoplasms | 13 | 16 | 12 | 13
Total animals with metastatic neoplasms | 1 | 3 | 1 | 2
Total metastatic neoplasms | 1 | 5 | 4 | 10

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 0/49 (0%) | 3/50 (6%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate^b^ | 0.0% | 8.1% | 9.9% | 13.5%
Terminal rate^c^ | 0/21 (0%) | 2/21 (10%) | 2/25 (8%) | 4/30 (13%)
First incidence (days) | –^e^ | 691 | 478 | 530
Poly-3 test^d^ | P = 0.066 | P = 0.135 | P = 0.085 | P = 0.035
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 0/49 (0%) | 4/50 (8%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate | 0.0% | 10.7% | 9.9% | 13.5%
Terminal rate | 0/21 (0%) | 3/21 (14%) | 2/25 (8%) | 4/30 (13%)
First incidence (days) | – | 691 | 478 | 530
Poly-3 test | P = 0.106 | P = 0.071 | P = 0.085 | P = 0.035
Liver: Hepatocellular Adenoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 5.7% | 5.3% | 2.5% | 9.1%
Terminal rate | 2/22 (9%) | 0/21 (0%) | 1/25 (4%) | 3/30 (10%)
First incidence (days) | 731 (T) | 648 | 731 (T) | 642
Poly-3 test | P = 0.256 | P = 0.668N | P = 0.457N | P = 0.446
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 5.7% | 5.3% | 5.1% | 9.1%
Terminal rate | 2/22 (9%) | 0/21 (0%) | 2/25 (8%) | 3/30 (10%)
First incidence (days) | 731 (T) | 648 | 731 (T) | 642
Poly-3 test | P = 0.298 | P = 0.668N | P = 0.650N | P = 0.446
Mammary Gland: Fibroadenoma
Overall rate | 20/50 (40%) | 28/50 (56%) | 31/50 (62%) | 18/50 (36%)
Adjusted rate | 49.6% | 62.7% | 69.3% | 38.5%
Terminal rate | 10/22 (46%) | 12/21 (57%) | 17/25 (68%) | 9/30 (30%)
First incidence (days) | 311 | 395 | 395 | 530
Poly-3 test | P = 0.015N | P = 0.149 | P = 0.041 | P = 0.202N
Mammary Gland: Adenoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 11.2% | 10.7% | 0.0% | 2.3%
Terminal rate | 2/22 (9%) | 2/21 (10%) | 0/25 (0%) | 1/30 (3%)
First incidence (days) | 459 | 646 | – | 731 (T)
Poly-3 test | P = 0.084N | P = 0.618N | P = 0.047N | P = 0.124N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 23/50 (46%) | 31/50 (62%) | 31/50 (62%) | 19/50 (38%)
Adjusted rate | 55.9% | 69.3% | 69.3% | 40.6%
Terminal rate | 11/22 (50%) | 14/21 (67%) | 17/25 (68%) | 10/30 (33%)
First incidence (days) | 311 | 395 | 395 | 530
Poly-3 test | P = 0.004N | P = 0.133 | P = 0.131 | P = 0.105N
Mammary Gland: Adenocarcinoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 13.6% | 10.7% | 7.5% | 2.3%
Terminal rate | 1/22 (5%) | 2/21 (10%) | 1/25 (4%) | 1/30 (3%)
First incidence (days) | 303 | 674 | 584 | 731 (T)
Poly-3 test | P = 0.051N | P = 0.489N | P = 0.307N | P = 0.067N
Mammary Gland: Adenoma or Adenocarcinoma
Overall rate | 9/50 (18%) | 8/50 (16%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 24.0% | 21.1% | 7.5% | 4.6%
Terminal rate | 3/22 (14%) | 4/21 (19%) | 1/25 (4%) | 2/30 (7%)
First incidence (days) | 303 | 646 | 584 | 731 (T)
Poly-3 test | P = 0.007N | P = 0.492N | P = 0.042N | P = 0.012N
Mammary Gland: Fibroadenoma, Adenoma, or Adenocarcinoma
Overall rate | 27/50 (54%) | 34/50 (68%) | 33/50 (66%) | 20/50 (40%)
Adjusted rate | 63.3% | 75.3% | 73.0% | 42.8%
Terminal rate | 12/22 (55%) | 15/21 (71%) | 18/25 (72%) | 11/30 (37%)
First incidence (days) | 303 | 395 | 395 | 530
Poly-3 test | P < 0.001N | P = 0.145 | P = 0.213 | P = 0.036N
Ovary: Benign Granulosa Cell Tumor
Overall rate | 3/50 (6%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 8.5% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/22 (9%) | 0/21 (0%) | 0/25 (0%) | 0/30 (0%)
First incidence (days) | 646 | – | – | –
Poly-3 test | P = 0.145N | P = 0.108N | P = 0.098N | P = 0.085N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 18/50 (36%) | 14/50 (28%) | 16/50 (32%) | 5/50 (10%)
Adjusted rate | 46.6% | 35.8% | 37.6% | 11.2%
Terminal rate | 7/22 (32%) | 5/21 (24%) | 7/25 (28%) | 1/30 (3%)
First incidence (days) | 528 | 643 | 541 | 626
Poly-3 test | P < 0.001N | P = 0.226N | P = 0.273N | P < 0.001N
Thyroid Gland (C-cell): Adenoma
Overall rate | 2/50 (4%) | 8/50 (16%) | 8/50 (16%) | 14/50 (28%)
Adjusted rate | 5.5% | 20.4% | 20.2% | 31.6%
Terminal rate | 0/22 (0%) | 3/21 (14%) | 8/25 (32%) | 11/30 (37%)
First incidence (days) | 459 | 534 | 731 (T) | 646
Poly-3 test | P = 0.008 | P = 0.056 | P = 0.057 | P = 0.003
Thyroid Gland (C-cell): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 10/50 (20%) | 8/50 (16%) | 15/50 (30%)
Adjusted rate | 5.5% | 25.5% | 20.2% | 33.6%
Terminal rate | 0/22 (0%) | 5/21 (24%) | 8/25 (32%) | 11/30 (37%)
First incidence (days) | 459 | 534 | 731 (T) | 646
Poly-3 test | P = 0.009 | P = 0.017 | P = 0.057 | P = 0.002
Uterus: Stromal Polyp
Overall rate | 7/50 (14%) | 9/50 (18%) | 16/50 (32%) | 12/50 (24%)
Adjusted rate | 19.6% | 23.8% | 39.3% | 27.2%
Terminal rate | 5/22 (23%) | 6/21 (29%) | 12/25 (48%) | 10/30 (33%)
First incidence (days) | 590 | 643 | 558 | 646
Poly-3 test | P = 0.419 | P = 0.440 | P = 0.047 | P = 0.298
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 17/50 (34%) | 12/50 (24%)
Adjusted rate | 19.6% | 23.8% | 41.8% | 27.2%
Terminal rate | 5/22 (23%) | 6/21 (29%) | 13/25 (52%) | 10/30 (33%)
First incidence (days) | 590 | 643 | 558 | 646
Poly-3 test | P = 0.439 | P = 0.440 | P = 0.028 | P = 0.298
Uterus: Adenocarcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 0/50 (0%) | 5/50 (10%)
Adjusted rate | 2.9% | 2.7% | 0.0% | 11.3%
Terminal rate | 1/22 (5%) | 1/21 (5%) | 0/25 (0%) | 3/30 (10%)
First incidence (days) | 731 (T) | 731 (T) | – | 530
Poly-3 test | P = 0.017 | P = 0.748N | P = 0.475N | P = 0.166
All Organs: Benign Neoplasms
Overall rate | 39/50 (78%) | 42/50 (84%) | 41/50 (82%) | 38/50 (76%)
Adjusted rate | 87.4% | 90.3% | 88.0% | 77.6%
Terminal rate | 19/22 (86%) | 18/21 (86%) | 23/25 (92%) | 22/30 (73%)
First incidence (days) | 311 | 395 | 395 | 530
Poly-3 test | P = 0.036N | P = 0.451 | P = 0.604 | P = 0.152N
All Organs: Malignant Neoplasms
Overall rate | 11/50 (22%) | 13/50 (26%) | 12/50 (24%) | 12/50 (24%)
Adjusted rate | 28.8% | 33.5% | 29.0% | 26.1%
Terminal rate | 4/22 (18%) | 7/21 (33%) | 6/25 (24%) | 5/30 (17%)
First incidence (days) | 303 | 585 | 564 | 530
Poly-3 test | P = 0.337N | P = 0.421 | P = 0.594 | P = 0.484N
All Organs: Benign or Malignant Neoplasms
Overall rate | 41/50 (82%) | 42/50 (84%) | 43/50 (86%) | 42/50 (84%)
Adjusted rate | 88.6% | 90.3% | 90.8% | 84.8%
Terminal rate | 19/22 (86%) | 18/21 (86%) | 23/25 (92%) | 23/30 (77%)
First incidence (days) | 303 | 395 | 395 | 530
Poly-3 test | P = 0.238N | P = 0.532 | P = 0.494 | P = 0.396N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, ovary, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 22 | 27 | 18 | 18
Natural deaths | 5 | 1 | 7 | 2
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 22 | 21 | 25 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (49) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Artery, inflammation | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Artery, inflammation | – | 1 (2%) | – | –
Artery, serosa, inflammation | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Artery, inflammation | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Artery, inflammation | – | 1 (2%) | – | –
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Artery, inflammation | – | 1 (2%) | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 5 (10%) | 5 (10%) | 1 (2%)
Basophilic focus | 7 (14%) | 3 (6%) | 2 (4%) | 7 (14%)
Cholangiofibrosis | 1 (2%) | – | – | –
Clear cell focus | 16 (32%) | 15 (30%) | 23 (46%) | 38 (76%)
Eosinophilic focus | 7 (14%) | 6 (12%) | 7 (14%) | 15 (30%)
Fatty change | 2 (4%) | 4 (8%) | 11 (22%) | 10 (20%)
Fibrosis | 1 (2%) | 1 (2%) | – | 1 (2%)
Hematopoietic cell proliferation | 7 (14%) | 1 (2%) | 4 (8%) | 3 (6%)
Hepatodiaphragmatic nodule | 2 (4%) | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Mixed cell focus | 6 (12%) | 6 (12%) | 8 (16%) | 18 (36%)
Pigmentation | 1 (2%) | – | – | –
Bile duct, cyst | 4 (8%) | 11 (22%) | 5 (10%) | 5 (10%)
Bile duct, cyst, multiple | 2 (4%) | – | 1 (2%) | 2 (4%)
Bile duct, dilatation | – | – | 1 (2%) | –
Bile duct, hyperplasia | 14 (28%) | 13 (26%) | 17 (34%) | 13 (26%)
Centrilobular, hepatocyte, hypertrophy | – | 1 (2%) | 10 (20%) | 45 (90%)
Hepatocyte, necrosis | 2 (4%) | – | 2 (4%) | 5 (10%)
Hepatocyte, periportal, hypertrophy | – | – | 1 (2%) | –
Serosa, inflammation, chronic active | – | – | – | 1 (2%)
Vein, thrombosis | – | – | – | 1 (2%)
Mesentery | (1) | (1) | (1) | (2)
Artery, inflammation | – | – | – | 1 (50%)
Fat, necrosis | 1 (100%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Inflammation, chronic | – | – | – | 1 (2%)
Acinus, atrophy | 2 (4%) | 4 (8%) | – | 2 (4%)
Acinus, basophilic focus | – | – | 1 (2%) | –
Acinus, hyperplasia | 1 (2%) | 1 (2%) | – | 4 (8%)
Artery, inflammation | 3 (6%) | 7 (14%) | 5 (10%) | 5 (10%)
Duct, cyst | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Parotid gland, hyperplasia | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | 2 (4%) | – | 1 (2%)
Epithelium, hyperplasia | – | – | 1 (2%) | 3 (6%)
Serosa, inflammation, chronic active | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Ectopic tissue | 1 (2%) | – | – | –
Artery, inflammation | – | – | 1 (2%) | –
Tooth | (0) | (1) | (0) | (0)
Inflammation, suppurative | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, inflammation | – | 2 (4%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 16 (32%) | 12 (24%) | 15 (30%) | 17 (34%)
Artery, inflammation | – | – | – | 1 (2%)
Lymphatic, pericardium, inflammation | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | 9 (18%) | 4 (8%) | 8 (16%) | 7 (14%)
Degeneration, cystic | 9 (18%) | 12 (24%) | 12 (24%) | 14 (28%)
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | –
Hyperplasia | 4 (8%) | 7 (14%) | 8 (16%) | 12 (24%)
Hypertrophy | 15 (30%) | 17 (34%) | 11 (22%) | 20 (40%)
Necrosis | 3 (6%) | – | 2 (4%) | 2 (4%)
Thrombosis | 4 (8%) | – | 2 (4%) | 2 (4%)
Adrenal medulla | (49) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Degeneration | 1 (2%) | – | – | –
Hyperplasia | 17 (35%) | 25 (50%) | 34 (68%) | 36 (72%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | –
Parathyroid gland | (45) | (44) | (48) | (42)
Fibrosis | – | – | 1 (2%) | 4 (10%)
Hyperplasia | – | – | 1 (2%) | 1 (2%)
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | 2 (4%)
Cyst | – | – | 1 (2%) | 1 (2%)
Pars distalis, hyperplasia | 15 (30%) | 14 (28%) | 16 (32%) | 17 (34%)
Pars distalis, vacuolization cytoplasmic | – | – | 1 (2%) | –
Pars intermedia, hyperplasia | 1 (2%) | 1 (2%) | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | 1 (2%) | – | –
Ultimobranchial cyst | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%)
Ultimobranchial cyst, multiple | – | – | 1 (2%) | –
C-cell, hyperplasia | 16 (32%) | 15 (30%) | 21 (42%) | 13 (26%)
Follicular cell, hyperplasia | – | 1 (2%) | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (49) | (50)
Cyst | 3 (6%) | 4 (8%) | 2 (4%) | 7 (14%)
Inflammation | 13 (26%) | 21 (42%) | 15 (31%) | 16 (32%)
Ovary | (50) | (50) | (50) | (50)
Cyst | 11 (22%) | 7 (14%) | 8 (16%) | 10 (20%)
Fibrosis | 1 (2%) | – | – | –
Inflammation | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | 1 (2%) | –
Artery, inflammation | 1 (2%) | 1 (2%) | – | –
Granulosa cell, hyperplasia | – | – | – | 1 (2%)
Mesothelium, hyperplasia | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenomyosis | 1 (2%) | – | 2 (4%) | 3 (6%)
Bacterium | 1 (2%) | – | – | –
Dilatation | 1 (2%) | 3 (6%) | 3 (6%) | –
Hemorrhage | 2 (4%) | – | 2 (4%) | –
Inflammation, suppurative | 1 (2%) | – | 2 (4%) | 2 (4%)
Inflammation, chronic active | 2 (4%) | 3 (6%) | 1 (2%) | –
Metaplasia, squamous | 4 (8%) | 6 (12%) | 10 (20%) | 1 (2%)
Necrosis | – | – | 1 (2%) | –
Prolapse | 1 (2%) | – | – | –
Thrombosis | – | – | 1 (2%)
Artery, inflammation, chronic | – | – | – | 1 (2%)
Artery, necrosis, fibrinoid | – | – | – | 1 (2%)
Cervix, cyst, squamous, multiple | 1 (2%) | – | – | –
Cervix, cyst, squamous | – | 1 (2%) | – | 1 (2%)
Cervix, hyperplasia, squamous | – | 2 (4%) | – | –
Cervix, hypertrophy, stromal | 1 (2%) | – | – | 1 (2%)
Endometrium, atypical hyperplasia | – | – | 1 (2%) | 3 (6%)
Endometrium, erosion | – | 1 (2%) | – | –
Endometrium, hyperplasia, cystic | 41 (82%) | 34 (68%) | 31 (62%) | 22 (44%)
Serosa, fibrosis | – | 1 (2%) | – | –
Serosa, inflammation, chronic active | – | – | – | 1 (2%)
Vagina | (46) | (48) | (48) | (38)
Cyst, squamous | – | – | 1 (2%) | –
Hyperplasia, stromal | – | 1 (2%) | – | –
Hyperplasia, granular cell | 1 (2%) | – | – | –
Inflammation, suppurative | – | 1 (2%) | 1 (2%) | 2 (5%)
Inflammation, chronic | – | – | 1 (2%) | –
Ulcer | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Lymph node | (2) | (6) | (5) | (3)
Congestion | – | 1 (17%) | – | –
Hyperplasia | – | 1 (17%) | – | –
Iliac, congestion | – | – | 1 (20%) | –
Iliac, ectasia | – | – | – | 1 (33%)
Iliac, hyperplasia | – | 1 (17%) | 2 (40%) | –
Lumbar, congestion | 1 (50%) | 1 (17%) | – | –
Lumbar, hyperplasia | – | 1 (17%) | – | –
Pancreatic, hyperplasia | – | 1 (17%) | – | –
Renal, congestion | 1 (50%) | 1 (17%) | 2 (40%) | –
Renal, ectasia | – | 1 (17%) | – | –
Lymph node, bronchial | (32) | (27) | (22) | (20)
Lymph node, mandibular | (49) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | – | –
Lymph node, mediastinal | (50) | (50) | (50) | (49)
Congestion | – | 1 (2%) | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
Artery, inflammation | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 31 (62%) | 31 (62%) | 38 (76%) | 36 (72%)
Inflammation | – | 1 (2%) | – | –
Capsule, fibrosis | – | – | – | 1 (2%)
Red pulp, infiltration cellular, histiocyte | – | – | – | 1 (2%)
Thymus | (50) | (48) | (49) | (49)
Atrophy | 44 (88%) | 44 (92%) | 43 (88%) | 48 (98%)
Cyst | 1 (2%) | – | 1 (2%) | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Cyst | – | – | 1 (2%) | 1 (2%)
Hyperplasia, cystic | 2 (4%) | 7 (14%) | 1 (2%) | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | 3 (6%) | –
Inflammation | – | – | – | 1 (2%)
Ulcer | 3 (6%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (3) | (6) | (1) | (3)
Hemorrhage | 1 (33%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Hypothalamus, compression | 7 (14%) | 7 (14%) | 6 (12%) | 1 (2%)
Unilateral, inflammation, granulomatous | – | 1 (2%) | – | –
Unilateral, necrosis | – | 1 (2%) | – | –
Peripheral nerve | (1) | (4) | (2) | (1)
Inflammation | – | – | 1 (50%) | –
Spinal cord | (1) | (4) | (1) | (1)
Cyst epithelial inclusion | – | 1 (25%) | – | –
Axon, nerve, degeneration | – | 1 (25%) | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Bacterium | – | – | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Foreign body | – | – | – | 1 (2%)
Inflammation | 1 (2%) | 2 (4%) | 2 (4%) | 4 (8%)
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Squamous epithelium, hyperplasia | 2 (4%) | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Fibrosis | 11 (22%) | 17 (34%) | 24 (48%) | 28 (56%)
Hemorrhage | 12 (24%) | 11 (22%) | 18 (36%) | 26 (52%)
Inflammation, chronic | 35 (70%) | 42 (84%) | 48 (96%) | 46 (92%)
Metaplasia, osseous | 5 (10%) | 4 (8%) | 4 (8%) | 2 (4%)
Metaplasia, squamous | 1 (2%) | 2 (4%) | 2 (4%) | –
Alveolar epithelium, hyperplasia | 2 (4%) | – | 1 (2%) | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 35 (70%) | 31 (62%) | 36 (72%) | 33 (66%)
Artery, mediastinum, inflammation, chronic | – | – | – | 1 (2%)
Artery, mediastinum, necrosis, fibrinoid | – | – | – | 1 (2%)
Bronchiole, hyperplasia | – | – | 1 (2%) | –
Mediastinum, inflammation, chronic | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | – | 1 (2%) | – | 1 (2%)
Inflammation | 2 (4%) | 3 (6%) | 6 (12%) | 2 (4%)
Inflammation, acute | – | 1 (2%) | – | –
Nasopharyngeal duct, inflammation, suppurative | – | – | 1 (2%) | –
Olfactory epithelium, accumulation, hyaline droplet | 40 (80%) | 36 (72%) | 40 (80%) | 30 (60%)
Olfactory epithelium, degeneration | – | 1 (2%) | 2 (4%) | –
Olfactory epithelium, hemorrhage | – | – | – | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | 1 (2%)
Respiratory epithelium, inflammation | – | – | – | 1 (2%)
Sinus, polyp, inflammatory | 1 (2%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cornea, inflammation | 1 (2%) | 1 (2%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | 2 (4%) | – | – | 1 (2%)
Hyperplasia | – | – | – | 3 (6%)
Inflammation | 1 (2%) | 1 (2%) | 4 (8%) | 2 (4%)
Zymbal’s gland | (0) | (1) | (1) | (2)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Infarct | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Nephropathy | 44 (88%) | 49 (98%) | 49 (98%) | 47 (94%)
Artery, inflammation | – | – | – | 1 (2%)
Interstitium, inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Pelvis, inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Renal tubule, hyperplasia | – | – | 2 (4%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Polyp, inflammatory | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.