# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 16 | 19 | 21 | 27
Natural deaths | 9 | 10 | 14 | 18
Survivors
Terminal kill | 25 | 21 | 15 | 5
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Leiomyoma | 1 (2%) | – | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Adenocarcinoma | – | 1 (2%) | – | –
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Adenocarcinoma | – | 2 (4%) | 1 (2%) | –
Leiomyosarcoma | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | – | 1 (2%) | – | –
Hepatocellular carcinoma | – | 2 (4%) | – | 1 (2%)
Schwannoma malignant, metastatic, heart | – | – | – | 1 (2%)
Mesentery | (2) | (2) | (1) | (1)
Pancreas | (50) | (50) | (50) | (50)
Acinus, adenoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | 2 (4%) | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (0) | (1) | (0) | (0)
Tooth | (1) | (0) | (0) | (0)
Odontoma | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (50)
Heart | (50) | (50) | (50) | (50)
Sarcoma | – | – | – | 1 (2%)
Endocardium, schwannoma malignant | – | – | 1 (2%) | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | 1 (2%) | – | 1 (2%)
Carcinoma | – | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 8 (16%) | 8 (16%) | 12 (24%) | 10 (20%)
Pheochromocytoma malignant | 2 (4%) | – | 2 (4%) | 2 (4%)
Bilateral, pheochromocytoma benign | 4 (8%) | 5 (10%) | 4 (8%) | 2 (4%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 8 (16%) | 5 (10%) | 2 (4%) | –
Carcinoma | – | 4 (8%) | – | 1 (2%)
Parathyroid gland | (48) | (48) | (48) | (46)
Adenoma | – | – | – | 2 (4%)
Carcinoma, metastatic, thyroid gland | – | – | – | 1 (2%)
Pituitary gland | (50) | (50) | (49) | (50)
Carcinoma, metastatic, Zymbal’s gland | | 1 (2%) | – | –
Pars distalis, adenoma | 11 (22%) | 6 (12%) | 7 (14%) | 6 (12%)
Pars intermedia, adenoma | – | – | – | 1 (2%)
Thyroid gland | (50) | (49) | (49) | (50)
Bilateral, C-cell, adenoma | | 1 (2%) | 1 (2%) | 1 (2%)
C-cell, adenoma | 2 (4%) | 4 (8%) | 2 (4%) | 11 (22%)
C-cell, carcinoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Follicular cell, adenoma | – | – | 1 (2%) | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Epididymis | (50) | (50) | (50) | (50)
Sarcoma | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Carcinoma | – | – | 1 (2%) | –
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | – | 2 (4%) | 2 (4%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (7) | (7) | (10) | (4)
Lymph node, bronchial | (30) | (26) | (29) | (26)
Lymph node, mandibular | (50) | (50) | (50) | (50)
Lymph node, mediastinal | (50) | (49) | (50) | (50)
Lymph node, mesenteric | (49) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Thymus | (48) | (50) | (48) | (49)
Integumentary System
Mammary gland | (43) | (38) | (38) | (37)
Adenoma | – | 1 (3%) | – | –
Fibroadenoma | 2 (5%) | 1 (3%) | 2 (5%) | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | – | – | 2 (4%) | –
Keratoacanthoma | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Keratoacanthoma, multiple | 1 (2%) | – | 1 (2%) | –
Squamous cell papilloma | 1 (2%) | 2 (4%) | – | 1 (2%)
Sebaceous gland, adenoma | 1 (2%) | 2 (4%) | 2 (4%) | –
Subcutaneous tissue, fibroma | – | 4 (8%) | 2 (4%) | –
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, hemangioma | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, lipoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | – | – | 2 (4%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | – | – | 1 (2%) | –
Skeletal muscle | (7) | (6) | (4) | (2)
Hemangiosarcoma | – | 1 (17%) | – | –
Schwannoma malignant | – | 1 (17%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | 2 (4%) | 1 (2%) | 1 (2%) | –
Peripheral nerve | (7) | (5) | (4) | (2)
Spinal cord | (7) | (5) | (4) | (2)
Schwannoma malignant, metastatic, skeletal muscle | – | 1 (20%) | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 2 (4%) | – | 1 (2%)
Alveolar/bronchiolar carcinoma | – | – | – | 2 (4%)
Carcinoma, metastatic, lung | 1 (2%) | – | – | –
Carcinoma, metastatic, salivary glands | – | 1 (2%) | – | –
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (2%) | –
Artery, schwannoma malignant, metastatic, heart | – | – | – | 1 (2%)
Mediastinum, paraganglioma | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Iris, leiomyoma | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (50) | (50)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%)
Zymbal’s gland | (1) | (2) | (0) | (0)
Adenoma | – | 1 (50%) | – | –
Carcinoma | 1 (100%) | 1 (50%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Lipoma | – | – | 1 (2%) | –
Renal tubule, adenoma | – | – | 2 (4%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Urothelium, papilloma | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 1 (2%) | –
Leukemia granulocytic | 1 (2%) | – | – | –
Leukemia mononuclear | 3 (6%) | 2 (4%) | – | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | –
Mesothelioma malignant | 1 (2%) | – | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 37 | 41 | 39 | 35
Total primary neoplasms | 62 | 70 | 62 | 51
Total animals with benign neoplasms | 30 | 32 | 32 | 30
Total benign neoplasms | 48 | 53 | 48 | 41
Total animals with malignant neoplasms | 12 | 16 | 12 | 10
Total malignant neoplasms | 14 | 17 | 14 | 10
Total animals with metastatic neoplasms | 1 | 3 | 1 | 3
Total metastatic neoplasms | 1 | 4 | 1 | 4

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Adrenal Cortex: Adenoma
Overall rate^a^ | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate^b^ | 7.5% | 2.7% | 0.0% | 3.2%
Terminal rate^c^ | 1/25 (4%) | 1/21 (5%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | 516 | 729 (T) | –^e^ | 645
Poly-3 test^d^ | P = 0.390N | P = 0.329N | P = 0.129N | P = 0.400N
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 12/50 (24%) | 13/50 (26%) | 16/50 (32%) | 12/50 (24%)
Adjusted rate | 29.7% | 32.5% | 37.9% | 35.0%
Terminal rate | 8/25 (32%) | 6/21 (29%) | 4/15 (27%) | 2/5 (40%)
First incidence (days) | 374 | 485 | 500 | 476
Poly-3 test | P = 0.392 | P = 0.489 | P = 0.288 | P = 0.403
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 14/50 (28%) | 13/50 (26%) | 18/50 (36%) | 14/50 (28%)
Adjusted rate | 34.2% | 32.5% | 42.1% | 39.7%
Terminal rate | 9/25 (36%) | 6/21 (29%) | 4/15 (27%) | 2/5 (40%)
First incidence (days) | 374 | 485 | 500 | 476
Poly-3 test | P = 0.321 | P = 0.531N | P = 0.296 | P = 0.395
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 0.0% | 7.9% | 0.0% | 3.2%
Terminal rate | 0/25 (0%) | 2/21 (10%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 631 | – | 612
Poly-3 test | P = 0.653 | P = 0.111 | –^f^ | P = 0.455
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 5.3% | 0.0% | 9.3%
Terminal rate | 0/25 (0%) | 1/21 (5%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 650 | – | 516
Poly-3 test | P = 0.073 | P = 0.228 | – | P = 0.086
Pancreatic Islets: Adenoma
Overall rate | 8/50 (16%) | 5/50 (10%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 19.8% | 13.2% | 5.2% | 0.0%
Terminal rate | 4/25 (16%) | 4/21 (19%) | 1/15 (7%) | 0/5 (0%)
First incidence (days) | 533 | 655 | 607 | –
Poly-3 test | P = 0.008N | P = 0.316N | P = 0.052N | P = 0.011N
Pancreatic Islets: Carcinoma
Overall rate | 0/50 (0%) | 4/50 (8%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 0.0% | 10.6% | 0.0% | 3.2%
Terminal rate | 0/25 (0%) | 3/21 (14%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 674 | – | 686
Poly-3 test | P = 0.569N | P = 0.054 | – | P = 0.453
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 9/50 (18%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 19.8% | 23.7% | 5.2% | 3.2%
Terminal rate | 4/25 (16%) | 7/21 (33%) | 1/15 (7%) | 0/5 (0%)
First incidence (days) | 533 | 655 | 607 | 686
Poly-3 test | P = 0.012N | P = 0.443 | P = 0.052N | P = 0.041N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 11/50 (22%) | 6/50 (12%) | 7/49 (14%) | 6/50 (12%)
Adjusted rate | 28.0% | 15.8% | 18.8% | 18.1%
Terminal rate | 10/25 (40%) | 4/21 (19%) | 5/15 (33%) | 1/5 (20%)
First incidence (days) | 723 | 607 | 717 | 430
Poly-3 test | P = 0.333N | P = 0.150N | P = 0.245N | P = 0.233N
Skin: Keratoacanthoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 7.6% | 5.3% | 5.3% | 9.3%
Terminal rate | 2/25 (8%) | 2/21 (10%) | 2/15 (13%) | 1/5 (20%)
First incidence (days) | 618 | 729 (T) | 729 (T) | 467
Poly-3 test | P = 0.426 | P = 0.525N | P = 0.523N | P = 0.563
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 10.1% | 8.0% | 5.3% | 9.3%
Terminal rate | 2/25 (8%) | 3/21 (14%) | 2/15 (13%) | 1/5 (20%)
First incidence (days) | 618 | 729 (T) | 729 (T) | 467
Poly-3 test | P = 0.599N | P = 0.530N | P = 0.359N | P = 0.614N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Basal Cell Adenoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 10.1% | 8.0% | 10.6% | 9.3%
Terminal rate | 2/25 (8%) | 3/21 (14%) | 4/15 (27%) | 1/5 (20%)
First incidence (days) | 618 | 729 (T) | 729 (T) | 467
Poly-3 test | P = 0.592 | P = 0.530N | P = 0.617 | P = 0.614N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 0/50 (0%) | 4/50 (8%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 10.6% | 5.2% | 0.0%
Terminal rate | 0/25 (0%) | 3/21 (14%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 680 | 590 | –
Poly-3 test | P = 0.299N | P = 0.054 | P = 0.233 | –
Skin (Subcutaneous Tissue): Fibroma or Fibrous Histiocytoma
Overall rate | 1/50 (2%) | 5/50 (10%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 2.5% | 12.9% | 5.2% | 0.0%
Terminal rate | 0/25 (0%) | 3/21 (14%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | 584 | 318 | 590 | –
Poly-3 test | P = 0.167N | P = 0.093 | P = 0.490 | P = 0.550N
Small Intestine (Duodenum or Jejunum): Adenocarcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.9% | 2.6% | 0.0%
Terminal rate | 0/25 (0%) | 2/21 (10%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | – | 525 | 611 | –
Poly-3 test | P = 0.350N | P = 0.113 | P = 0.494 | –
Thyroid Gland (C-cell): Adenoma
Overall rate | 2/50 (4%) | 5/49 (10%) | 3/49 (6%) | 12/50 (24%)
Adjusted rate | 5.1% | 13.4% | 7.9% | 36.3%
Terminal rate | 2/25 (8%) | 4/21 (19%) | 1/15 (7%) | 3/5 (60%)
First incidence (days) | 729 (T) | 680 | 669 | 568
Poly-3 test | P < 0.001 | P = 0.192 | P = 0.482 | P < 0.001
Thyroid Gland (C-cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 5/49 (10%) | 4/49 (8%) | 13/50 (26%)
Adjusted rate | 7.6% | 13.4% | 10.6% | 39.2%
Terminal rate | 3/25 (12%) | 4/21 (19%) | 1/15 (7%) | 3/5 (60%)
First incidence (days) | 729 (T) | 680 | 669 | 568
Poly-3 test | P < 0.001 | P = 0.326 | P = 0.481 | P < 0.001
All Organs: Mononuclear Cell Leukemia
Overall rate | 3/50 (6%) | 2/50 (4%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 7.5% | 5.3% | 0.0% | 3.2%
Terminal rate | 0/25 (0%) | 0/21 (0%) | 0/15 (0%) | 0/5 (0%)
First incidence (days) | 590 | 710 | – | 589
Poly-3 test | P = 0.316N | P = 0.530N | P = 0.129N | P = 0.399N
All Organs: Benign Neoplasms
Overall rate | 30/50 (60%) | 32/50 (64%) | 32/50 (64%) | 30/50 (60%)
Adjusted rate | 68.2% | 76.0% | 71.6% | 73.0%
Terminal rate | 17/25 (68%) | 18/21 (86%) | 12/15 (80%) | 5/5 (100%)
First incidence (days) | 374 | 485 | 500 | 430
Poly-3 test | P = 0.477 | P = 0.273 | P = 0.452 | P = 0.394
All Organs: Malignant Neoplasms
Overall rate | 12/50 (24%) | 16/50 (32%) | 12/50 (24%) | 10/50 (20%)
Adjusted rate | 27.2% | 38.3% | 29.6% | 28.9%
Terminal rate | 1/25 (4%) | 8/21 (38%) | 3/15 (20%) | 0/5 (0%)
First incidence (days) | 374 | 306 | 463 | 528
Poly-3 test | P = 0.458N | P = 0.189 | P = 0.500 | P = 0.534
All Organs: Benign or Malignant Neoplasms
Overall rate | 37/50 (74%) | 41/50 (82%) | 39/50 (78%) | 35/50 (70%)
Adjusted rate | 79.2% | 88.5% | 84.0% | 81.4%
Terminal rate | 18/25 (72%) | 19/21 (91%) | 13/15 (87%) | 5/5 (100%)
First incidence (days) | 374 | 306 | 463 | 430
Poly-3 test | P = 0.475N | P = 0.158 | P = 0.360 | P = 0.502

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, lung, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of p-Chloro-α,α,α-trifluorotoluene^a^

| Chamber Control | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 16 | 19 | 21 | 27
Natural deaths | 9 | 10 | 14 | 18
Survivors
Terminal kill | 25 | 21 | 15 | 5
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation, acute | – | 1 (2%) | – | –
Artery, inflammation | 1 (2%) | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Serosa, inflammation | 1 (2%) | – | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Peyer’s patch, hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Intestine small, ileum | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Artery, inflammation | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (2%) | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Artery, inflammation | 1 (2%) | – | – | 1 (2%)
Peyer’s patch, hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 3 (6%)
Basophilic focus | 2 (4%) | 3 (6%) | 4 (8%) | 2 (4%)
Cholangiofibrosis | – | – | – | 1 (2%)
Clear cell focus | 40 (80%) | 31 (62%) | 29 (58%) | 10 (20%)
Degeneration, cystic | – | 2 (4%) | 1 (2%) | 1 (2%)
Eosinophilic focus | 1 (2%) | 5 (10%) | 6 (12%) | 8 (16%)
Fatty change | – | 3 (6%) | 7 (14%) | 26 (52%)
Hematopoietic cell proliferation | 1 (2%) | 1 (2%) | 1 (2%) | –
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Hepatodiaphragmatic nodule | 2 (4%) | – | – | –
Hyperplasia, nodular | 1 (2%) | – | – | –
Hypertrophy | – | – | – | 1 (2%)
Inflammation, chronic active | 2 (4%) | 1 (2%) | –
Mixed cell focus | 2 (4%) | 6 (12%) | 3 (6%) | 2 (4%)
Vacuolization cytoplasmic | – | 1 (2%) | – | –
Bile duct, cyst | – | 1 (2%) | 2 (4%) | –
Bile duct, hyperplasia | 32 (64%) | 26 (52%) | 24 (48%) | 23 (46%)
Centrilobular, hepatocyte, hypertrophy | 2 (4%) | 17 (34%) | 39 (78%) | 47 (94%)
Centrilobular, hepatocyte, necrosis | – | – | 1 (2%) | 2 (4%)
Hepatocyte, degeneration | 1 (2%) | – | – | –
Hepatocyte, necrosis | 3 (6%) | 3 (6%) | 4 (8%) | 4 (8%)
Mesentery | (2) | (2) | (1) | (1)
Artery, inflammation | – | – | – | 1 (100%)
Fat, necrosis | 1 (50%) | 2 (100%) | 1 (100%) | –
Pancreas | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Acinus, atrophy | 8 (16%) | 6 (12%) | 6 (12%) | 4 (8%)
Acinus, hyperplasia | 7 (14%) | 11 (22%) | 12 (24%) | 11 (22%)
Acinus, vacuolization cytoplasmic | – | – | – | 1 (2%)
Artery, inflammation | 17 (34%) | 19 (38%) | 19 (38%) | 19 (38%)
Duct, cyst | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Atrophy, focal | – | – | – | 1 (2%)
Inflammation | – | – | 2 (4%) | 1 (2%)
Parotid gland, atrophy | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | 2 (4%) | – | 1 (2%)
Mineralization | – | 1 (2%) | – | –
Ulcer | – | 1 (2%) | – | 4 (8%)
Epithelium, hyperplasia | 1 (2%) | 4 (8%) | – | 4 (8%)
Stomach, glandular | (50) | (50) | (50) | (50)
Mineralization | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Ulcer | 1 (2%) | 1 (2%) | – | –
Tongue | (0) | (1) | (0) | (0)
Artery, inflammation | – | 1 (100%) | – | –
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (50)
Aorta, inflammation | 1 (2%) | – | – | –
Aorta, mineralization | 3 (6%) | 1 (2%) | 2 (4%) | 3 (6%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 41 (82%) | 39 (78%) | 45 (90%) | 40 (80%)
Congestion | – | – | 1 (2%) | –
Atrium, thrombosis | – | 2 (4%) | 1 (2%) | 4 (8%)
Atrium, myocardium, inflammation | – | – | 1 (2%) | –
Epicardium, inflammation | 1 (2%) | – | – | –
Myocardium, mineralization | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Degeneration, cystic | 9 (18%) | 5 (10%) | 10 (20%) | 6 (12%)
Hyperplasia | 11 (22%) | 15 (30%) | 19 (38%) | 8 (16%)
Hypertrophy | 18 (36%) | 11 (22%) | 13 (26%) | 14 (28%)
Necrosis | – | 2 (4%) | 2 (4%) | 2 (4%)
Thrombosis | – | 2 (4%) | 1 (2%) | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | 1 (2%) | – | –
Zona fasciculata, atrophy | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 28 (56%) | 37 (74%) | 35 (70%) | 30 (60%)
Necrosis | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Parathyroid gland | (48) | (48) | (48) | (46)
Hyperplasia | 4 (8%) | 1 (2%) | 4 (8%) | 1 (2%)
Hyperplasia, focal | – | – | – | 1 (2%)
Pituitary gland | (50) | (50) | (49) | (50)
Angiectasis | – | 1 (2%) | 1 (2%) | –
Cyst | 2 (4%) | 3 (6%) | 5 (10%) | 1 (2%)
Pars distalis, hyperplasia | 13 (26%) | 15 (30%) | 12 (24%) | 8 (16%)
Pars distalis, necrosis | – | – | 1 (2%) | –
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (49) | (50)
Ultimobranchial cyst | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Ultimobranchial cyst, multiple | 1 (2%) | – | – | –
C-cell, hyperplasia | 16 (32%) | 12 (24%) | 14 (29%) | 15 (30%)
Follicular cell, hyperplasia | 1 (2%) | 1 (2%) | | 1 (2%)
Follicular cell, hypertrophy | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Inflammation | 1 (100%) | – | – | –
Epididymis | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Artery, inflammation | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%)
Preputial gland | (50) | (50) | (50) | (50)
Cyst | 4 (8%) | 2 (4%) | 3 (6%) | 1 (2%)
Inflammation | 26 (52%) | 26 (52%) | 14 (28%) | 17 (34%)
Prostate | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Inflammation | 1 (2%) | 5 (10%) | 1 (2%) | 2 (4%)
Seminal vesicle | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Inflammation | 3 (6%) | 2 (4%) | – | 2 (4%)
Testes | (50) | (50) | (50) | (50)
Artery, inflammation | 22 (44%) | 26 (52%) | 25 (50%) | 28 (56%)
Germinal epithelium, atrophy | 5 (10%) | 6 (12%) | 12 (24%) | 6 (12%)
Interstitial cell, hyperplasia | 1 (2%) | 1 (2%) | – | 2 (4%)
Tunic, inflammation | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | –
Lymph node | (7) | (7) | (10) | (4)
Axillary, congestion | – | 1 (14%) | – | –
Deep cervical, hyperplasia | 1 (14%) | – | – | –
Iliac, ectasia | – | – | 1 (10%) | –
Iliac, hyperplasia | 1 (14%) | – | – | –
Inguinal, ectasia | – | 1 (14%) | – | –
Lumbar, congestion | – | 1 (14%) | – | –
Lumbar, ectasia | – | 1 (14%) | – | –
Lumbar, hyperplasia | – | 1 (14%) | – | –
Renal, congestion | 1 (14%) | 4 (57%) | 9 (90%) | 3 (75%)
Renal, ectasia | – | 2 (29%) | – | –
Renal, hyperplasia | 1 (14%) | – | – | –
Lymph node, bronchial | (30) | (26) | (29) | (26)
Lymph node, mandibular | (50) | (50) | (50) | (50)
Congestion | – | 1 (2%) | 2 (4%) | 1 (2%)
Ectasia | – | – | 1 (2%) | 1 (2%)
Hyperplasia | 3 (6%) | 1 (2%) | 1 (2%) | –
Lymph node, mediastinal | (50) | (49) | (50) | (50)
Congestion | 3 (6%) | 2 (4%) | 5 (10%) | 8 (16%)
Hyperplasia | – | 1 (2%) | 1 (2%) | –
Lymph node, mesenteric | (49) | (50) | (50) | (50)
Congestion | 1 (2%) | 2 (4%) | – | –
Hemorrhage | – | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 29 (58%) | 30 (60%) | 30 (60%) | 22 (44%)
Hemorrhage | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | – | –
Lymphoid follicle, hyperplasia | – | – | 1 (2%) | –
Red pulp, congestion | – | 1 (2%) | – | 1 (2%)
Thymus | (48) | (50) | (48) | (49)
Atrophy | 45 (94%) | 44 (88%) | 46 (96%) | 45 (92%)
Cyst | – | – | 1 (2%) | 1 (2%)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (43) | (38) | (38) | (37)
Skin | (50) | (50) | (50) | (50)
Cyst, squamous | 1 (2%) | – | – | –
Cyst epithelial inclusion | 3 (6%) | 4 (8%) | 4 (8%) | 3 (6%)
Edema | – | 1 (2%) | 1 (2%) | –
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Ulcer | – | – | 1 (2%) | 3 (6%)
Sebaceous gland, cyst | – | – | 1 (2%)
Sebaceous gland, inflammation, suppurative | 1 (2%) | – | – | –
Subcutaneous tissue, fibrosis | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (7) | (6) | (4) | (2)
Degeneration | 1 (14%) | – | – | –
Inflammation | 2 (29%) | – | – | –
Regeneration | – | 1 (17%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Gliosis | 1 (2%) | – | – | –
Hemorrhage | – | – | – | 1 (2%)
Artery, inflammation | – | 1 (2%) | – | –
Cerebellum, necrosis | 1 (2%) | – | – | –
Cerebrum, necrosis | 1 (2%) | – | – | 2 (4%)
Glial cell, hyperplasia | 1 (2%) | – | – | –
Hypothalamus, compression | – | 2 (4%) | – | 1 (2%)
Unilateral, compression | – | – | 1 (2%) | –
Peripheral nerve | (7) | (5) | (4) | (2)
Axon, degeneration | 3 (43%) | – | – | –
Spinal cord | (7) | (5) | (4) | (2)
Axon, degeneration | – | 1 (20%) | – | –
Nerve, gliosis | 1 (14%) | – | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Inflammation | 5 (10%) | 6 (12%) | 6 (12%) | 4 (8%)
Metaplasia, squamous | – | – | 1 (2%) | –
Lung | (50) | (50) | (50) | (50)
Edema | – | 1 (2%) | 1 (2%) | –
Fibrosis | 8 (16%) | 22 (44%) | 28 (56%) | 24 (48%)
Foreign body | – | – | – | 2 (4%)
Hemorrhage | 11 (22%) | 23 (46%) | 28 (56%) | 28 (56%)
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Inflammation, chronic | 32 (64%) | 42 (84%) | 47 (94%) | 45 (90%)
Metaplasia, osseous | 12 (24%) | 17 (34%) | 17 (34%) | 9 (18%)
Alveolar epithelium, hyperplasia | 1 (2%) | 2 (4%) | – | –
Alveolus, infiltration cellular, histiocyte | 27 (54%) | 26 (52%) | 27 (54%) | 22 (44%)
Bronchiole, inflammation, suppurative | – | – | – | 1 (2%)
Mediastinum, hemorrhage | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Exudate | 8 (16%) | 12 (24%) | 12 (24%) | 18 (36%)
Foreign body | – | 1 (2%) | – | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | 2 (4%) | – | – | –
Nasopharyngeal duct, inflammation, suppurative | – | – | – | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 37 (74%) | 31 (62%) | 34 (68%) | 30 (60%)
Olfactory epithelium, degeneration | 1 (2%) | – | 2 (4%) | 2 (4%)
Olfactory epithelium, inflammation | – | – | – | 1 (2%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Special Senses System
Eye | (50) | (50) | (50) | (50)
Degeneration | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | – | –
Anterior chamber, inflammation, suppurative | 1 (2%) | 1 (2%) | – | –
Cornea, hyperplasia | – | – | 1 (2%) | –
Cornea, inflammation | 4 (8%) | 5 (10%) | 9 (18%) | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | – | 2 (4%) | 1 (2%) | –
Hyperplasia | 1 (2%) | – | – | –
Inflammation | – | 3 (6%) | 1 (2%) | 2 (4%)
Zymbal’s gland | (1) | (2) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | 3 (6%) | 2 (4%) | 2 (4%) | 3 (6%)
Hemorrhage | 1 (2%) | – | – | –
Infarct | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Nephropathy | 49 (98%) | 49 (98%) | 50 (100%) | 50 (100%)
Thrombosis | – | – | – | 1 (2%)
Pelvis, dilatation | – | 2 (4%) | – | –
Renal tubule, mineralization | 1 (2%) | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | – | 2 (4%) | – | –
Necrosis | – | 1 (2%) | – | –
Ulcer | 1 (2%) | – | – | 1 (2%)
Urothelium, hyperplasia | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.