# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-593

Report Series: NTP Technical Report Series

Report Series Number: 593

Official citation: National Toxicology Program (NTP). 2018. NTP technical report on the toxicology and carcinogenesis studies of 2,3-butanedione (CASRN 431-03-8) in Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 593.