# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of 2,3-Butanedione (CASRN 431-03-8) in Wistar Han [Crl:WI (Han)] Rats and B6C3F1/N Mice (Inhalation Studies) on July 13, 2017, are listed below. Panel members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, panel members had five major responsibilities in reviewing the NTP studies:

• to ascertain that all relevant literature data have been adequately cited and interpreted,

• to determine if the design and conditions of the NTP studies were appropriate,

• to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,

• to judge the significance of the experimental results by scientific criteria, and

• to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Russell C. Cattley, V.M.D., Ph.D., Chairperson
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama, USA
- Michael W. Conner, D.V.M.
  Global Blood Therapeutics, Inc.
  San Francisco, California, USA
- Noël Dybdal, D.V.M., Ph.D.
  Genetech
  San Francisco, California, USA
- Terry Gordon, Ph.D.
  New York University School of Medicine
  New York, New York, USA
- Gabriele Ludewig, Ph.D.
  The University of Iowa College of Public Health
  Iowa City, Iowa, USA
- Kristini K. Miles, Ph.D.
  Kimberly-Clark Corporation
  Roswell, Georgia, USA
- Richard A. Peterson, II, D.V.M., Ph.D.
  AbbVie
  Chicago, Illinois, USA