# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted the results and reported findings in the technical report
  D.L. Morgan, Ph.D., Study Scientist
  G.P. Flake, M.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, B.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  H.N. Moore, Ph.D., 2-year Study Director
  S.J. Harbo, D.V.M., 3-month Study Director
  S.L. Grumbein, D.V.M., Ph.D.
  B.K. Hayden
  K.M. Patton, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  R.A. Miller, D.V.M., Ph.D.
  C.C. Shackelford, D.V.M., Ph.D.
- Pathology Associates International, a Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  C.L. Johnson, D.V.M., coordinated 2-year rats (March 3, 2015)
  L.H. Kooistra, D.V.M., Ph.D., coordinated 2-year mice (November 18, 2014)