# References

1 Hazardous Substances Data Bank (HSDB). Diacetyl. 2016. https://pubchem.ncbi.nlm.nih.gov/compound/650 [Accessed: June 23, 2016]
2 Selfridge TB, Amerine MA. Odor thresholds and interactions of ethyl acetate and diacetyl in an artificial wine medium. Am J Enol Vitic. 1978; 29(1):1–6.
3 Smit G, Smit BA, Engels WJ. Flavour formation by lactic acid bacteria and biochemical flavour profiling of cheese products. FEMS Microbiol Rev. 2005; 29(3):591–610. 10.1016/j.fmrre.2005.04.002 15935512
4 Milesi MM, Wolf IV, Bergamini CV, Hynes ER. Two strains of nonstarter lactobacilli increased the production of flavor compounds in soft cheeses. J Dairy Sci. 2010; 93(11):5020–5031. 10.3168/jds.2009-3043 20965316
5 National Toxicology Program (NTP). Chemical information review document for artificial butter flavoring and constituents diacetyl (CAS No. 431-03-8) and acetoin (CAS No. 513-86-0). Research Triangle Park, NC: U.S Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2007. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/artificial_butter_flavoring_508be.pdf
6 Eriks K, Hayden TD, Hsi Yang S, Chan IY. Crystal and molecular structure of biacetyl (2,3-butanedione), (H3CCO) 2, at -12 and-100 °C. J Am Chem Soc. 1983; 105(12):3940–3942.10.1021/ja00350a032
7 Flavor & Extract Manufacturers Association (FEMA). Respiratory health and safety in the flavor manufacturing workplace, 2012 update. 2012. https://www.femaflavor.org/sites/default/files/2018-06/FEMA%202012%20Respiratory%20Health%20and%20Safety%20in%20Workplace.pdf [Accessed: June 30, 2016]
8 United States Environmental Protection Agency (USEPA). Benchmark Dose Software (BMDS). 2011. https://www.epa.gov/ncea/bmds/index.html [Accessed: November 28, 2016]
9 Burdock GA. Encyclopedia of food and color additives. Boca Raton, FL: CRC Press; 1996. p. 2115.
10 Rincon-Delgadillo MI, Lopez-Hernandez A, Wijaya I, Rankin SA. Diacetyl levels and volatile profiles of commercial starter distillates and selected dairy foods. J Dairy Sci. 2012; 95(3):1128–1139. 10.3168/jds.2011-4834 22365196
11 Code of Federal Regulations (CFR). 21:§184.1278.
12 Ubbink J. Flavor delivery systems. In: Kirk-Othmer Encyclopedia of Chemical Technology. Hoboken, NJ: John Wiley and Sons, Inc.; 2013. p. 1-35. 10.1002/0471238961.0612012221020209.a01.pub2
13 National Institute for Occupational Safety and Health (NIOSH). Occupational exposure to 2,3-butanedione and 2,3-pentanedione. pp. 20, 213, 214. Draft Report. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2011.
14 Saraiva MA, Borges CM, Florêncio MH. Non‐enzymatic model glycation reactions—A comprehensive study of the reactivity of a modified arginine with aldehydic and diketonic dicarbonyl compounds by electrospray mass spectrometry. J Mass Spectrom. 2006; 41(6):755–770. 10.1002/jms.1031 16646000
15 Egilman DS, Schilling JH. Bronchiolitis obliterans and consumer exposure to butter-flavored microwave popcorn: A case series. Int J Occup Environ Health. 2012; 18(1):29–42. 10.1179/1077352512Z.0000000005 22550695
16 Pierce JS, Abelmann A, Spicer LJ, Adams RE, Finley BL. Diacetyl and 2,3-pentanedione exposures associated with cigarette smoking: Implications for risk assessment of food and flavoring workers. Crit Rev Toxicol. 2014; 44(5):420–435. 10.3109/10408444.2014.882292 24635357
17 Etter JF, Zäther E, Svensson S. Analysis of refill liquids for electronic cigarettes. Addiction. 2013; 108(9):1671–1679. 10.1111/add.12235 23701634
18 Farsalinos KE, Kistler KA, Gillman G, Voudris V. Evaluation of electronic cigarette liquids and aerosol for the presence of selected inhalation toxins. Nicotine Tob Res. 2014; 17(2):168–174. 10.1093/ntr/ntu176 25180080
19 Allen JG, Flanigan SS, LeBlanc M, Vallarino J, MacNaughton P, Stewart JH, Christiani DC. Flavoring chemicals in e-cigarettes: Diacetyl, 2,3-pentanedione, and acetoin in a sample of 51 products, including fruit-, candy-, and cocktail-flavored e-cigarettes. Environ Health Perspect. 2016; 124(6):733–739. 10.1289/ehp.1510185 26642857
20 Al Rashidi M, Shihadeh A, Saliba NA. Volatile aldehydes in the mainstream smoke of the narghile waterpipe. Food Chem Toxicol. 2008; 46(11):3546–3549. 10.1016/j.fct.2008.09.007 18834915
21 Shihadeh A, Salman R, Jaroudi E, Saliba N, Sepetdjian E, Blank MD, Cobb CO, Eissenberg T. Does switching to a tobacco-free waterpipe product reduce toxicant intake? A crossover study comparing CO, NO, PAH, volatile aldehydes,“tar” and nicotine yields. Food Chem Toxicol. 2012; 50(5):1494–1498. 10.1016/j.fct.2012.02.041 22406330
22 Kreiss K, Gomaa A, Kullman G, Fedan K, Simoes EJ, Enright PL. Clinical bronchiolitis obliterans in workers at a microwave-popcorn plant. N Engl J Med. 2002; 347(5):330–338. 10.1056/NEJMoa020300 12151470
23 van Rooy FG, Rooyackers JM, Prokop M, Houba R, Smit LA, Heederik DJ. Bronchiolitis obliterans syndrome in chemical workers producing diacetyl for food flavorings. Am J Respir Crit Care Med. 2007; 176(5):498–504. 10.1164/rccm.200611-1620OC 17541015
24 Parmet AJ, Von Essen S. Rapidly progressive, fixed airway obstructive disease in popcorn workers: A new occupational pulmonary illness? J Occup Environ Med. 2002; 44(3):216–218. 10.1097/00043764-200203000-00002 11911019
25 Kanwal R, Kullman G, Fedan KB, Kreiss K. Occupational lung disease risk and exposure to butter-flavoring chemicals after implementation of controls at a microwave popcorn plant. Public Health Rep. 2011; 126(4):480–494. 10.1177/003335491112600405 21800743
26 Daglia M, Papetti A, Grisoli P, Aceti C, Spini V, Dacarro C, Gazzani G. Isolation, identification, and quantification of roasted coffee antibacterial compounds. J Agric Food Chem. 2007; 55(25):10208–10213. 10.1021/jf0722607 18001036
27 Akiyama M, Murakami K, Ohtani N, Iwatsuki K, Sotoyama K, Wada A, Tokuno K, Iwabuchi H, Tanaka K. Analysis of volatile compounds released during the grinding of roasted coffee beans using solid-phase microextraction. J Agric Food Chem. 2003; 51(7):1961–1969. 10.1021/jf020724p 12643659
28 Centers for Disease Control and Prevention (CDC). Obliterative bronchiolitis in workers in a coffee-processing facility - Texas, 2008-2012. MMWR Morb Mortal Wkly Rep. 2013; 62(16):305–307. 23615673
29 Bailey RL, Cox‐Ganser JM, Duling MG, LeBouf RF, Martin SB Jr, Bledsoe TA, Green BJ, Kreiss K. Respiratory morbidity in a coffee processing workplace with sentinel obliterative bronchiolitis cases. Am J Ind Med. 2015; 58(12):1235–1245. 10.1002/ajim.22533 26523478
30 National Institute for Occupational Safety and Health (NIOSH). Flavoring-related lung disease. 2016. https://www.cdc.gov/niosh/topics/flavorings/exposure.html [Accessed: August 22, 2017]
31 National Institute for Occupational Safety and Health (NIOSH). Health Hazard Evaluation Report: Agrilink Foods Popcorn Plant, Ridgway, IL. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2003. HETA 2002-0408-2915.
32 National Institute for Occupational Safety and Health (NIOSH). Report on severe fixed obstructive lung disease in workers at a flavoring manufacturing plant: Carmi Flavor and Fragrance Company, Inc., Commerce, CA. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2007., HETA 2006-0303-3043.
33 American Conference of Governmental Industrial Hygienists (ACGIH). TLVs® and BEIs® based on the documentation of the threshold limit values for chemical substances and physical agents & biological exposure indices. Cincinnati, OH: ACGIH; 2015. p. 24.
34 National Institute for Occupational Safety and Health (NIOSH). Criteria for a recommended standard: Occupational exposure to diacetyl and 2,3 pentanedione. 2016. https://www.cdc.gov/niosh/docs/2016-111/default.html [Accessed: August 22, 2017]
35 Fennell TR, Morgan DL, Watson SL, Dhungana S, Waidyanatha S. Systemic uptake, albumin and hemoglobin binding of [14C]2,3-butanedione administered by intratracheal instillation in male Harlan Sprague Dawley rats and oropharyngeal aspiration in male B6C3F1/N mice. Chem Biol Interact. 2015;227:112–119. 10.1016/j.cbi.2014.12.029 25559854
36 Morris JB, Hubbs AF. Inhalation dosimetry of diacetyl and butyric acid, two components of butter flavoring vapors. Toxicol Sci. 2009; 108(1):173–183. 10.1093/toxsci/kfn222 18940962
37 Gloede E, Cichocki JA, Baldino JB, Morris JB. A validated hybrid computational fluid dynamics-physiologically based pharmacokinetic model for respiratory tract vapor absorption in the human and rat and its application to inhalation dosimetry of diacetyl. Toxicol Sci. 2011; 123(1):231–246. 10.1093/toxsci/kfr165 21705714
38 Gabriel MA, Jabara H, Al-Khalidi UA. Metabolism of acetoin in mammalian liver slices and extracts. Interconversion with butane-2,3-diol and biacetyl. Biochem J. 1971; 124(4):793–800. 10.1042/bj1240793 4399820
39 Montgomery JA, David F, Garneau M, Brunengraber H. Metabolism of 2,3-butanediol stereoisomers in the perfused rat liver. J Biol Chem. 1993; 268(27):20185–20190. 8376379
40 Sawada H, Hara A, Nakayama T, Seiriki K. Kinetic and structural properties of diacetyl reductase from hamster liver. J Biochem. 1985; 98(5):1349–1357. 10.1093/oxfordjournals.jbchem.a135402 3910648
41 Otsuka M, Mine T, Ohuchi E, Ohmori S. A detoxication route for acetaldehyde: Metabolism of diacetyl, acetoin, and 2,3-butanediol in liver homogenate and perfused liver of rats. J Biochem. 1996; 119(2):246–251. 10.1093/oxfordjournals.jbchem.a021230 8882713
42 Nakagawa J, Ishikura S, Asami J, Isaji T, Usami N, Hara A, Sakurai T, Tsuritani K, Oda K, Takahashi M, et al. Molecular characterization of mammalian dicarbonyl/L-xylulose reductase and its localization in kidney. J Biol Chem. 2002; 277(20):17883–17891. 10.1074/jbc.M110703200 11882650
43 Endo S, Matsunaga T, Horie K, Tajima K, Bunai Y, Carbone V, El-Kabbani O, Hara A. Enzymatic characteristics of an aldo–keto reductase family protein (AKR1C15) and its localization in rat tissues. Arch Biochem Biophys. 2007; 465(1):136–147. 10.1016/j.abb.2007.05.008 17574202
44 Colley J, Gaunt IF, Lansdown AB, Grasso P, Gangolli SD. Acute and short-term toxicity of diacetyl in rats. Food Cosmet Toxicol. 1969;7:571–580. 10.1016/S0015-6264(69)80460-8 5386601
45 Hubbs AF, Battelli LA, Goldsmith WT, Porter DW, Frazer D, Friend S, Schwegler-Berry D, Mercer RR, Reynolds JS, Grote A, et al. Necrosis of nasal and airway epithelium in rats inhaling vapors of artificial butter flavoring. Toxicol Appl Pharmacol. 2002; 185(2):128–135. 10.1006/taap.2002.9525 12490137
46 Hubbs AF, Goldsmith WT, Kashon ML, Frazer D, Mercer RR, Battelli LA, Kullman GJ, Schwegler-Berry D, Friend S, Castranova V. Respiratory toxicologic pathology of inhaled diacetyl in Sprague-Dawley rats. Toxicol Pathol. 2008; 36(2):330–344. 10.1177/0192623307312694 18474946
47 Morgan DL, Flake GP, Kirby PJ, Palmer SM. Respiratory toxicity of diacetyl in C57BL/6 mice. Toxicol Sci. 2008; 103(1):169–180. 10.1093/toxsci/kfn016 18227102
48 Sharples LD, McNeil K, Stewart S, Wallwork J. Risk factors for bronchiolitis obliterans: A systematic review of recent publications. J Heart Lung Transplant. 2002; 21(2):271–281. 10.1016/S1053-2498(01)00360-6 11834356
49 Palmer SM, Flake GP, Kelly FL, Zhang HL, Nugent JL, Kirby PJ, Foley JF, Gwinn WM, Morgan DL. Severe airway epithelial injury, aberrant repair and bronchiolitis obliterans develops after diacetyl instillation in rats. PLoS One. 2011; 6(3):e17644. 10.1371/journal.pone.0017644 21464978
50 Morgan DL, Jokinen MP, Price HC, Gwinn WM, Palmer SM, Flake GP. Bronchial and bronchiolar fibrosis in rats exposed to 2,3-pentanedione vapors: Implications for bronchiolitis obliterans in humans. Toxicol Pathol. 2012; 40(3):448–465. 10.1177/0192623311431946 22215510
51 Roberts DW, York M, Basketter DA. Structure‐activity relationships in the murine local lymph node assay for skin sensitization: Α,β‐diketones. Contact Dermat. 1999; 41(1):14–17. 10.1111/j.1600-0536.1999.tb06201.x 10416702
52 Anderson SE, Franko J, Wells J, Lukomska E, Meade BJ. Evaluation of the hypersensitivity potential of alternative butter flavorings. Food Chem Toxicol. 2013;62:373–381. 10.1016/j.fct.2013.08.053 24007741
53 Anderson SE, Wells J, Fedorowicz A, Butterworth LF, Meade B, Munson AE. Evaluation of the contact and respiratory sensitization potential of volatile organic compounds generated by simulated indoor air chemistry. Toxicol Sci. 2007; 97(2):355–363. 10.1093/toxsci/kfm043 17347135
54 Hubbs AF, Cumpston AM, Goldsmith WT, Battelli LA, Kashon ML, Jackson MC, Frazer DG, Fedan JS, Goravanahally MP, Castranova V, et al. Respiratory and olfactory cytotoxicity of inhaled 2,3-pentanedione in Sprague-Dawley rats. Am J Pathol. 2012; 181(3):829–844. 10.1016/j.ajpath.2012.05.021 22894831
55 Morgan DL, Jokinen MP, Johnson CL, Price HC, Gwinn WM, Bousquet RW, Flake GP. Chemical reactivity and respiratory toxicity of the α-diketone flavoring agents: 2,3-butanedione, 2,3-pentanedione, and 2,3-hexanedione. Toxicol Pathol. 2016; 44(5):763–783. 10.1177/0192623316638962 27025954
56 Kullman G, Boylstein R, Jones W, Piacitelli C, Pendergrass S, Kreiss K. Characterization of respiratory exposures at a microwave popcorn plant with cases of bronchiolitis obliterans. J Occup Environ Hyg. 2005; 2(3):169–178. 10.1080/15459620590923091 15764540
57 National Institute for Occupational Safety and Health (NIOSH). Health Hazard Evaluation Report: American Pop Corn Company, Sioux City, IA. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2004. HETA 2001-04112-294.
58 National Institute for Occupational Safety and Health (NIOSH). Health Hazard Evaluation Report: ConAgra Snack Foods, Marion, OH. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2004. HETA 2003-0112-2949.
59 National Institute for Occupational Safety and Health (NIOSH). Health Hazard Evaluation Report: Gilster-Mary Lee Corporation, Jasper, MO. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2006. HETA 2000-0401-2991.
60 National Institute for Occupational Safety and Health (NIOSH). Health Hazard Evaluation Report: Yatsko’s Popcorn, Sand Coulee, MT. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2007. HETA 2006-0195-3044.
61 King TE Jr. Overview of bronchiolar disorders in adults. UpToDate; 2016. https://www.uptodate.com/contents/bronchiolitis-in-adults [Accessed: July 26, 2017]
62 Stoner GD, Shimkin MB, Kniazeff AJ, Weisburger JH, Weisburger EK, Gori GB. Test for carcinogenicity of food additives and chemotherapeutic agents by the pulmonary tumor response in strain A mice. Cancer Res. 1973; 33(12):3069–3085. 4202501
63 Furihata C, Yoshida S, Matsushima T. Potential initiating and promoting activities of diacetyl and glyoxal in rat stomach mucosa. Jpn J Cancer Res. 1985; 76(9):809–814. 3932277
64 Bjeldanes LF, Chew H. Mutagenicity of 1,2-dicarbonyl compounds: Maltol, kojic acid, diacetyl and related substances. Mutat Res. 1979; 67(4):367–371. 10.1016/0165-1218(79)90034-X 384239
65 Marnett LJ, Hurd HK, Hollstein MC, Levin DE, Esterbauer H, Ames BN. Naturally occurring carbonyl compounds are mutagens Salmonella tester strain TA104. Mutat Res. 1985; 148(1-2):25–34. 10.1016/0027-5107(85)90204-0 3881660
66 Aeschbacher HU, Wolleb U, Löliger J, Spadone JC, Liardon R. Contribution of coffee aroma constituents to the mutagenicity of coffee. Food Chem Toxicol. 1989; 27(4):227–232. 10.1016/0278-6915(89)90160-9 2659457
67 Zimmermann FK, Mohr A. Formaldehyde, glyoxal, urethane, methyl carbamate, 2,3-butanedione, 2,3-hexanedione, ethyl acrylate, dibromoacetonitrile and 2-hydroxypropionitrile induce chromosome loss in Saccharomyces cerevisiae. Mutat Res. 1992; 270(2):151–166. 10.1016/0027-5107(92)90126-M 1383732
68 Tucker JD, Taylor RT, Christensen ML, Strout CL, Hanna ML, Carrano AV. Cytogenetic response to 1,2-dicarbonyls and hydrogen peroxide in Chinese hamster ovary AUXB1 cells and human peripheral lymphocytes. Mutat Res. 1989; 224(2):269–279. 10.1016/0165-1218(89)90166-3 2507914
69 Whittaker P, Clarke JJ, San RH, Begley TH, Dunkel VC. Evaluation of the butter flavoring chemical diacetyl and a fluorochemical paper additive for mutagenicity and toxicity using the mammalian cell gene mutation assay in L5178Y mouse lymphoma cells. Food Chem Toxicol. 2008; 46(8):2928–2933. 10.1016/j.fct.2008.06.001 18585428
70 Hubbs AF, Fluharty KL, Edwards RJ, Barnabei JL, Grantham JT, Palmer SM, Kelly F, Sargent LM, Reynolds SH, Mercer RR, et al. Accumulation of ubiquitin and sequestosome-1 implicate protein damage in diacetyl-induced cytotoxicity. Am J Pathol. 2016; 186(11):2887–2908. 10.1016/j.ajpath.2016.07.018 27643531
71 Mathews JM, Watson SL, Snyder RW, Burgess JP, Morgan DL. Reaction of the butter flavorant diacetyl (2,3-butanedione) with N-α-acetylarginine: A model for epitope formation with pulmonary proteins in the etiology of obliterative bronchiolitis. J Agric Food Chem. 2010; 58(24):12761–12768. 10.1021/jf103251w 21077678
72 Kelly FL, Sun J, Fischer BM, Voynow JA, Kummarapurugu AB, Zhang HL, Nugent JL, Beasley RF, Martinu T, Gwinn WM, et al. Diacetyl induces amphiregulin shedding in pulmonary epithelial cells and in experimental bronchiolitis obliterans. Am J Respir Cell Mol Biol. 2014; 51(4):568–574. 10.1165/rcmb.2013-0339OC 24816162
73 Morgan DL, Merrick BA, Gerrish KE, Stockton PS, Wang Y, Foley JF, Gwinn WM, Kelly FL, Palmer SM, Ton TV-T, et al. Gene expression in obliterative bronchiolitis-like lesions in 2,3-pentanedione-exposed rats. PLoS One. 2015; 10(2):e0118459. 10.1371/journal.pone.0118459 25710175
74 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):1079-1083. 10.1093/ajcp/20.11_ts.1079
75 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
76 Boorman GA, Montgomery CAJ, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman H, Weisburger E, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
77 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
78 More SS, Vartak AP, Vince R. The butter flavorant, diacetyl, exacerbates β-amyloid cytotoxicity. Chem Res Toxicol. 2012; 25(10):2083–2091. 10.1021/tx3001016 22731744
79 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481.10.1080/01621459.1958.10501452
80 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
81 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690.10.1093/biomet/62.3.679
82 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, UK: Chapman and Hall; 1997.
83 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
84 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
85 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
86 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
87 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
88 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
89 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
90 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
91 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
92 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
93 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145.10.2307/2333011
94 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill Book Company, Inc.; 1957. p. 276–278, 412.
95 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200.10.1177/009286159202600210
96 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59. 10.1006/rtph.1995.1009 7784636
97 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
98 Code of Federal Regulations (CFR). 21:Part 58.
99 Schmid W. The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
100 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the US Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
101 Miller J, Miller E. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt H, Watson J, Winsten J, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
102 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
103 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman M, Flamm W, Lorentzen R, editors. Advances in Modern Environmental Toxicology: Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co., Inc.; 1985. p. 13–59.
104 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
105 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
106 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16(S18):1-14. 10.1002/em.2850160502
107 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three‐exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutag. 1993; 21(2):160-179. 10.1002/em.2850210210
108 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutag. 1995; 25(4):302-313. 10.1002/em.2850250407
109 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
110 Yankeelov JA Jr. Modification of arginine in proteins by oligomers of 2,3-butanedione. Biochemistry. 1970; 9(12):2433–2439. 10.1021/bi00814a007 5463664
111 Jabeen R, Mohammad AA, Elefano EC, Petersen JR, Saleemuddin M. Antibodies and Fab fragments protect Cu, Zn-SOD against methylglyoxal-induced inactivation. Biochim Biophys Acta, Gen Subj. 2006; 1760(8):1167–1174. 10.1016/j.bbagen.2006.04.002 16740365
112 Riordan JF. Functional arginyl residues in carboxypeptidase A. Modification with butanedione. Biochemistry. 1973; 12(20):3915–3923. 10.1021/bi00744a020 4355543
113 Zakim D, Hochman Y, Kenney WC. Evidence for an active site arginine in UDP-glucuronyltransferase. J Biol Chem. 1983; 258(10):6430–6434. 6406480
114 Zeng J, Davies MJ. Protein and low molecular mass thiols as targets and inhibitors of glycation reactions. Chem Res Toxicol. 2006; 19(12):1668–1676. 10.1021/tx0602158 17173381
115 Zeng J, Dunlop RA, Rodgers KJ, Davies MJ. Evidence for inactivation of cysteine proteases by reactive carbonyls via glycation of active site thiols. Biochem J. 2006; 398(2):197–206. 10.1042/BJ20060019 16671891
116 Oya T, Hattori N, Mizuno Y, Miyata S, Maeda S, Osawa T, Uchida K. Methylglyoxal modification of protein chemical and immunochemical characterization of methylglyoxal-arginine adducts. J Biol Chem. 1999; 274(26):18492–18502. 10.1074/jbc.274.26.18492 10373458
117 Riley ML, Harding JJ. The reaction of methylglyoxal with human and bovine lens proteins. Biochim Biophys Acta Mol Basis Dis. 1995; 1270(1):36–43. 10.1016/0925-4439(94)00069-3 7827133
118 Ahmed N, Thornalley PJ. Quantitative screening of protein biomarkers of early glycation, advanced glycation, oxidation and nitrosation in cellular and extracellular proteins by tandem mass spectrometry multiple reaction monitoring. Biochem Soc Trans. 2003; 31(Pt 6):1417–1422. 10.1042/bst0311417 14641078
119 Daigaku Y, Davies AA, Ulrich HD. Ubiquitin-dependent DNA damage bypass is separable from genome replication. Nature. 2010; 465(7300):951–955. 10.1038/nature09097 20453836
120 Dantuma NP, Groothuis TA, Salomons FA, Neefjes J. A dynamic ubiquitin equilibrium couples proteasomal activity to chromatin remodeling. J Cell Biol. 2006; 173(1):19–26. 10.1083/jcb.200510071 16606690
121 Haschek WM, Witschi HR, Nikula KJ. Respiratory system. In: Haschek W, Rousseaux C, Wallig M, editors. Fundamentals of Toxicologic Pathology. 2nd ed. New York, NY: Academic Press; 2010. p. 93–133.10.1016/B978-0-12-370469-6.00006-4
122 Herbert RA, Leininger JR. Nose, larynx, and trachea. In: Maronpot R, Boorman G, Gaul B, editors. Pathology of the Mouse. Vienna, IL: Cache River Press; 1999. p. 290.
123 O’Koren EG, Hogan BL, Gunn MD. Loss of basal cells precedes bronchiolitis obliterans–like pathological changes in a murine model of chlorine gas inhalation. Am J Respir Cell Mol Biol. 2013; 49(5):788–797. 10.1165/rcmb.2012-0369OC 23742075
124 Flake GP, Morgan DL. Pathology of diacetyl and 2,3-pentanedione airway lesions in a rat model of obliterative bronchiolitis. Toxicology. 2017;388:40–47. 10.1016/j.tox.2016.10.013 27984136
125 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of chloroprene (CAS No. 126-99-8) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 467. NIH Publication No. 98-3957.
126 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of furfuryl alcohol (CAS No. 98-00-0) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 482. NIH Publication No. 99-3972.
127 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of ozone (CAS No. 10028-15-6) and ozone/NNK (CAS No. 10028-15-6/64091-91-4) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1994. Technical Report Series No. 440. NIH Publication No. 95-3371.
128 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of vinylidene chloride (CAS No. 75-35-4) in F344/N rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2015. Technical Report Series No. 582.
129 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of tetrahydrofuran (CAS No. 109-99-9) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 475. NIH Publication No. 98-3965.
130 Babu AN, Nicolls MR. Critical pathways leading to obliterative bronchiolitis in lung allografts. Curr Opin Organ Transplant. 2006; 11(5):483–489.10.1097/01.mot.0000244650.00717.9c
131 Morgan K. Nasal dosimetry, lesion distribution, and the toxicological pathologist: A brief review. In: Miller F, editor. Nasal Toxicity and Dosimetry of Inhaled Xenobiotics: Implications for Human Health. Washington, DC: Taylor and Francis; 1995. p. 41–57.
132 Jiang XZ, Buckley LA, Morgan KT. Pathology of toxic responses to the RD50 concentration of chlorine gas in the nasal passages of rats and mice. Toxicol Appl Pharmacol. 1983; 71(2):225–236. 10.1016/0041-008X(83)90339-3 6636187
133 Monticello TM, Morgan KT. Cell proliferation and formaldehyde‐induced respiratory carcinogenesis. Risk Anal. 1994; 14(3):313–319. 10.1111/j.1539-6924.1994.tb00246.x 8029503
134 Broderson JR, Lindsey JR, Crawford JE. The role of environmental ammonia in respiratory mycoplasmosis of rats. Am J Pathol. 1976; 85(1):115–130. 970435
135 Kruysse A, Feron VJ, Til HP. Repeated exposure to acetaldehyde vapor: Studies in Syrian golden hamsters. Arch Environ Health. 1975; 30(9):449–452. 10.1080/00039896.1975.10666748 1164047
136 Cassee FR, Groten JP, Feron VJ. Changes in the nasal epithelium of rats exposed by inhalation to mixtures of formaldehyde, acetaldehyde, and acrolein. Fundam Appl Toxicol. 1996; 29(2):208–218. 10.1006/faat.1996.0024 8742318
137 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethylamine (CAS No. 109-89-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 566. NIH Publication No. 12-5908.
138 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of propargyl alcohol (CAS No. 107-19-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2008. Technical Report Series No. 552. NIH Publication No. 08-5893.
139 Haseman JK, Clark AM, Holden HE. Carcinogenicity results for 114 laboratory animal studies used to assess the predictivity of four in vitro genetic toxicity assays for rodent carcinogenicity. Environ Mol Mutag. 1990; 16(S18):15-31. 10.1002/em.2850160503
140 Haseman JK, Hailey JR. An update of the National Toxicology Program database on nasal carcinogens. Mutat Res. 1997; 380(1-2):3–11. 10.1016/S0027-5107(97)00121-8 9385384
141 Feron VJ, Woutersen RA, van Garderen-Hoetmer A, Dreef-van der Meulen H. Upper respiratory tract tumors in Cpb: WU (Wistar random) rats. Environ Health Perspect. 1990;85:305–315. 10.1289/ehp.85-1568344 2384064
142 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of propylene oxide (CAS No. 75-56-9) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1985. Technical Report Series No. 267. NIH Publication No. 85 2527.
143 National Toxicology Program (NTP). Carcinogenesis bioassay of 1,2-dibromoethane (CAS No. 106-93-4) in F344 rats and B6C3F1 mice (inhalation study). Research Triangle Park, NC and Bethesda, MD: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1982. Technical Report Series No. 210. NIH Publication No. 82-1766.
144 National Toxicology Program (NTP). Carcinogenesis bioassay of 1,2-dibromo-3-chloropropane (CAS No. 96-12-8) in F344 rats and B6C3F1 mice (inhalation study). Research Triangle Park, NC and Bethesda, MD: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1982. Technical Report Series No. 206. NIH Publication No. 82-1762.
145 Reznik G. Comparative anatomy and histomorphology of the nasal and paranasal cavities in rodents. In: Reznik G, Stinson S, editors. Nasal Tumors in Animals and Man. Vol. 1. Boca Raton, FL: CRC Press; 1983. p. 35–44.
146 Morgan KT, Harkema JR. Neoplasms: Nasal neoplasia. In: Jones T, Mohr U, Hunt R, editors. Monographs on Pathology of Laboratory Animals. New York, NY: Springer-Verlag; 1996. p. 87–104.
147 International Agency for Research on Cancer (IARC). The mouse: Respiratory system and mesothelium. In: Mohr U, editor. International Classification of Rodent Tumours. Part II; 1998. p. 1–44.
148 Woutersen RA, Van Garderen‐Hoetmer A, Bruijntjes JP, Zwart A, Feron VJ. Nasal tumours in rats after severe injury to the nasal mucosa and prolonged exposure to 10 ppm formaldehyde. J Appl Toxicol. 1989; 9(1):39–46. 10.1002/jat.2550090108 2926095
149 Nelson N, Levine RJ, Albert RE, Blair AE, Griesemer RA, Landrigan PJ, Stayner LT, Swenberg JA. Contribution of formaldehyde to respiratory cancer. Environ Health Perspect. 1986;70:23–35. 10.1289/ehp.867023 3830109
150 Squire RA, Cameron LL. An analysis of potential carcinogenic risk from formaldehyde. Regul Toxicol Pharmacol. 1984; 4(2):107–129. 10.1016/0273-2300(84)90034-5 6377399
151 More SS, Raza A, Vince R. The butter flavorant, diacetyl, forms a covalent adduct with 2-deoxyguanosine, uncoils DNA, and leads to cell death. J Agric Food Chem. 2012; 60(12):3311–3317. 10.1021/jf300180e 22385266
152 Shapiro R, Hachmann J. The reaction of guanine derivatives with 1,2-dicarbonyl compounds. Biochemistry. 1966; 5(9):2799–2807. 10.1021/bi00873a004 5961865
153 Murata-Kamiya N, Kamiya H. Methylglyoxal, an endogenous aldehyde, crosslinks DNA polymerase and the substrate DNA. Nucleic Acids Res. 2001; 29(16):3433–3438. 10.1093/nar/29.16.3433 11504881
154 Lai C, Lin G, Wang W, Luo H. Absolute configurations and stability of cyclic guanosine mono‐adducts with glyoxal and methylglyoxal. Chirality. 2011; 23(7):487–494. 10.1002/chir.20875 21500285
155 Kanwal RS, Martin S. Letter of May 13, 2003, from R.S. Kanwal and S. Martin, Division of Respiratory Disease Studies, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health, Department of Health and Human Services, to Keith Heuermann, B.K. Heuermann Popcorn, Inc., Phillips, NE. 2003.
156 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cumene (CAS No. 98-82-8) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services; 2009. Technical Report Series No. 542. NIH Publication No. 09-5885.
157 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests. 5. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19(Suppl. 21):2-141. 10.1002/em.2850190603
158 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
159 MacGregor JT, Bishop ME, McNamee JP, Hayashi M, Asano N, Wakata A, Nakajima M, Saito J, Aidoo A, Moore MM, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. 10.1093/toxsci/kfl076 16888079
160 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutag. 2004; 44(5):427-435. 10.1002/em.20075
161 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117