# Conclusions

Under the conditions of these 2-year inhalation studies, there was some evidence of carcinogenic activity^1^ of 2,3-butanedione in male Wistar Han rats based on the combined incidences of squamous cell papilloma and squamous cell carcinoma of the nose. There was some evidence of carcinogenic activity of 2,3-butanedione in female Wistar Han rats based on the incidences of squamous cell carcinoma of the nose. There was no evidence of carcinogenic activity of 2,3-butanedione in male B6C3F1/N mice exposed to 12.5, 25, or 50 ppm. There was equivocal evidence of carcinogenic activity of 2,3-butanedione in female B6C3F1/N mice based on the occurrences of adenocarcinoma of the nose.

1 See Explanation of Levels of Evidence of Carcinogenic Activity. See a summary of the Peer Review Panel comments and the public discussion on this Technical Report in Appendix K.

Exposure to 2,3-butanedione resulted in increased incidences of nonneoplastic lesions of the nose, larynx, trachea, lung, and eye in male and female rats and mice.