# Discussion

2,3-Butanedione is a volatile, direct acting, diketone that caused significant toxicity throughout the respiratory tract of rodents. The severity and distribution of lesions in the respiratory tract caused by direct-acting volatile toxicants is dependent upon the water solubility and reactivity of the chemical, the exposure concentration and duration, and regional differences in cellular susceptibility. 2,3-Butanedione is water soluble and can readily penetrate the aqueous mucous layer protecting the respiratory tract mucosa^36^. 2,3-Butanedione also is highly reactive, especially toward guanidinium groups on positively charged amino acids such as arginine, lysine, and histidine^35; 71; 110^. Arginyl residues are often located at the active sites of enzymes, and reaction with 2,3-butanedione and related diketones results in a loss of enzyme activity^55; 111-115^.

. Reaction of 2,3-butanedione with arginyl residues on proteins can result in modification of structure and function^116-118^. In a recent study, 2,3-butanedione-induced airway damage in mice was correlated with increased immunofluorescence for markers of protein turnover and autophagy^70^. Inhalation exposure of mice to 200 ppm 2,3-butanedione for 6 hours caused concentration-dependent increases in bronchial epithelial cells with increased accumulations of total ubiquitin and K63-ubiquitin, central mediators of protein turnover. Immunofluorescent colocalization of ubiquitin with lysosomal-associated membrane proteins 1 and 2, and with sequestosome-1, a multifunctional scaffolding protein, confirmed ubiquitin autophagy. Free ubiquitin was depleted, which is a concern because of its role in cellular homeostasis, including DNA repair and chromatin remodeling^119; 120^.

Inhalation of 2,3-butanedione and other direct-acting irritants causes a characteristic sequence of events, beginning with injury to the epithelium lining the respiratory tract. Necrosis of epithelial cells typically is followed by inflammation and regenerative proliferation to repair the injured epithelium. Repeated exposure and injury to the epithelium can result in an adaptive response such as squamous metaplasia, and excessive cell proliferation can result in epithelial hyperplasia^121; 122^. Repetitive epithelial injury in the respiratory tract can also lead to fibrosis. Fibrosis in the small airways can progress to bronchiolitis obliterans, a debilitating obstructive airway disease characterized by epithelial degeneration and progressive fibroproliferation with eventual obliteration of the airway lumens. Occupational exposure to 2,3-butanedione was first associated with an increased prevalence of bronchiolitis obliterans in workers at a microwave popcorn packaging plant^22; 24^. The prevalence of bronchiolitis obliterans was highest for workers in the artificial butter flavor mixing room where a mean 2,3-butanedione concentration of 57.2 ppm was reported^25; 59^.

Initial studies were conducted to better understand the association between 2,3-butanedione exposure and the development of bronchiolitis obliterans. Male Wistar Han rats were exposed 6 hours/day, 5 days/week for 2 weeks to 100, 150, 175, or 200 ppm 2,3-butanedione, and bronchiolitis obliterans occurred only in rats exposed to 150 ppm or greater^55^. These studies demonstrated that 2,3-butanedione has a steep concentration-response curve and suggest that peak exposure concentration may be more important than exposure duration in the pathogenesis of bronchiolitis obliterans. In these 2-week studies, airway epithelial injury caused by repeated exposure to 100 ppm 2,3-butanedione was insufficient to trigger the dysregulated fibroproliferation associated with bronchiolitis obliterans. It is possible that repeated exposure to 150 ppm 2,3-butanedione or greater not only causes epithelial necrosis, but may also eliminate progenitor cells thereby preventing reepithelialization^123^. Alternatively, denudation of both the epithelium and basement membrane exposes the underlying connective tissue to chemical irritation, potentially triggering the fibrotic response^124^.

Two-week exposures to 50 and 100 ppm 2,3-butanedione caused significant lesions in the nasal cavity, but concentrations reaching the small airways may have been insufficient to cause loss of basal cells and basement membrane disruption. Absorption and reaction of inhaled 2,3-butanedione in the nose and upper respiratory tract reduce the concentration that reaches the distal airways. This effect is greater in rodents than humans because rodents are obligate nose breathers, and because their complex nasal anatomy allows more efficient scrubbing of 2,3-butanedione from the inhaled air. These species differences may result in greater nasal toxicity in 2,3-butanedione-exposed rodents, with less injury to the lower airways. Morris and Hubbs^36^ estimated that in nose-breathing rats exposed to 100 ppm 2,3-butanedione, only 62 ppm reached the bronchi. In contrast, in mouth-breathing humans this concentration was predicted to be 97 ppm, about 1.5-fold higher, suggesting that the dose delivered to intrapulmonary airways in humans may be much greater than that in the rat.

The current 2-year studies were designed to evaluate whether chronic exposures to low concentrations of 2,3-butanedione would cause respiratory tract fibrosis or have carcinogenic effects. Small areas of submucosal fibrosis were present in the proximal bronchi of a few rats exposed to 50 ppm for 2 years; however, these minimal lesions were not progressive and did not cause bronchiolitis obliterans. Although a few incidences of fibrosis were present in the small airways, fibrosis was much more prevalent in the nose and trachea of rats and mice exposed for 2 years to 2,3-butanedione. Fibrosis of the lamina propria of the nasal mucosa occurred in most of the rats and mice exposed for 2 years to 50 ppm 2,3-butanedione and many of those exposed to 25 ppm. In most cases, fibrosis occurred along the lateral walls of the nasal cavities and the tips of the nasoturbinates, sites receiving high exposure to inhaled 2,3-butanedione vapors. Fibrosis of the nasal cavity has been reported in NTP chronic inhalation studies of other water-soluble, reactive chemicals such as chloroprene^125^, furfuryl alcohol^126^, ozone^127^, vinylidene chloride^128^, and tetrahydrofuran^129^.

Chronic exposure to 50 ppm 2,3-butanedione also caused considerable submucosal fibrosis in the trachea of rats and mice. Mild to moderate tracheal fibrosis occurred in most of the male (94%) and female (88%) mice exposed to 50 ppm 2,3-butanedione for 2 years. The prevalence and severity of these tracheal lesions were considerably lower in rats [male rats (54%), female rats (38%)] than in mice. Tracheal fibrosis is uncommon in NTP inhalation studies and has only been reported for one other chemical. o-Phthalaldehyde inhalation caused minimal to mild tracheal fibrosis in male and female rats exposed for 3 months. Like, 2,3-butanedione, o-phthalaldehyde is water soluble, direct-acting, and highly reactive. Submucosal fibrosis in relatively large air passages such as the nasal cavity and trachea typically have minimal effects on pulmonary function. 2,3-Butanedione also caused minimal to mild interstitium fibrosis of alveolar septae in 11 male and nine female rats in the 50 ppm groups. In some animals the fibrosis formed nodular foci that expanded the alveolar walls and extended in tendrils into the surrounding alveolar septae.

2,3-Butanedione did not cause bronchiolitis obliterans in this 2-year study because the highest exposure concentration was limited to 50 ppm in an attempt to minimize adverse nasal effects over a 2-year period. However, the significant nasal and tracheal fibrosis and the foci of bronchial fibrosis in both species and foci of pulmonary fibrosis in the rats demonstrate the potent fibrogenicity of this chemical following inhalation exposure. Because rodents are nose-only breathers and absorb more of the 2,3-butanedione in the nose than do humans, the fibrosis that occurred in the nose and trachea of the rats and mice may be considered as a rodent surrogate for bronchiolitis obliterans in humans. Fibrosis of the trachea in the mice was particularly prominent in terms of the circumferential and intramural extent, the associated loss of cartilage in some tracheas, and the resulting reduction in size of the tracheal lumen. In addition, many of the male mice and a few of the female mice exhibited fibrosis of the tracheal carina, which is the distal end of the trachea at the point of bifurcation into the right and left mainstem bronchi. This was a unique lesion that was diagnosed separately to indicate that the fibrogenic effect of the chemical reached the distal end of the trachea. Because the carina is typically not represented in all mice and in very few rats, the true incidence of this carinal lesion in the study is probably underrepresented.

The fibrotic foci in the bronchi were identified in the large bronchi at bifurcation points, which are probably high impact areas receiving maximal airflow. The foci of pulmonary interstitial fibrosis in the rats suggest sensitivity of the alveolar epithelium to 2,3-butanedione. Pulmonary fibrosis has been seen previously in short-term studies at higher concentrations (e.g., 150 ppm) of this chemical^55^.

Although the pathogenesis of bronchiolitis obliterans is unclear, airway epithelial injury appears to be a critical first step^130^. Considerable evidence suggests that immunological injury of the airway epithelium is a key factor in transplant-related bronchiolitis obliterans. 2,3-Butanedione-induced bronchiolitis obliterans may result from immunological reaction to 2,3-butanedione-arginine adducts on the airway epithelium membrane proteins^71^. Serum from rats and mice exposed to 0, 12.5, 25, or 50 ppm 2,3-butanedione in the current 2-year studies was evaluated for autoantibodies against nuclear antigens; however, none of the exposed groups had an incidence of ANA-positive responses that was significantly different from that of the chamber control group (data not presented). Inhalation exposure to 2,3-butanedione caused the most severe toxicity in the nasal cavity of rats and mice, with decreasing toxicity at more distal sites in the respiratory tract. Nasal toxicity often occurs in rodents during inhalation exposure to reactive chemicals because they are obligate nose breathers and the nasal cavity is exposed to the highest concentrations of inhaled toxicants. Nasal irritation was frequently reported by workers in NIOSH medical surveys at microwave popcorn plants and flavoring manufacturing plants^34^. 2,3-Butanedione and other water-soluble, reactive chemicals are rapidly scrubbed from the inhaled air passing over the moist nasal turbinates^131^. Once absorbed, 2,3-butanedione can readily penetrate the protective aqueous mucous layer and react with the nasal mucosa^36^. The nasal cavity is a common target site for rodents exposed by inhalation to many direct-acting, reactive chemicals such as chlorine^132^, formaldehyde^133^, ammonia^134^, acetaldehyde^135^, acrolein^136^, diethylamine^137^, and propargyl alcohol^138^.

Although toxicity for the nasal cavity was expected, chronic exposure of rats to 2,3-butanedione also resulted in some evidence of carcinogenicity in the nasal cavity. Low incidences of squamous cell carcinoma of the nasal mucosa occurred in male (6%) and female (6%) rats exposed to 50 ppm 2,3-butanedione for 2 years. A squamous cell papilloma also occurred in one 50 ppm male rat and was considered a potential precursor lesion to squamous cell carcinoma. Although incidences of squamous cell carcinoma were not statistically significant, the combination of three squamous cell carcinomas and one squamous cell papilloma in 50 ppm male rats was statistically significant relative to concurrent chamber controls (0/50). Nasal neoplasms are rare in rodents and have not been observed in NTP historical controls (0/349 by all routes) for male Wistar Han rats. The spontaneous incidence of nasal neoplasms of all types is typically much less than 0.5% in Fischer 344^139; 140^ and Wistar^141^ rats.

Squamous metaplasia of the respiratory epithelium occurred in the nasal cavities of most rats exposed to 50 ppm 2,3-butanedione. The metaplastic squamous epithelium was frequently thickened, hyperkeratotic, and sometimes atypical. Squamous metaplasia is considered an adaptive change, because squamous epithelium is more resistant to injury than other epithelial types. Squamous metaplasia may be reversible with discontinuation of exposure, but with chronic exposure, squamous metaplasia may give rise to squamous cell papilloma or squamous cell carcinoma^121; 122^. Rats appear to be more susceptible than mice to squamous cell carcinoma caused by inhaled chemicals^140^. Squamous cell carcinomas have been reported in NTP inhalation studies for 10 chemicals. Of these 10 chemicals, eight caused squamous cell carcinomas in male rats, two in female rats, and only one in female mice.

The presence of adenocarcinoma in the nasal cavity of two (4%) female mice exposed to 50 ppm for 2 years may have been related to chronic 2,3-butanedione exposure. This incidence of adenocarcinoma was not statistically significant relative to concurrent chamber control mice and occurred only at the high concentration that did cause significant decreases in body weight gain and survival of mice. However, spontaneous adenocarcinoma of the nasal cavity is extremely rare and has not been observed in NTP historical controls for B6C3F1/N mice (0/548 by all routes). Treatment-related adenocarcinoma of the nose has only been reported in NTP inhalation studies of propylene oxide^142^, 1,2-dibromoethane^143^, and 1,2-dibromo-3-chloropropane^144^. Adenocarcinomas may arise from the respiratory epithelium of the anterior nasal cavity, the epithelium of the submucosal glands, or from a malignant change within an existing adenoma^122; 145-147^. Adenocarcinomas in the two 2,3-butanedione-exposed female mice in the current study appeared to arise in Level III, the olfactory portion of the nasal cavity. Exposure to 50 ppm 2,3-butanedione caused extensive respiratory metaplasia in the olfactory region of the nose in almost all mice, and this respiratory metaplasia of both the olfactory epithelium and the underlying Bowman’s glands may have been the background precursor lesion leading to the two adenocarcinomas.

Squamous cell carcinomas of the nasal cavity occurred in rats exposed to 50 ppm 2,3-butanedione, a concentration that caused significant respiratory epithelial hyperplasia, and squamous metaplasia. Repeated injury to the nasal mucosa caused by reactive inhaled toxicants may contribute to the induction of nasal tumors^148^. Formaldehyde, a known nasal carcinogen, causes squamous cell carcinoma in the nasal cavity of rats, but only at exposure concentrations that cause severe degeneration, hyperplasia, and squamous metaplasia in the nasal epithelium^149; 150^. Sustained cytotoxicity and cell proliferation in the nasal cavity caused by chronic 2,3-butanedione exposure may predispose to nasal carcinogenesis because cell division is required to convert DNA adducts to permanent mutations^133^. 2,3-Butanedione has been shown to form adducts with 2-deoxyguanosine and to disrupt DNA ternary structure^151^. In the current study 2,3-butanedione was shown to be mutagenic in bacterial assays. The related 1,2-dicarbonyl compounds, methylglyoxal and glyoxal, also form adducts with guanosine and are highly mutagenic^152-154^.

Eye irritation was frequently reported in NIOSH medical surveys at microwave popcorn plants and flavoring manufacturing plants^34^. At one plant, several workers developed severe eye irritation and blurred vision after use of a new butter flavoring^155^. 2,3-Butanedione is a major volatile component of artificial butter flavorings and likely contributed to these ocular effects. In the current studies, chronic exposure to 2,3-butanedione vapors caused ocular lesions in rats and mice. Microscopic lesions included corneal inflammation, minimal to mild ulcer and hyperplasia of the corneal epithelium, and an increased incidence of cataracts. Inhalation studies of other contact irritant gases and vapors such as diethylamine^137^, cumene^156^, and propargyl alcohol^138^ also reported eye irritation in rats and mice.