# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-593.

## Rats

### Three-month Study

Two male rats in the 100 ppm group were found dead on days 91 and 92, respectively (Table 3). All other rats survived to the end of the study. The final mean body weights and body weight gains of 100 ppm males and females were significantly less than those of the chamber control groups (Table 3 and Figure 2). Abnormal breathing was observed in 100 ppm males (5/10) and females (5/10) and 50 ppm females (6/10). Sneezing was observed in 50 ppm males (9/10) and females (6/10) and in 100 ppm males (9/10) and females (8/10). Lethargy was observed in one 100 ppm male.

Table 3 Survival and Body Weights of Rats in the Three-month Inhalation Study of 2,3-Butanedione^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 143 ± 3 | 410 ± 8 | 267 ± 8
6.25 | 10/10 | 144 ± 3 | 401 ± 13 | 258 ± 11 | 98
12.5 | 10/10 | 142 ± 3 | 386 ± 8 | 244 ± 8 | 94
25 | 10/10 | 143 ± 3 | 407 ± 16 | 264 ± 15 | 99
50 | 10/10 | 144 ± 3 | 387 ± 8 | 243 ± 7 | 94
100 | 8/10^c^ | 141 ± 4 | 333 ± 12** | 192 ± 10** | 81
Female
0 | 10/10 | 124 ± 2 | 236 ± 6 | 112 ± 5
6.25 | 10/10 | 122 ± 2 | 235 ± 5 | 113 ± 4 | 99
12.5 | 10/10 | 123 ± 2 | 228 ± 4 | 106 ± 4 | 97
25 | 10/10 | 122 ± 2 | 226 ± 4 | 104 ± 4 | 96
50 | 10/10 | 120 ± 2 | 232 ± 6 | 112 ± 5 | 98
100 | 10/10 | 122 ± 2 | 208 ± 9** | 86 ± 8** | 88

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ or Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Weeks of death: 13, 14.

Figure 2

Growth Curves for Rats Exposed to 2,3-Butanedione by Inhalation for Three Months

On day 23 and at study termination, neutrophil counts in the blood were significantly increased in 100 ppm females and were consistent with the inflammation observed in the respiratory tract (Table 4 and Table F-1). Erythrocyte count, hemoglobin concentration, packed cell volume, and hematocrit were significantly increased on day 23 in 100 ppm females. At study termination, the erythrocyte count, hemoglobin concentration, and packed cell volume were significantly increased in 100 ppm males; hemoglobin concentration and packed cell volume were also significantly increased in the 50 ppm group of males. In female rats at study termination, the erythrocyte count was significantly increased in the 50 and 100 ppm groups, and the packed cell volume was significantly increased in the 100 ppm group. While it may be that the mild increase in the erythron was due to decreased water intake, other indicators of dehydration were unchanged (urea nitrogen and total protein concentrations). Another plausible explanation for the erythron alterations is that the extent of the respiratory lesions in these particular groups led to hypoxia and a mild secondary erythrocytosis. No other statistically significant changes in hematology parameters were considered toxicologically relevant.

Table 4 Selected Hematology Data for Rats in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 7
Packed cell volume (%)
Day 3 | 44.1 ± 0.6 | 43.0 ± 0.5 | 41.4 ± 0.6* | 42.1 ± 0.5 | 42.4 ± 0.4 | 42.7 ± 0.7
Day 23 | 46.8 ± 0.7 | 46.0 ± 0.6 | 46.5 ± 0.7 | 46.6 ± 0.9 | 45.9 ± 0.7 | 47.0 ± 0.8
Week 14 | 47.2 ± 0.7 | 47.3 ± 0.6 | 47.5 ± 0.7 | 48.6 ± 1.2 | 49.4 ± 0.8* | 50.3 ± 1.1*
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.2 | 13.4 ± 0.2 | 13.1 ± 0.2 | 13.3 ± 0.2 | 13.3 ± 0.1 | 13.4 ± 0.2
Day 23 | 14.7 ± 0.2 | 14.6 ± 0.2 | 14.7 ± 0.2 | 14.8 ± 0.3 | 14.4 ± 0.2 | 14.9 ± 0.2
Week 14 | 15.2 ± 0.2 | 15.3 ± 0.2 | 15.4 ± 0.2 | 15.7 ± 0.3 | 15.7 ± 0.2* | 16.3 ± 0.4**
Erythrocytes (10^6^/μL)
Day 3 | 7.07 ± 0.10 | 6.86 ± 0.12 | 6.68 ± 0.11 | 6.89 ± 0.09 | 6.96 ± 0.09 | 6.96 ± 0.14
Day 23 | 7.80 ± 0.11 | 7.64 ± 0.15 | 7.67 ± 0.13 | 7.80 ± 0.12 | 7.75 ± 0.11 | 7.98 ± 0.16
Week 14 | 8.82 ± 0.14 | 8.86 ± 0.13 | 8.97 ± 0.10 | 8.93 ± 0.25 | 9.14 ± 0.16 | 9.57 ± 0.19**
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 3 | 45.2 ± 0.5 | 45.7 ± 0.3 | 45.4 ± 0.4 | 44.0 ± 0.7 | 45.2 ± 0.5 | 44.6 ± 0.9
Day 23 | 47.2 ± 0.2 | 47.3 ± 0.4 | 48.1 ± 0.7 | 47.6 ± 0.6 | 48.3 ± 0.5 | 48.9 ± 0.5**
Week 14 | 46.3 ± 0.5 | 45.8 ± 0.6 | 46.8 ± 0.7 | 46.1 ± 0.3 | 47.8 ± 0.4 | 48.1 ± 0.8
Packed cell volume (%)
Day 3 | 43.7 ± 0.5 | 43.6 ± 0.4 | 43.0 ± 0.4 | 41.8 ± 0.5 | 43.3 ± 0.5 | 42.8 ± 0.8
Day 23 | 45.4 ± 0.2 | 45.8 ± 0.3 | 46.4 ± 0.6 | 45.9 ± 0.5 | 46.4 ± 0.5 | 47.5 ± 0.5**
Week 14 | 45.7 ± 0.3 | 45.7 ± 0.4 | 46.9 ± 0.6 | 45.7 ± 0.4 | 47.1 ± 0.5 | 47.6 ± 0.6*
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.2 | 13.7 ± 0.1 | 13.6 ± 0.1 | 13.1 ± 0.2 | 13.8 ± 0.2 | 13.6 ± 0.2
Day 23 | 14.8 ± 0.1 | 14.9 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.2 | 15.2 ± 0.2 | 15.4 ± 0.2**
Week 14 | 14.8 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.2 | 14.7 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.3
Erythrocytes (10^6^/μL)
Day 3 | 7.15 ± 0.13 | 7.10 ± 0.07 | 7.08 ± 0.12 | 6.93 ± 0.11 | 7.19 ± 0.05 | 7.12 ± 0.17
Day 23 | 7.68 ± 0.06 | 7.68 ± 0.05 | 7.88 ± 0.11 | 7.82 ± 0.11 | 7.90 ± 0.11 | 8.07 ± 0.14*
Week 14 | 8.17 ± 0.09 | 8.18 ± 0.09 | 8.36 ± 0.12 | 8.16 ± 0.07 | 8.54 ± 0.11* | 8.67 ± 0.17*
Segmented neutrophils (10^3^/μL)
Day 3 | 0.90 ± 0.11 | 0.76 ± 0.10 | 0.65 ± 0.06 | 0.69 ± 0.08 | 0.77 ± 0.06 | 1.03 ± 0.14
Day 23 | 0.90 ± 0.09 | 0.82 ± 0.09 | 0.63 ± 0.08 | 0.75 ± 0.10 | 1.82 ± 0.35 | 1.59 ± 0.24*
Week 14 | 1.54 ± 0.21 | 1.27 ± 0.15 | 1.24 ± 0.08 | 1.32 ± 0.27 | 2.19 ± 0.27 | 3.48 ± 0.42**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

Triglyceride concentrations were decreased in 100 ppm males and 100 ppm females on day 3 (Table F-1). These alterations were transient and may have been due to decreases in feed intake as the animals acclimated to exposure. All other statistically significant biochemical changes were mild, inconsistent, and not considered toxicologically relevant.

Relative lung weight was significantly increased in 100 ppm females (Table G-1). Significant decreases in absolute organ weights were restricted to the 100 ppm groups. Absolute heart weights were significantly decreased in 100 ppm males, while relative heart weights were increased in both sexes at 100 ppm. Significant decreases occurred in absolute liver, thymus, and right kidney weights of 100 ppm males and absolute liver and thymus weights of 100 ppm females. These findings are of uncertain toxicologic significance given the body weight decreases in these groups. No treatment-related lesions were noted in these tissues.

Exposure-related histopathology findings occurred in the nose, larynx, trachea, lung, and eye of rats. In the nose, lesions occurred primarily in the 50 and 100 ppm groups, as well as in a few 25 ppm males and females (Table 5). Suppurative inflammation of mild to marked severity occurred in all males and females exposed to 50 or 100 ppm. Mild respiratory epithelium necrosis occurred in all males and females exposed to 100 ppm, and minimal necrosis occurred in a few of the 50 ppm animals. Respiratory epithelium regeneration occurred in most of the rats exposed to 100 ppm and in a few exposed to 50 ppm. Mild to marked squamous metaplasia of the respiratory epithelium occurred in all 50 and 100 ppm rats, and minimal squamous metaplasia occurred in most of those exposed to 25 ppm. Respiratory epithelium hyperplasia occurred in all females and most males exposed to 50 or 100 ppm, and minimal hyperplasia occurred in two 25 ppm males. In animals exposed to 100 ppm, mild olfactory epithelium necrosis occurred in nine males and minimal necrosis occurred in four females. Olfactory epithelium degeneration, characterized by cytoplasmic vacuolation, occurred in Level II of most of the 50 ppm rats and also occurred in some 25 ppm males and females and 100 ppm females. Minimal to moderate respiratory metaplasia of the olfactory epithelium occurred in all females and most of the males exposed to 50 or 100 ppm and also in two 25 ppm males. Olfactory epithelium atrophy occurred in four females and one male exposed to 100 ppm. Atrophy of olfactory epithelium may occur as a sequel to degeneration or necrosis of the olfactory epithelium. Mild to moderate turbinate atrophy, primarily affecting the nasoturbinate bones in Level I, occurred in all males and females exposed to 100 ppm; minimal to mild turbinate atrophy also occurred in a few of the 50 ppm rats. Necrosis of septal cartilage occurred in one male and two females in the 100 ppm groups. Hyperplasia of nasal-associated lymphoid tissue adjacent to the nasopharyngeal duct in Level III occurred in most of the rats exposed to 50 or 100 ppm, and minimal hyperplasia occurred in a few animals exposed to 25 ppm.

Table 5 Incidences of Nonneoplastic Lesions of the Respiratory System in Rats in the Three-month Inhalation Study of 2,3-Butanedione

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative^b^ | 0 | 0 | 0 | 1 (1.0)^c^ | 10** (2.5) | 10** (3.6)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 2 (1.0) | 10** (2.2)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 0 | 4* (1.0) | 10** (1.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 8** (1.0) | 10** (2.3) | 10** (3.5)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 10** (2.6) | 9** (2.7)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 9** (2.1)
Olfactory Epithelium, Degeneration | 0 | 0 | 0 | 3 (1.0) | 9** (1.6) | 0
Olfactory Epithelium, Metaplasia, Respiratory | 0 | 0 | 0 | 2 (1.0) | 7** (1.9) | 9** (2.0)
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 3 (1.0) | 10** (2.2)
Septum, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Lymphoid Tissue, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 9** (1.7) | 6** (2.3)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 8** (1.4) | 10** (3.5)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 3 (1.3) | 1 (2.0)
Squamous Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 5* (2.0)
Squamous Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Trachea | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 10** (3.5)
Epithelium, Regeneration | 0 | 0 | 0 | 0 | 0 | 9** (1.4)
Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 4* (1.3)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 2 (1.5)
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 2 (1.5)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 4* (1.8)
Bronchus, Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 0 | 3 (2.0)
Bronchus, Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 4* (2.3)
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 0 | 0 | 5* (2.0)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 5* (1.2)
Inflammation, Eosinophil | 2 (1.0) | 0 | 3 (1.0) | 1 (1.0) | 0 | 6 (2.0)
Infiltration Cellular, Histiocyte | 1 (1.0) | 0 | 1 (1.0) | 0 | 0 | 7** (1.4)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative | 0 | 0 | 0 | 0 | 10** (2.0) | 10** (3.6)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 3 (1.0) | 10** (2.2)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 0 | 3 (1.0) | 9** (1.3)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 5** (1.0) | 10** (2.8) | 10** (3.7)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 10** (2.6) | 10** (2.8)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 4* (1.0)
Olfactory Epithelium, Degeneration | 0 | 0 | 0 | 4* (1.0) | 9** (1.0) | 4* (1.8)
Olfactory Epithelium, Metaplasia, Respiratory | 0 | 0 | 0 | 0 | 10** (1.4) | 10** (2.5)
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 4* (1.5)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 4* (1.3) | 10** (2.0)
Septum, Necrosis | 0 | 0 | 0 | 0 | 0 | 2 (1.5)
Lymphoid Tissue, Hyperplasia | 0 | 1 (1.0) | 0 | 2 (1.0) | 8** (1.8) | 6** (2.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 8** (1.0) | 10** (3.0)
Squamous Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 9** (2.0)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 2 (1.5)
Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 6** (1.7)
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 5** (1.0)
Trachea | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Necrosis | 0 | 0 | 0 | 0 | 1 (2.0) | 10** (2.7)
Epithelium, Regeneration | 0 | 0 | 0 | 0 | 2 (1.0) | 10** (1.2)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 9** (2.4)
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 5* (1.8)
Bronchus, Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 0 | 4* (2.0)
Bronchus, Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 0 | 0 | 4* (1.8)
Bronchus, Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 8** (1.0)
Inflammation, Eosinophil | 4 (1.0) | 3 (1.0) | 0* | 1 (1.0) | 1 (1.0) | 7 (2.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 0 | 0 | 0 | 3 (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked.

In the larynx, respiratory epithelium squamous metaplasia of moderate to marked severity occurred in all rats exposed to 100 ppm, and minimal to mild squamous metaplasia occurred in most of the 50 ppm animals (Table 5). The squamous epithelium lining the arytenoid cartilages was mildly hyperplastic in most of the 100 ppm animals, and two 100 ppm males exhibited mild atypical hyperplasia of the squamous epithelium. Minimal to mild respiratory epithelium hyperplasia occurred in a few 50 and 100 ppm males and two 100 ppm females. Foci of epithelium necrosis occurred in two males and six females exposed to 100 ppm. The foci of necrosis were small and sometimes located in more than one location in the same animal. The sites of necrosis were variable, but were most often seen either in the squamous epithelium lining the arytenoid cartilages or in the respiratory epithelium lining the lateral walls of Level III. Minimal chronic active inflammation occurred in a few of the 100 ppm rats.

In the trachea, mild to marked mucosal epithelium necrosis occurred in all 100 ppm males and females and mild epithelium necrosis occurred in one 50 ppm female rat (Table 5). The necrosis was a focal to multifocal change consisting of loss of the epithelium with the denuded tracheal surface sometimes covered by a layer of inflammatory exudate and cell debris. Minimal to mild epithelium regeneration occurred in most of the 100 ppm animals; this lesion also occurred with a minimal severity in two 50 ppm females. Regeneration was characterized by a single layer of cuboidal epithelium covering the tracheal surface and was considered to be a reparative change secondary to necrosis. Minimal to mild epithelium squamous metaplasia occurred in four 100 ppm males. In the distal portion of the trachea, hyperplasia of the mucosal epithelium occurred in nine 100 ppm females, two 100 ppm males, and two 50 ppm males. Minimal to mild chronic active inflammation occurred in a few 100 ppm animals, usually in areas of epithelium necrosis.

In the lung, bronchus epithelium changes occurred only in the large bronchi of the 100 ppm groups. Either minimal to mild bronchus epithelium hyperplasia or mild atypical bronchus epithelium hyperplasia occurred in the majority of the rats exposed to 100 ppm (Table 5). Hyperplasia of the bronchial epithelium consisted of irregular thickening of the epithelial layer due to an increase in the number of epithelial cells, while atypical hyperplasia was characterized by thickened epithelium with the cells having enlarged, hyperchromatic nuclei. The severity grading of the atypical hyperplasia was based upon both the severity of the atypical cellular changes and the extent of the lesion. Mild to moderate bronchus epithelium necrosis occurred in four 100 ppm males, and mild epithelium necrosis occurred in two 100 ppm females. The necrosis was characterized by areas of partial to total loss of the full thickness of the respiratory epithelium, sometimes with residual necrotic cells. Mild bronchus epithelium regeneration occurred in half of the 100 ppm males, and minimal to mild regeneration occurred in four of the 100 ppm females. In areas of regeneration, the normal respiratory epithelium was replaced by a single layer of flattened to cuboidal epithelial cells, presumably covering areas of previous epithelial loss due to necrosis. Mild squamous metaplasia of the bronchus epithelium occurred in two 100 ppm females. Minimal bronchiole epithelium hyperplasia occurred in most of the 100 ppm females, and minimal to mild bronchiole epithelium hyperplasia occurred in half of the 100 ppm males. Hyperplasia of the bronchiole epithelium consisted of an increase in epithelial thickness due to an increase in the number of epithelial cells as well as an increase in the size of some epithelial cells, often with increased size of the nuclei. Epithelial cells in affected bronchioles appeared crowded and sometimes disorganized, and in some cases, appeared to form more than one layer. A mild eosinophilic inflammatory infiltrate occurred in the lungs of most 100 ppm males and females, centered around the blood vessels and airways, with occasional extension into a few alveolar lumens. The infiltrate consisted primarily of eosinophils, often mixed with a few neutrophils, lymphocytes, and macrophages, and also occurred in a few of the animals exposed to lower concentrations, as well as in a few of the chamber controls. Minimal to mild cellular infiltrations of histiocytes, sometimes in aggregates, also occurred in the alveolar spaces of most of the 100 ppm males, and minimal infiltrations of alveolar histiocytes occurred in one 12.5 ppm male, one chamber control male, and three 100 ppm females.

A few exposed rats exhibited lesions of the cornea of the eye (Table 6). Two 100 ppm males and three 100 ppm females exhibited minimal to mild acute inflammation of the cornea; one 50 ppm female had mild acute corneal inflammation. Minimal neovascularization of the corneal stroma accompanied the inflammation in one male and one female each in the 100 ppm groups, and minimal vacuolation of the corneal epithelium occurred in one 100 ppm female. Minimal mineralization of the corneal stroma occurred in one 50 ppm male.

Table 6 Incidences of Nonneoplastic Lesions of the Eye in Rats in the Three-month Inhalation Study of 2,3-Butanedione

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Number Examined Microscopically | 10 | 0 | 0 | 0 | 10 | 10
Cornea, Inflammation, Acute^a^ | 0 | – | – | – | 0 | 2 (1.5)^b^
Cornea, Neovascularization | 0 | – | – | – | 0 | 1 (1.0)
Cornea, Mineralization | 0 | – | – | – | 1 (1.0) | 0
Female
Number Examined Microscopically | 10 | 0 | 0 | 0 | 10 | 10
Cornea, Inflammation, Acute | 0 | – | – | – | 1 (2.0) | 3 (1.3)
Cornea, Neovascularization | 0 | – | – | – | 0 | 1 (1.0)
Cornea, Epithelium, Vacuolation | 0 | – | – | – | 0 | 1 (1.0)

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure Concentration Selection Rationale: Based on significant reductions in body weights and increased incidences of nonneoplastic lesions of the respiratory tract at 100 ppm, 2,3-butanedione exposure concentrations selected for the 2-year inhalation study in rats were 12.5, 25, and 50 ppm. Nasal lesions were a concern at 50 ppm; however, this concentration was included because lower exposure concentrations were not expected to result in sufficient airway exposure and injury to potentially cause bronchiolitis obliterans. The 50 ppm exposure concentration was also included because it was considered occupationally relevant. Flavoring mixers were exposed to a mean concentration of 57.2 ppm 2,3-butanedione in a microwave popcorn manufacturing plant where some workers developed bronchiolitis obliterans^25^.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 7 and in the Kaplan-Meier survival curves (Figure 3). Survival of 50 ppm males was significantly less than that of the chamber control group. In males, 72% of the chamber control group survived to study termination but 66% and 44% of the 25 and 50 ppm animals, respectively, survived; survival of 12.5 ppm males was similar to that of the chamber controls. The primary cause of early deaths in male rats and one female rat exposed to 50 ppm was inflammation of the lungs.

Table 7 Survival of Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 12 | 11 | 15 | 18
Natural deaths | 2 | 2 | 2 | 10
Animals surviving to study termination | 36 | 37^c^ | 33 | 22
Percent probability of survival at end of study^a^ | 72 | 74 | 66 | 44
Mean survival (days)^b^ | 692 | 696 | 676 | 666
Survival analysis^d^ | P = 0.001 | P = 0.986N | P = 0.626 | P = 0.007
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 15 | 18 | 26 | 15
Natural deaths | 1 | 1 | 0 | 4
Animals surviving to study termination | 34 | 31 | 24 | 31c
Percent probability of survival at end of study | 68 | 62 | 48 | 60
Mean survival (days) | 688 | 681 | 665 | 691
Survival analysis | P = 0.507 | P = 0.723 | P = 0.077 | P = 0.591

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^c^ Includes one animal that was euthanized moribund during the last week of the study.

^d^ The result of the life table trend test^81^ is in the chamber control column, and the results of the life table pairwise comparisons^80^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

Figure 3

Kaplan-Meier Survival Curves for Rats Exposed to 2,3-Butanedione by Inhalation for Two Years

#### Body Weights and Clinical Observations

At the end of the study, mean body weights of both sexes exposed to 50 ppm were decreased relative to the respective chamber control groups, with more of an effect in males (81% of chamber controls) than in females (91% of chamber controls) (Figure 4; Table 8, and Table 9). Exposure-related clinical observations in males included thinness, abnormal breathing, eye abnormality, and nasal/eye discharge. Exposure-related clinical observations in females included eye abnormality and abnormal breathing. Eye abnormality was the most frequently noted clinical observation in both males and females exposed to 25 or 50 ppm. A number of appendage ulcer/abscesses were recorded in chamber control and exposed male rats that were attributed to housing heavy rats in wire caging.

Figure 4

Growth Curves for Rats Exposed to 2,3-Butanedione by Inhalation for Two Years

Table 8 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of 2,3-Butanedione

Day | Chamber Control | | 12.5 ppm | | | | 25 ppm | | | 50 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 137 | 50 | 136 | 99 | | 50 | 137 | 99 | 50 | 135 | 98 | 50
8 | 181 | 50 | 178 | 98 | | 50 | 179 | 99 | 50 | 172 | 95 | 50
16 | 229 | 50 | 226 | 99 | | 50 | 229 | 100 | 50 | 215 | 94 | 50
22 | 258 | 50 | 256 | 99 | | 50 | 261 | 101 | 50 | 242 | 94 | 50
29 | 287 | 50 | 285 | 99 | | 50 | 291 | 101 | 49 | 269 | 94 | 50
36 | 312 | 50 | 307 | 99 | | 50 | 316 | 101 | 49 | 292 | 94 | 50
43 | 332 | 50 | 327 | 99 | | 50 | 336 | 101 | 49 | 312 | 94 | 50
50 | 348 | 50 | 341 | 98 | | 50 | 352 | 101 | 49 | 326 | 94 | 50
57 | 361 | 50 | 352 | 98 | | 50 | 365 | 101 | 49 | 339 | 94 | 50
64 | 372 | 50 | 362 | 97 | | 50 | 377 | 101 | 49 | 349 | 94 | 50
71 | 382 | 50 | 372 | 97 | | 50 | 387 | 101 | 49 | 358 | 94 | 50
78 | 392 | 50 | 381 | 97 | | 50 | 396 | 101 | 49 | 365 | 93 | 50
85 | 399 | 50 | 389 | 98 | | 50 | 403 | 101 | 49 | 372 | 93 | 50
113 | 426 | 50 | 416 | 98 | | 50 | 431 | 101 | 49 | 402 | 95 | 50
141 | 443 | 50 | 434 | 98 | | 50 | 449 | 101 | 49 | 418 | 94 | 50
169 | 461 | 50 | 448 | 97 | | 50 | 465 | 101 | 49 | 431 | 94 | 50
197 | 476 | 50 | 465 | 98 | | 49 | 480 | 101 | 49 | 443 | 93 | 50
225 | 491 | 50 | 481 | 98 | | 49 | 497 | 101 | 49 | 457 | 93 | 50
253 | 501 | 50 | 492 | 98 | | 49 | 507 | 101 | 49 | 465 | 93 | 50
281 | 512 | 50 | 503 | 98 | | 49 | 517 | 101 | 49 | 475 | 93 | 50
309 | 521 | 50 | 512 | 98 | | 49 | 525 | 101 | 49 | 482 | 93 | 50
337 | 532 | 50 | 523 | 98 | | 49 | 535 | 101 | 48 | 491 | 92 | 50
365 | 541 | 50 | 533 | 99 | | 49 | 543 | 100 | 48 | 496 | 92 | 50
393 | 557 | 49 | 544 | 98 | | 49 | 553 | 99 | 48 | 505 | 91 | 50
421 | 565 | 49 | 552 | 98 | | 49 | 561 | 99 | 48 | 510 | 90 | 50
449 | 576 | 48 | 561 | 97 | | 49 | 565 | 98 | 48 | 516 | 90 | 50
477 | 588 | 48 | 570 | 97 | | 49 | 575 | 98 | 48 | 524 | 89 | 50
505 | 590 | 47 | 578 | 98 | | 49 | 577 | 98 | 48 | 533 | 90 | 49
533 | 595 | 45 | 582 | 98 | | 49 | 578 | 97 | 47 | 527 | 89 | 49
561 | 601 | 45 | 584 | 97 | | 49 | 580 | 96 | 44 | 515 | 86 | 46
589 | 606 | 45 | 583 | 96 | | 48 | 578 | 95 | 42 | 503 | 83 | 39
617 | 611 | 45 | 598 | 98 | | 44 | 581 | 95 | 39 | 499 | 82 | 35
645 | 615 | 41 | 609 | 99 | | 41 | 584 | 95 | 39 | 499 | 81 | 30
659 | 614 | 40 | 614 | 100 | | 40 | 584 | 95 | 39 | 503 | 82 | 28
673 | 611 | 40 | 613 | 100 | | 40 | 582 | 95 | 39 | 496 | 81 | 28
687 | 607 | 40 | 614 | 101 | | 39 | 579 | 96 | 39 | 498 | 82 | 26
701 | 615 | 38 | 614 | 100 | | 38 | 584 | 95 | 37 | 501 | 82 | 26
715 | 612 | 38 | 614 | 100 | | 37 | 580 | 95 | 36 | 495 | 81 | 24
Mean for Weeks
1-13 | 307 | | 301 | 98 | | | 310 | 101 | | 288 | 94
14-52 | 485 | | 475 | 98 | | | 490 | 101 | | 452 | 93
53-103 | 594 | | 585 | 99 | | | 574 | 97 | | 508 | 86

Table 9 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of 2,3-Butanedione

Day | Chamber Control | | 12.5 ppm | | | 25 ppm | | | 50 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 116 | 50 | 117 | 101 | 50 | 115 | 99 | 50 | 115 | 100 | 50
8 | 135 | 50 | 138 | 102 | 50 | 136 | 101 | 50 | 135 | 100 | 50
16 | 152 | 50 | 158 | 104 | 50 | 153 | 101 | 50 | 155 | 102 | 50
22 | 163 | 50 | 167 | 102 | 50 | 168 | 103 | 50 | 166 | 102 | 50
29 | 174 | 50 | 182 | 105 | 50 | 181 | 104 | 50 | 178 | 103 | 50
36 | 183 | 50 | 191 | 105 | 50 | 191 | 105 | 50 | 188 | 103 | 50
43 | 192 | 50 | 201 | 104 | 50 | 200 | 104 | 50 | 196 | 102 | 50
50 | 199 | 50 | 207 | 104 | 50 | 207 | 104 | 50 | 203 | 102 | 50
57 | 204 | 50 | 212 | 104 | 50 | 211 | 104 | 50 | 210 | 103 | 50
64 | 211 | 50 | 218 | 104 | 50 | 218 | 103 | 50 | 214 | 102 | 50
71 | 214 | 50 | 222 | 104 | 50 | 220 | 103 | 50 | 218 | 102 | 50
78 | 217 | 50 | 226 | 104 | 50 | 223 | 103 | 50 | 221 | 102 | 50
85 | 219 | 50 | 229 | 105 | 50 | 227 | 104 | 50 | 224 | 102 | 50
113 | 232 | 50 | 242 | 105 | 50 | 240 | 104 | 50 | 237 | 102 | 50
141 | 240 | 50 | 252 | 105 | 49 | 250 | 104 | 50 | 246 | 103 | 50
169 | 247 | 50 | 256 | 103 | 49 | 256 | 104 | 50 | 252 | 102 | 50
197 | 255 | 50 | 266 | 104 | 49 | 267 | 105 | 50 | 262 | 103 | 50
225 | 263 | 50 | 270 | 103 | 49 | 273 | 104 | 50 | 268 | 102 | 50
253 | 268 | 49 | 276 | 103 | 49 | 280 | 104 | 50 | 273 | 102 | 50
281 | 275 | 49 | 284 | 103 | 49 | 288 | 105 | 50 | 280 | 102 | 50
309 | 283 | 49 | 289 | 102 | 49 | 297 | 105 | 50 | 287 | 101 | 50
337 | 294 | 49 | 299 | 102 | 49 | 309 | 105 | 50 | 298 | 101 | 50
365 | 303 | 49 | 308 | 102 | 49 | 317 | 104 | 49 | 304 | 100 | 50
393 | 314 | 49 | 316 | 101 | 49 | 328 | 105 | 49 | 315 | 100 | 50
421 | 322 | 48 | 327 | 102 | 47 | 336 | 104 | 49 | 322 | 100 | 50
449 | 334 | 48 | 336 | 101 | 47 | 345 | 103 | 48 | 328 | 98 | 49
477 | 345 | 48 | 344 | 100 | 47 | 357 | 104 | 46 | 340 | 99 | 49
505 | 355 | 48 | 351 | 99 | 47 | 364 | 103 | 46 | 350 | 99 | 48
533 | 358 | 48 | 363 | 101 | 46 | 371 | 104 | 41 | 351 | 98 | 48
561 | 367 | 46 | 370 | 101 | 46 | 374 | 102 | 41 | 357 | 97 | 46
589 | 372 | 45 | 374 | 100 | 44 | 378 | 102 | 39 | 359 | 96 | 45
617 | 384 | 42 | 382 | 100 | 41 | 389 | 102 | 36 | 359 | 94 | 45
645 | 389 | 41 | 389 | 100 | 40 | 396 | 102 | 35 | 354 | 91 | 37
659 | 395 | 39 | 394 | 100 | 39 | 398 | 101 | 34 | 358 | 91 | 37
673 | 393 | 38 | 397 | 101 | 38 | 397 | 101 | 34 | 358 | 91 | 37
687 | 399 | 36 | 400 | 100 | 37 | 402 | 101 | 33 | 359 | 90 | 36
701 | 395 | 36 | 399 | 101 | 37 | 405 | 103 | 31 | 361 | 92 | 35
715 | 400 | 34 | 403 | 101 | 34 | 410 | 103 | 30 | 363 | 91 | 33
Mean for Weeks
1-13 | 183 | | 190 | 104 | | 188 | 103 | | 186 | 102
14-52 | 262 | | 270 | 103 | | 273 | 104 | | 267 | 102
53-103 | 364 | | 366 | 101 | | 373 | 103 | | 346 | 95

#### Gross Observations

At terminal euthanasia, several rats exposed to 50 ppm had mottled lesions of the lungs, which often correlated histopathologically to acute inflammation of the bronchi and alveoli. Many rats exposed to 50 ppm and some rats exposed to 25 ppm had eye lesions or foci that were described as small, opaque, pale, cloudy, or as nodules, which generally corresponded histopathologically to inflammation of the cornea and associated structures. It was also noted that the nasal passages could not be well flushed in some animals.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the nose, larynx, trachea, lung, eye, bone marrow, and skin. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Nose: Three squamous cell carcinomas and one squamous cell papilloma of the nasal mucosa occurred in male rats exposed to 50 ppm, and three squamous cell carcinomas of the nasal mucosa occurred in females exposed to 50 ppm (Table 10, Table A-1, Table A-2, Table B-1, and Table B-2). All of these neoplasms arose from the lateral walls, the nasoturbinates, or the maxilloturbinates in Level I and/or Level II of the nasal cavity. In these locations, the normal respiratory and transitional mucosal epithelia were often replaced in part by squamous metaplastic epithelium, which was sometimes contiguous with the squamous cell carcinomas. The squamous metaplastic epithelium was frequently thickened and hyperkeratotic, and sometimes atypical, suggesting that it may have provided the preneoplastic background for development of the squamous cell carcinomas. Among the males, one of the squamous cell carcinomas arose in the distal portion of a nasoturbinate and formed a bulbous mass due to expansion of the lamina propria by neoplastic infiltration (Figure 8). The second squamous cell carcinoma formed a plaque-like mass along the lateral wall and adjacent maxilloturbinate, with invasion of the lamina propria adjacent to the alveolar process of the premaxilla bone (Figure 9). The third squamous cell carcinoma formed a large mass that filled and occluded one side of the nasal cavity, impinging upon and deviating the nasal septum towards the opposite lateral wall (Figure 10). Histologically, this latter mass displayed squamous cell carcinoma on the surface, while much of the infiltrating neoplasm exhibited a solid, spindle cell pattern that invaded the dorsal wall of the nose and extended through the frontal process of the premaxilla bone. A second smaller squamous carcinoma was also noted in the same animal on the nasoturbinate of the opposite side of the nasal cavity. The squamous cell papilloma noted in a fourth male rat of the 50 ppm group formed a largely necrotic polypoid structure extending from the dorsal end to the ventral end of the nasal cavity, partially filling the lumen on one side (Figure 11). Among the 50 ppm females with squamous cell carcinomas, one animal exhibited a lesion involving the entire lateral wall mucosa dorsal to the nasolacrimal duct on one side, with invasion of the lateral wall lamina propria and the nasopremaxillary suture, perineural invasion, and invasion of a Haversian canal within the premaxillary bone (Figure 12). In the other two females, each squamous cell carcinoma involved the lateral wall, with one of these irregularly nodular and infiltrating next to the alveolar process of the premaxillary bone (Figure 13), while the other was plaque-like and invaded more superficially into the lamina propria (Figure 14).

Table 10 Incidences of Neoplasms and Nonneoplastic Lesions of the Nose in Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Inflammation, Suppurative^a^ | 3 (1.0)^b^ | 4 (1.5) | 35** (1.9) | 50** (3.9)
Respiratory Epithelium, Hyperplasia | 0 | 2 (1.0) | 5* (1.2) | 50** (3.7)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 5* (1.0) | 34** (2.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 2 (1.0)
Olfactory Epithelium, Atrophy | 0 | 5* (1.4) | 27** (1.4) | 22** (1.3)
Olfactory Epithelium, Metaplasia, Respiratory | 1 (1.0) | 3 (1.3) | 6 (1.7) | 50** (3.2)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 6* (1.3)
Turbinate, Hyperostosis | 0 | 0 | 0 | 10** (1.2)
Lamina Propria, Fibrosis | 0 | 0 | 28** (1.0) | 38** (1.2)
Squamous Cell Papilloma^c^ | 0 | 0 | 0 | 1
Squamous Cell Carcinoma^c^
Overall rate^d^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^e^ | 0.0% | 0.0% | 0.0% | 7.5%
Terminal rate^f^ | 0/36 (0%) | 0/37 (0%) | 0/33 (0%) | 1/22 (5%)
First incidence (days) | –^h^ | – | – | 616
Poly-3 test^g^ | P = 0.010 | –^i^ | – | P = 0.101
Squamous Cell Papilloma or Carcinoma^c^ | – | – | – | –
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 9.9%
Terminal rate | 0/36 (0%) | 0/37 (0%) | 0/33 (0%) | 1/22 (5%)
First incidence (days) | – | – | – | 589
Poly-3 test | P = 0.002 | – | – | P = 0.049
Adenoma^j^ | 1 | 0 | 0 | 0
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Inflammation, Suppurative | 4 (1.8) | 3 (1.0) | 11* (1.5) | 49** (3.9)
Respiratory Epithelium, Hyperplasia | 1 (2.0) | 0 | 2 (1.0) | 44** (3.4)
Respiratory Epithelium, Metaplasia, Squamous | 1 (2.0) | 0 | 1 (2.0) | 44** (1.8)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 3 (3.3)
Olfactory Epithelium, Atrophy | 1 (1.0) | 1 (1.0) | 14** (1.4) | 24** (1.9)
Olfactory Epithelium, Metaplasia, Respiratory | 1 (4.0) | 0 | 18** (1.3) | 46** (2.8)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 4 (2.8)
Turbinate, Hyperostosis | 0 | 0 | 0 | 8** (1.0)
Lamina Propria, Fibrosis | 1 (1.0) | 1 (1.0) | 17** (1.0) | 46** (1.4)
Squamous Cell Carcinoma^c^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate | 0/34 (0%) | 0/31 (0%) | 0/24 (0%) | 2/30 (7%)
First incidence (days) | – | – | – | 724
Poly-3 test | P = 0.011 | – | – | P = 0.118

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked.

^c^ Historical control incidence for squamous cell papilloma, squamous cell carcinoma, or squamous cell papilloma or carcinoma of the nose in Wistar Han rats in 2-year inhalation studies with chamber control groups: 0/200 males and 0/200 females; all routes: 0/349 males and 0/350 females.

^d^ Number of animals with neoplasm per number of animals with nose examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal euthanasia.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

^j^ Historical incidence for 2-year inhalation studies (mean ± standard deviation): 1/200 (0.5% ± 1.0%), range 0%–2%; all routes 1/349 (0.3% ± 0.8%), range 0%–2%.

Figure 8

Squamous Cell Carcinoma in the Nose of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplasm forms a bulbous mass (arrow), arising from the tip of a nasoturbinate in Level II, and projects into the nasal cavity. B) The neoplasm invades into the fibrotic stroma of the nasoturbinate (arrow). C) Between the nests of neoplastic cells, a few remnants of bone (arrowhead) from the nasoturbinate hook are seen. Dilated respiratory glands (asterisk), probably secondary to outflow obstruction, are also noted. D) Many of the nests of neoplastic cells have central cystic spaces filled with keratin and cell debris (asterisk). Original objective magnification: A = 1×, B = 4×, C = 10×, D = 20×.

Figure 9

Squamous Cell Carcinoma in the Nose of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A, B) The neoplasm forms a plaque-like mass, arising from the lateral wall (arrowhead) of the nasal cavity and the adjacent maxilloturbinate (arrow). C) The keratinizing squamous carcinoma (arrow) invades the stroma adjacent to the bone (arrowheads) of the maxilloturbinate. D, E, F) The lateral wall portion of the neoplasm exhibits foci of microinvasion (arrowheads) into the lamina propria close to the alveolar process of the premaxillary bone. Original objective magnification: A = 1×, B = 2×, C = 4×, D = 4×, E = 10×, F = 20×.

Figure 10

Squamous Cell Carcinoma in the Nose of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplasm forms a large solid and cystic mass, filling and expanding one side of the nasal cavity in Levels I and II, with deviation of the nasal septum to the opposite side. The main portion of the solid neoplasm is located in the dorsolateral wall (top arrowhead), but the infiltration also extends laterally and ventrally to invade the premaxilla bone (lower arrowhead). The cystic spaces (asterisk) are probably dilated respiratory glands with their ducts obstructed by the invasive neoplasm. B, C) The inner surface of the neoplasm shows a keratinizing squamous carcinoma (lower right), with buds (arrowheads) and nests (arrow in C) of invasion into the lamina propria. D) Much of the invasive neoplasm consists of a solid, spindle cell component with only scattered squamous cell nests (arrowhead). A cystically dilated respiratory gland is present in the upper left (asterisk). E) The neoplasm (arrowhead) invades through the frontal process of the premaxillary bone into the surrounding muscle. F) The spindle cell character of the invasive neoplasm is evident (between the arrowheads). Original objective magnification: A = 1×, B = 10×, C = 10×, D = 10×, E = 10×, F = 20×.

Figure 11

Squamous Cell Papilloma in the Nose of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The necrotic, polypoid mass extends from the dorsal end (top arrow) of the nasal cavity almost to the ventral end (bottom arrow). B) Necrotic neoplasm largely fills the lateral meatus (upper asterisk), wraps around the nasoturbinate, and extends into the dorsal meatus (lower asterisk). C) Arrows indicate the pedicle of the neoplasm at the base of the nasoturbinate. D) Focal islands of residual squamous epithelium with keratin are noted (arrowheads). E) Residual nests of squamous epithelium are indicated by the arrow and the arrowhead, with the latter lying adjacent to bone fragments. F) A nest of neoplastic cells (arrow) lies adjacent to bone (arrowhead). Fibrotic stroma is present in the center. Original objective magnification: A = 1×, B = 4×, C = 10×, D = 10×, E = 10×, F = 20×.

Figure 12

Squamous Cell Carcinoma in the Nose of a Female Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplasm involves much of the lateral wall (between the arrows) on one side of Level I. B) The neoplasm invades the lamina propria (arrow) close to the premaxillary bone. C) Perineural invasion is present (arrow). D) Nests of neoplastic cells invade the naso-premaxillary suture (arrows). E) A nest of neoplastic cells (arrow) within a Haversian canal in the premaxillary bone. The neoplasm probably reached the interior of the bone by invading through a Volkmann canal on the dorsomedial side of the bone. F) Atypical squamous metaplasia (arrow) with marked hyperkeratosis (asterisk), is replacing the respiratory epithelium of the lateral wall. This type of metaplasia is atypical both architecturally and cytologically and is a probable background precursor for the development of squamous carcinoma. Original objective magnification: A = 1×, B = 4×, C = 10×, D = 10×, E = 20×, F = 10×.

Figure 13

Squamous Cell Carcinoma in the Nose of a Female Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplasm extends from near the ventral end (lower arrow) of the lateral wall to the dorsal end (upper arrow). Note that the bulbous expansion of the neoplasm dorsally has caused the adjacent lateral hook of the nasoturbinate to deviate medially. B) Nests of neoplastic cells invade the lamina propria. C) The neoplasm invades the lamina propria (arrow) of the ventral meatus, adjacent to the incisor tooth (asterisk). D) Neoplasm invades the deeper portion of the lamina propria (arrow), adjacent to the alveolar process of the premaxillary bone. Original objective magnification: A = 1×, B = 4×, C = 4×, D = 10×.

Figure 14

Squamous Cell Carcinoma in the Nose of a Female Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplasm forms a plaque-like lesion along the lateral wall of Level II (arrows). B) The neoplasm (arrows) is superficial, in situ, and hyperkeratotic in this region. C, D) Small buds of microinvasive neoplasm are noted in the lamina propria (arrows). Original objective magnification: A = 1×, B = 10×, C = 10×, D = 20×.

No squamous cell carcinomas or papillomas of the nose occurred in the concurrent male or female chamber controls, and none are recorded in the NTP historical control database (Table 10). The combined incidence of three squamous cell carcinomas and one squamous cell papilloma in the 50 ppm male rats was significantly increased. One adenoma occurred in Level III of a con-current chamber control male (Table 10 and Table A-1).

A spectrum of nonneoplastic lesions occurred in both the respiratory and olfactory epithelium, primarily in the 25 and 50 ppm groups (Table 10, Table A-3, and Table B-3). Suppurative inflammation, usually of marked severity, occurred in almost all 50 ppm males and females and also occurred, usually to a mild degree, in most of the 25 ppm males and some of the 25 ppm females. The inflammation consisted of both exudate in the nasal cavities and inflammatory infiltrate within the nasal mucosa. The respiratory epithelium in Levels I and II exhibited both moderate to marked epithelium hyperplasia and mild squamous metaplasia in most of the 50 ppm males and females; minimal respiratory epithelium hyperplasia and squamous metaplasia occurred in a few of the 25 ppm males. The respiratory epithelium hyperplasia occurred most often along the nasal septum of Levels I and II, and was characterized by increased cell density, numerous goblet cells, and increased thickness, often with folds. Minimal to mild olfactory epithelial atrophy occurred in many of the animals exposed to 25 or 50 ppm, and respiratory metaplasia of the olfactory epithelium occurred in almost all of the 50 ppm animals and in some of the 25 ppm animals. Both the atrophy and the respiratory metaplasia of the olfactory epithelium occurred most often in the dorsal meatus of Level II. In a few 50 ppm males and females, foci of necrosis occurred in either the olfactory or respiratory epithelia. Turbinate hyperostosis, characterized by increased thickness of the turbinate bone, occurred in a few of the 50 ppm rats, usually in the nasoturbinates.

In addition to the inflammation and spectrum of epithelial lesions, most of the animals exposed to 50 ppm, and many of those exposed to 25 ppm, exhibited fibrosis of the lamina propria of the nasal mucosa, primarily in Levels I and II (Figure 15) (Table 10, Table A-3, and Table B-3). The fibrosis was characterized by increased collagenous tissue immediately beneath the mucosal epithelium, with few or absent glands and vessels, most often present along the lateral walls of the nasal cavities and the tips of the nasoturbinates.

Figure 15

Normal Nasoturbinate, Level II, in the Nose of a Chamber Control Male Wistar Han Rat at Two Years (A), and Fibrosis in the Nose, Nasoturbinate Level II, of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

B) The lamina propria exhibits fibrosis (long arrow) with replacement of the glands. The mucosal respiratory epithelium in A (arrowhead) covering the turbinate has been replaced by regenerative hyperplastic epithelium in B (arrowhead). The tip of the turbinate bone is hyperostotic (short arrow). Original objective magnification: A = 20×, B = 20×.

Larynx: Most of the lesions in the larynx were significantly increased in only the 50 ppm groups (Table 11, Table A-3, and Table B-3). Minimal to mild chronic active inflammation occurred in most of the 50 ppm males and in half of the 50 ppm females. The inflammation consisted primarily of neutrophils with lesser numbers of lymphocytes and plasma cells and was most often present in the ventral pouch and/or the submucosa of the arytenoid processes where the squamous epithelium was often hyperplastic or ulcerated. Hyperplasia of the squamous epithelium overlying the arytenoid cartilages, graded as mild to moderate, occurred in almost all 50 ppm males and females, and hyperplasia of lesser degree occurred in a few of the rats exposed to 25 ppm. Focal areas of ulceration of the squamous epithelium occurred in some of the rats exposed to 50 ppm. Squamous metaplasia of the respiratory epithelium occurred in most of the 50 ppm animals. Squamous metaplasia was most commonly noted to start at the base of the epiglottis in Level I in minimal cases, with extension along the sides of the larynx in cases of mild severity. Moderate severity was used when the entire base of the epiglottis and two levels of the larynx were involved, and marked severity was reserved for cases in which all three levels of larynx were involved. The average severity of respiratory epithelium squamous metaplasia was in the mild to moderate range for both males and females.

Table 11 Incidences of Nonneoplastic Lesions of the Respiratory System in Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Larynx^a^ | 50 | 50 | 50 | 50
Inflammation, Chronic Active^b^ | 14 (1.1)^c^ | 7 (1.1) | 7 (1.0) | 33** (1.2)
Squamous Epithelium, Hyperplasia | 2 (1.0) | 2 (2.0) | 8* (1.3) | 46** (2.4)
Squamous Epithelium, Ulcer, Focal | 0 | 0 | 0 | 15** (1.3)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 1 (1.0) | 0 | 45** (2.3)
Trachea | 50 | 50 | 50 | 50
Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 8** (1.3)
Epithelium, Hyperplasia | 0 | 0 | 1 (1.0) | 32** (1.2)
Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 12** (1.2)
Epithelium, Regeneration | 0 | 0 | 5* (1.0) | 12** (1.1)
Epithelium, Atrophy | 0 | 0 | 0 | 7** (1.1)
Epithelium, Necrosis | 0 | 0 | 0 | 6** (1.0)
Submucosa, Fibrosis | 0 | 0 | 0 | 27** (1.1)
Lung | 50 | 49 | 50 | 50
Inflammation, Suppurative | 0 | 0 | 1 (2.0) | 15** (2.4)
Inflammation, Granulomatous | 4 (1.0) | 3 (1.0) | 1 (1.0) | 4 (1.0)
Peribronchial, Inflammation, Chronic Active | 0 | 0 | 0 | 13** (1.5)
Bronchus, Epithelium, Hyperplasia | 0 | 0 | 2 (1.0) | 47** (1.2)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 33** (1.3)
Bronchus, Epithelium, Atrophy | 0 | 0 | 1 (1.0) | 23** (1.0)
Bronchus, Epithelium, Regeneration | 0 | 0 | 4 (1.0) | 9** (1.0)
Bronchus, Submucosa, Fibrosis | 0 | 0 | 0 | 5* (1.0)
Alveolus, Infiltration Cellular, Histiocyte | 10 (1.1) | 14 (1.2) | 16 (1.1) | 34** (1.4)
Alveolar Epithelium, Hyperplasia | 1 (2.0) | 4 (1.0) | 2 (1.0) | 8** (1.1)
Interstitium, Fibrosis | 0 | 1 (1.0) | 1 (1.0) | 11** (1.3)
Female
Larynx | 50 | 50 | 50 | 50
Inflammation, Chronic Active | 4 (1.0) | 2 (1.0) | 4 (1.0) | 25** (1.3)
Squamous Epithelium, Hyperplasia | 1 (1.0) | 1 (2.0) | 6* (1.0) | 48** (2.5)
Squamous Epithelium, Ulcer, Focal | 0 | 0 | 0 | 5* (1.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 35** (2.3)
Trachea | 50 | 50 | 50 | 50
Inflammation, Chronic Active | 0 | 0 | 0 | 20** (2.0)
Epithelium, Hyperplasia | 0 | 0 | 0 | 30** (1.5)
Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 3 (2.0)
Epithelium, Regeneration | 0 | 0 | 0 | 3 (1.0)
Epithelium, Atrophy | 0 | 0 | 0 | 4 (1.0)
Epithelium, Necrosis | 0 | 0 | 0 | 1 (2.0)
Submucosa, Fibrosis | 0 | 0 | 0 | 19** (1.8)
Lung | 50 | 50 | 50 | 50
Inflammation, Suppurative | 0 | 0 | 0 | 3 (2.3)
Inflammation, Granulomatous | 2 (1.0) | 1 (1.0) | 3 (1.0) | 13** (1.0)
Peribronchial, Inflammation, Chronic Active | 1 (1.0) | 2 (1.0) | 0 | 27** (1.5)
Bronchus, Epithelium, Hyperplasia | 0 | 0 | 0 | 46** (1.4)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 8** (1.0) | 39** (1.4)
Bronchus, Epithelium, Atrophy | 0 | 0 | 0 | 7** (1.0)
Bronchus, Epithelium, Regeneration | 0 | 0 | 1 (1.0) | 2 (1.0)
Alveolus, Infiltration Cellular, Histiocyte | 13 (1.1) | 11 (1.0) | 10 (1.0) | 32** (1.3)
Alveolar Epithelium, Hyperplasia | 1 (1.0) | 1 (1.0) | 1 (1.0) | 3 (1.3)
Interstitium, Fibrosis | 1 (1.0) | 1 (1.0) | 1 (2.0) | 9** (1.2)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Trachea: Mild chronic active inflammation occurred in the mucosa and submucosa, and sometimes deeper structures, of many 50 ppm females, and minimal to mild inflammation occurred in a few 50 ppm males (Table 11, Table A-3, and Table B-3). A variety of epithelial lesions occurred in the mucosa, the most common being epithelium hyperplasia, which occurred in most 50 ppm males and females. Epithelium squamous metaplasia and/or epithelium regeneration occurred in some 50 ppm males and a few 50 ppm females; epithelium regeneration also occurred in a few 25 ppm males. Minimal epithelium atrophy occurred in a few 50 ppm rats, and focal epithelium necrosis occurred in a few 50 ppm males and one 50 ppm female. In addition to the epithelial lesions, submucosa fibrosis occurred in many 50 ppm males and females. The fibrosis was characterized by an increase in fibrous connective tissue that expanded a portion of the submucosa in minimal to mild cases and extended into the deeper tissues in moderate to marked cases (Figure 16). In severely affected animals, the fibrosis extended around the cartilage rings and was associated with loss of cartilage.

Figure 16

Fibrosis in the Trachea of a Female Wistar Han Rat (A) and A Male Wistar Han Rat (B), Both Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) There is marked fibrotic thickening of the wall (arrows), except for one segment at the bottom (between the arrowheads). Much of the cartilage in the wall has been replaced by the fibrosis, and there is reduction in the size of the tracheal lumen. B) Marked fibrotic thickening of the tracheal submucosa (arrow). Original objective magnification: A = 4×, B = 20×.

Lung: Inflammation of various types occurred in the airways and/or the alveolar parenchyma of the lung in many animals (Table 11, Table A-3, and Table B-3). Based on the cell type of the infiltrate and the location, most of these inflammatory lesions fell into one of three categories: suppurative, granulomatous, or peribronchial chronic active. Suppurative inflammation occurred mainly in the 50 ppm groups, primarily in the males, and was characterized by neutrophilic exudate within airway lumens, alveolar spaces, or both (Figure 17). Bacterial clusters were sometimes noted in areas of suppuration. Suppurative inflammation in the lungs may have been secondary to aspiration of inflammatory exudate from the upper respiratory tract, perhaps combined with impaired warming, humidifying, and filtering of the air by the inflamed nasal passages. Granulomatous inflammation occurred in a few animals in each exposed group, as well as in the chamber controls, and the incidence was significantly increased in 50 ppm females. This type of inflammation consisted of macrophages and giant cells often surrounding small fragments of foreign material, which was thought to have been aspirated from the upper respiratory tract. Peribronchial chronic active inflammation occurred primarily in the 50 ppm groups, occurring in several males and many females, and it consisted of mixed cell infiltrates surrounding bronchi, bronchioles, and blood vessels.

Figure 17

Suppurative Inflammation in the Lung of Two Male Wistar Han Rats Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

There is suppurative exudate in the bronchial lumens (arrowheads) (A and B). In A, acute inflammation is present around the bronchial branches and in the alveolar spaces of the lung (arrow). In B, the lung also exhibits dense aggregates (arrows) of inflammatory cells and bacterial colonies. Original objective magnification: A = 10×, B = 2×.

A variety of lesions occurred in the airways (Table 11, Table A-3, and Table B-3). Most common of these was epithelium hyperplasia, occurring in both the bronchi and the bronchioles of most of the 50 ppm males and females. Minimal bronchiolar epithelium hyperplasia also occurred in a few 25 ppm females and minimal bronchial epithelium hyperplasia in two 25 ppm males. Both bronchial and bronchiolar epithelium hyperplasia were characterized by increased epithelial height and cell density (Figure 18). The bronchiolar lesion sometimes included goblet cell metaplasia and occurred most often in areas of moderate to marked inflammation. Many 50 ppm males and a few 50 ppm females also exhibited areas of minimal epithelium atrophy within the extrapulmonary bronchi; the epithelium in these areas was reduced in height but retained some cilia. Retention of cilia was used to differentiate epithelium atrophy from epithelium regeneration, which also occurred in the extrapulmonary bronchi in a few 50 ppm males and females and was characterized by a single layer of flattened, nonciliated epithelial cells that appeared to have stretched to cover a denuded surface. Small areas of submucosa fibrosis occurred in the extrapulmonary bronchi just below the tracheal carinae in five 50 ppm males (Figure 18).

Figure 18

Bronchus Epithelium Hyperplasia (A) and Submucosa Fibrosis (B) in the Bronchi of Male Wistar Han Rats Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) Much of the mucosal epithelium shows mild hyperplasia (arrowheads), characterized by thickening and increased cellularity (compare to normal columnar epithelium at arrow). B) There is hyaline fibrosis of the submucosa (arrow) in this extra-pulmonary bronchus, and replacement of the respiratory epithelium in the center by a flattened, regenerating epithelium (arrowhead). Original objective magnification: A = 20×, B = 20×.

Lesions occurring in the lung parenchyma included histiocytic cellular infiltration in the alveolar spaces, alveolar epithelium hyperplasia, and interstitium fibrosis (Table 11, Table A-3, and Table B-3). Clusters of alveolar histiocytes occurred in most of the rats exposed to 50 ppm, as well as in some of the chamber controls and rats exposed to 12.5 or 25 ppm. Minimal alveolar epithelium hyperplasia occurred in a few chamber control and exposed animals and was increased in incidence in 50 ppm males. Minimal to mild interstitium fibrosis of alveolar septae occurred in 11 males and nine females in the 50 ppm groups. The interstitium fibrosis was characterized by thickening of alveolar septae by eosinophilic, collagenous material that caused the septae to take on a straightened or stiff appearance. In some animals the fibrosis formed nodular foci that expanded the alveolar walls and extended in tendrils into the surrounding alveolar septae (Figure 19).

Figure 19

Interstitium Fibrosis in the Lung of a Male Wistar Han Rat Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (A and B) (H&E)

Nodular foci of interstitial fibrosis of the alveolar walls, accompanied by inflammatory infiltrate, extend irregularly into the surrounding alveolar septa (arrows). Original objective magnification: A = 4×, B = 10×.

Eye: Chronic active inflammation of the cornea occurred in most of the 50 ppm animals, many of those exposed to 25 ppm, and a few of the 12.5 ppm and chamber control rats (Table 12, Table A-3, and Table B-3). Grading of the inflammation was based upon intensity, extent of the cornea involved, and bilaterality. Most animals with inflammation fell into the minimal to mild categories. Moderate severity was diagnosed when involvement was at least 50% in both eyes or greater than 67% in one eye, and marked severity when perforation appeared imminent or had occurred. More females than males had moderate inflammation, and a few 12.5 and 25 ppm females were graded as marked. In a few 25 and 50 ppm rats, acute and/or suppurative inflammation occurred in the anterior chamber and/or the iris. Minimal to moderate cornea epithelium hyperplasia occurred in a few animals in each exposed group. Cornea epithelium ulcers, usually minimal to mild, occurred in a few animals in the 25 and 50 ppm groups and in one male and one female exposed to 12.5 ppm. Minimal corneal epithelial necrosis occurred in two 50 ppm males, and minimal corneal stromal necrosis occurred in one 25 ppm female. Focal areas of mineralization of the corneal stroma, probably related to previous injury, occurred in a few animals. Increased incidences of cataract of the lens occurred in all exposed groups of males and in 25 and 50 ppm females, and the increases were significant in the 25 ppm males and in 25 and 50 ppm females. Phthisis bulbi, characterized by shrinkage of the globe with structural disorganization, occurred in a few exposed males and females, and the incidence was significantly increased in 50 ppm females.

Table 12 Incidences of Selected Nonneoplastic Lesions in Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Eye^a^ | 50 | 50 | 49 | 49
Cornea, Inflammation, Chronic Active^b^ | 1 (1.0)^c^ | 6 (2.3) | 16** (1.6) | 28** (1.3)
Anterior Chamber, Inflammation, Suppurative | 0 | 1 (1.0) | 6* (1.3) | 3 (2.0)
Iris, Inflammation, Acute | 0 | 1 (1.0) | 3 (1.0) | 1 (2.0)
Cornea, Epithelium, Hyperplasia | 0 | 2 (1.0) | 3 (1.7) | 6** (1.2)
Cornea, Epithelium, Ulcer | 0 | 1 (1.0) | 4 (1.3) | 6** (1.5)
Cornea, Necrosis | 0 | 0 | 0 | 2 (1.0)
Cornea, Mineralization | 1 (1.0) | 4 (1.0) | 1 (1.0) | 0
Lens, Cataract | 1 (2.0) | 5 (1.6) | 6* (1.3) | 3 (1.7)
Unilateral, Phthisis Bulbi | 0 | 1 (4.0) | 3 (3.7) | 1 (3.0)
Bilateral, Phthisis Bulbi | 0 | 0 | 1 (4.0) | 0
Bone Marrow | 50 | 50 | 50 | 50
Myeloid Cell, Hyperplasia | 15 (2.9) | 12 (2.8) | 16 (2.8) | 32** (2.9)
Skin | 50 | 50 | 50 | 50
Foot, Inflammation, Chronic Active | 11 (3.3) | 7 (3.1) | 17 (3.2) | 23** (3.0)
Foot, Ulcer | 14 (3.5) | 7 (3.4) | 17 (3.4) | 22 (2.9)
Female
Eye | 50 | 50 | 50 | 50
Cornea, Inflammation, Chronic Active | 2 (1.5) | 6 (2.0) | 23** (1.9) | 31** (2.0)
Anterior Chamber, Inflammation, Suppurative | 1 (1.0) | 0 | 6* (2.5) | 5 (1.8)
Iris, Inflammation, Acute | 0 | 0 | 5* (1.8) | 4 (1.0)
Cornea, Epithelium, Hyperplasia | 0 | 3 (2.0) | 8** (1.4) | 5* (1.4)
Cornea, Epithelium, Ulcer | 0 | 1 (2.0) | 2 (2.5) | 13** (1.8)
Cornea, Necrosis | 0 | 0 | 1 (1.0) | 0
Cornea, Mineralization | 0 | 1 (1.0) | 0 | 2 (1.0)
Lens, Cataract | 1 (1.0) | 1 (3.0) | 6* (1.5) | 9** (1.7)
Unilateral, Phthisis Bulbi | 0 | 1 (2.0) | 0 | 8** (3.1)
Bone Marrow | 50 | 50 | 50 | 50
Myeloid Cell, Hyperplasia | 12 (2.9) | 19 (3.2) | 20 (3.0) | 36** (2.9)
Skin | 50 | 50 | 50 | 50
Foot, Inflammation, Chronic Active | 0 | 0 | 0 | 4 (2.8)
Foot, Ulcer, Focal | 0 | 0 | 0 | 4 (3.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bone Marrow: Significantly increased incidences of myeloid cell hyperplasia occurred in 50 ppm males and females (Table 12, Table A-3, and Table B-3). The increase in myeloid cells in the marrow was probably a secondary reactive response to the inflammatory changes in the respiratory tract.

Skin: Incidences of chronic active inflammation and ulcer of the skin of the foot occurred in both chamber control and exposed groups of males; these lesions occurred with increased incidences in 25 and 50 ppm males and also occurred in a few 50 ppm females (Table 12, Table A-3, and Table B-3). These lesions were thought to be secondary to the large size of the Wistar Han rats, particularly the males, and walking on the wire caging. The increased incidences in the higher exposure concentration groups may have been related to debilitation and chemical exposure.

## Mice

### Three-month Study

All mice survived to the end of the study (Table 13). The final mean body weights and body weight gains of males exposed to 50 or 100 ppm and females exposed to 12.5 ppm or greater were significantly less than those of the chamber control groups (Table 13 and Figure 5). Sneezing was observed in 50 ppm males (9/10) and females (8/10) and 100 ppm males (9/10) and females (9/10). Abnormal breathing was observed in 100 ppm males (2/10) and females (1/10).

Table 13 Survival and Body Weights of Mice in the Three-month Inhalation Study of 2,3-Butanedione^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 24.9 ± 0.4 | 37.8 ± 1.2 | 12.9 ± 1.1
6.25 | 10/10 | 24.7 ± 0.3 | 38.0 ± 1.3 | 13.3 ± 1.0 | 101
12.5 | 10/10 | 24.9 ± 0.2 | 37.8 ± 0.7 | 13.0 ± 0.6 | 100
25 | 10/10 | 25.3 ± 0.3 | 39.1 ± 0.6 | 13.8 ± 0.6 | 103
50 | 10/10 | 24.4 ± 0.3 | 34.2 ± 1.1* | 9.7 ± 0.8** | 90
100 | 10/10 | 24.7 ± 0.2 | 27.9 ± 0.6** | 3.2 ± 0.5** | 74
Female
0 | 10/10 | 20.1 ± 0.3 | 33.0 ± 0.9 | 12.9 ± 0.9
6.25 | 10/10 | 20.6 ± 0.2 | 31.8 ± 0.7 | 11.2 ± 0.7 | 96
12.5 | 10/10 | 20.1 ± 0.2 | 30.9 ± 0.6* | 10.8 ± 0.6* | 94
25 | 10/10 | 20.0 ± 0.2 | 29.4 ± 0.7** | 9.4 ± 0.5** | 89
50 | 10/10 | 20.3 ± 0.3 | 27.6 ± 0.5** | 7.4 ± 0.4** | 84
100 | 10/10 | 20.4 ± 0.3 | 23.8 ± 0.5** | 3.4 ± 0.6** | 72

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 5

Growth Curves for Mice Exposed to 2,3-Butanedione by Inhalation for Three Months

At study termination, neutrophil counts in the blood were increased in 50 and 100 ppm male mice and 100 ppm female mice (Table 14 and Table F-2) and were consistent with inflammation. In 50 and 100 ppm males and 100 ppm females, mean cell volume and mean cell hemoglobin were significantly decreased, indicating a reduction in erythrocyte size. This may indicate some minimal alteration in iron metabolism or hemoglobin production during erythropoiesis. All other statistically significant changes in hematology parameters were minimal and not considered toxicologically relevant.

Table 14 Selected Hematology Data for Mice in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Mean cell volume (fL) | 48.7 ± 0.2 | 48.3 ± 0.3 | 48.9 ± 0.3 | 48.8 ± 0.1 | 47.8 ± 0.3* | 46.6 ± 0.3**
Mean cell hemoglobin (pg) | 15.1 ± 0.1 | 14.9 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1* | 14.6 ± 0.1**
Segmented neutrophils (10^3^/µL) | 0.42 ± 0.05 | 0.38 ± 0.03 | 0.42 ± 0.06 | 0.42 ± 0.03 | 1.22 ± 0.57* | 0.96 ± 0.20**
Female
Mean cell volume (fL) | 49.0 ± 0.2 | 49.1 ± 0.1 | 49.2 ± 0.2 | 49.1 ± 0.2 | 48.6 ± 0.1 | 47.2 ± 0.2**
Mean cell hemoglobin (pg) | 15.4 ± 0.1 | 15.4 ± 0.0 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.0 | 14.8 ± 0.1**
Segmented neutrophils (10^3^/µL) | 0.53 ± 0.08 | 0.47 ± 0.06 | 0.42 ± 0.06 | 0.59 ± 0.08 | 0.79 ± 0.16 | 1.04 ± 0.19*

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

Significant changes in organ weights were restricted to the 50 and 100 ppm groups (Table G-2). Relative lung weights were significantly increased in 50 ppm males and 100 ppm males and females. Absolute heart, kidney, and liver weights of males and females were significantly decreased in the 50 and 100 ppm groups. Relative kidney weights in females were significantly increased at 25 ppm and higher. Relative spleen weights in males were increased at 100 ppm and absolute spleen weights of females were decreased at 50 and 100 ppm. Absolute testis weights were significantly decreased and relative testis weights were significantly increased in 100 ppm males. Relative thymus weights were significantly decreased in 100 ppm males. Absolute thymus weights in females were significantly deceased at all exposure concentrations. These findings are of uncertain toxicologic significance given the body weight decreases in the exposed groups and the lack of treatment-related lesions in these tissues.

No gross lesions associated with exposure to 2,3-butanedione were noted in mice at the time of necropsy. Exposure-related histopathologic findings occurred primarily in the respiratory tract. Lesions in the nose occurred predominantly in the 50 and 100 ppm groups (Table 15). Minimal to moderate suppurative inflammation occurred in all males and females in the 50 and 100 ppm groups. The inflammation usually involved all levels of the nose and consisted of neutrophilic exudate combined with varying amounts of eosinophilic proteinaceous material within the lumen of the nasal cavity. Occasionally, neutrophils were also present within the nasal mucosal epithelium and underlying lamina propria, particularly in areas of necrosis. Large quantities of the eosinophilic proteinaceous material were present in some noses and filled or nearly filled the nasal cavity, especially in Level III. Minimal to mild respiratory epithelium necrosis occurred in all mice in the 50 and 100 ppm groups, and minimal necrosis occurred in eight males and four females exposed to 25 ppm. Respiratory epithelium regeneration, usually characterized by a single layer of flattened, elongated cells covering the surface, occurred in almost all animals in the 50 and 100 ppm groups, presumably occurring in areas previously denuded by necrosis. Moderate turbinate atrophy, primarily affecting the nasoturbinate bones in Level I, occurred in all mice exposed to 50 or 100 ppm and consisted of variable loss of bone associated with shortening and blunting of the turbinate bone. In some of the animals exposed to 50 or 100 ppm, turbinate necrosis also occurred in which fragments of the nasoturbinate hooks were detached from the body of the turbinate and were lacking in both osteocytes and osteoblasts. Necrosis of the nasal septum cartilage occurred in one 100 ppm female, and perforation of the nasal septum occurred in two 100 ppm males. Mild to moderate squamous metaplasia of the respiratory epithelium occurred in all mice exposed to 50 or 100 ppm. In the dorsal portions of Levels II and III in all mice exposed to 50 or 100 ppm, the olfactory epithelium exhibited minimal to mild atrophy with variable degrees of thinning of the olfactory epithelium. Olfactory epithelium respiratory metaplasia also occurred in most of these 50 and 100 ppm mice, usually in Level II and sometimes also in Level III.

Table 15 Incidences of Nonneoplastic Lesions of the Respiratory System in Mice in the Three-month Inhalation Study of 2,3-Butanedione

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative^b^ | 0 | 0 | 0 | 0 | 10** (1.9)^c^ | 10** (3.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 8** (1.0) | 10** (2.0) | 10** (1.7)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 10** (2.0) | 10** (3.0)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 10** (3.0) | 10** (3.0)
Turbinate, Necrosis | 0 | 0 | 0 | 0 | 3 (1.0) | 5* (1.0)
Septum, Perforation | 0 | 0 | 0 | 0 | 0 | 2 (2.5)
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 10** (1.8) | 10** (1.6)
Olfactory Epithelium, Metaplasia, Respiratory | 0 | 0 | 0 | 0 | 6** (1.5) | 7** (1.6)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Necrosis | 0 | 0 | 2 (1.0) | 1 (1.0) | 9** (1.0) | 8** (1.0)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 0 | 5* (1.2) | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 3 (1.3) | 0
Respiratory Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 7** (1.3) | 10** (3.4)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 8** (1.5) | 8** (2.4)
Squamous Epithelium, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 3 (1.3) | 5* (2.6)
Squamous Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 7** (1.7) | 5* (2.8)
Inflammation, Chronic Active | 1 (1.0) | 1 (1.0) | 3 (1.0) | 3 (1.7) | 8** (1.1) | 10** (1.2)
Trachea | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 10** (2.8)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 9** (2.4)
Epithelium, Degeneration | 0 | 0 | 0 | 1 (1.0) | 3 (1.3) | 8** (2.0)
Epithelium, Regeneration | 0 | 0 | 0 | 0 | 7** (1.6) | 0
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 7** (1.1)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Inflammation, Chronic | 1 (1.0) | 0 | 0 | 0 | 7** (1.3) | 10** (2.7)
Bronchus, Infiltration Cellular, Polymorphonuclear | 0 | 0 | 0 | 0 | 0 | 10** (1.7)
Bronchus, Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 2 (1.5) | 9** (2.1)
Bronchus, Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 10** (2.2)
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 0 | 1 (1.0) | 9** (2.6)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative | 0 | 0 | 0 | 1 (1.0) | 10** (2.1) | 10** (3.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 4* (1.0) | 10** (1.6) | 10** (2.0)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 0 | 9** (1.1) | 10** (1.6)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 10** (2.0) | 10** (3.0)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 10** (3.0) | 10** (3.0)
Turbinate, Necrosis | 0 | 0 | 0 | 0 | 4* (1.0) | 8** (1.3)
Septum, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 10** (2.0) | 10** (2.0)
Olfactory Epithelium, Metaplasia, Respiratory | 0 | 0 | 0 | 0 | 8** (1.6) | 9** (1.7)
Larynx | 10 | 10 | 10 | 10 | 9 | 10
Epithelium, Necrosis | 0 | 0 | 0 | 1 (1.0) | 5* (1.0) | 9** (1.2)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 2 (1.0) | 8** (1.6) | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 9** (1.6) | 0
Respiratory Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 10** (3.4)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 4* (1.0) | 8** (1.1) | 9** (2.3)
Squamous Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 4* (1.8) | 1 (2.0)
Squamous Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 2 (1.0) | 3 (1.3) | 9** (2.9)
Inflammation, Chronic Active | 0 | 3 (1.0) | 1 (1.0) | 4* (1.0) | 4* (1.0) | 10** (1.6)
Trachea | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 10** (3.2)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 9** (2.2)
Epithelium, Degeneration | 0 | 0 | 0 | 0 | 3 (1.7) | 8** (1.9)
Epithelium, Regeneration | 0 | 0 | 0 | 0 | 7** (2.1) | 0
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 0 | 7** (1.1)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Inflammation, Chronic | 1 (1.0) | 0 | 0 | 0 | 5 (1.6) | 8** (2.4)
Bronchus, Infiltration Cellular, Polymorphonuclear | 0 | 0 | 0 | 0 | 0 | 8** (1.6)
Bronchus, Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 0 | 7** (2.3)
Bronchus, Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 7** (2.0)
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 0 | 6** (1.0) | 7** (2.3)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Inflammation, Chronic | 1 (1.0) | 0 | 0 | 0 | 5 (1.6) | 8** (2.4)
Bronchus, Infiltration Cellular, Polymorphonuclear | 0 | 0 | 0 | 0 | 0 | 8** (1.6)
Bronchus, Epithelium, Hyperplasia, Atypical | 0 | 0 | 0 | 0 | 0 | 7** (2.3)
Bronchus, Epithelium, Metaplasia, Atypical Squamous | 0 | 0 | 0 | 0 | 0 | 7** (2.0)
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 0 | 6** (1.0) | 7** (2.3)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the larynx, epithelium necrosis, usually minimal, occurred in most of the males and females exposed to 50 or 100 ppm, in one male and one female in the 25 ppm groups, and in two males in the 12.5 ppm group (Table 15). The necrosis occurred primarily either in the squamous epithelium lining the arytenoid cartilages or in the respiratory epithelium lining the lateral walls of Levels II or III. Regenerative changes in the respiratory epithelium occurred in half of the 50 ppm males, most of the 50 ppm females, and two 25 ppm females and were considered to be reparative changes secondary to necrosis. The squamous epithelium lining the arytenoid cartilages exhibited either hyperplasia or atypical hyperplasia, minimal to moderate, in all 50 and 100 ppm males, all 100 ppm and most 50 ppm females, and a few 25 ppm males and females. Atypical squamous epithelium hyperplasia consisted of thickening of the epithelium by pleomorphic, atypical-appearing squamous epithelial cells, many of which were variably enlarged with enlarged nuclei and arranged in a disorganized pattern. Minimal to mild squamous metaplasia or minimal to marked atypical squamous metaplasia of the respiratory epithelium occurred in almost all 50 and 100 ppm males and females. Minimal to moderate respiratory epithelium hyperplasia occurred in most of the mice exposed to 50 or 100 ppm. These epithelial changes were accompanied by minimal to mild chronic active inflammation in all mice exposed to 100 ppm, many of those exposed to 50 ppm, and some animals in the lower exposure concentration groups.

In the trachea, atypical squamous metaplasia of the epithelium, ranging from mild to marked, occurred in all 100 ppm mice (Table 15). The atypical squamous metaplastic epithelium was characterized by varying degrees of cellular pleomorphism, with some of the cells quite large with enlarged nuclei and arranged in a disorganized pattern. Minimal to moderate hyperplasia of the respiratory epithelium occurred in most of the mice exposed to 100 ppm and a few of the mice exposed to 50 ppm. The mucosal epithelium also exhibited vacuolar degenerative changes in most of the 100 ppm mice and a few of the mice exposed to 50 ppm. Epithelium regenerative changes, composed generally of a single layer of enlarged cells with large nuclei, occurred in most of the 50 ppm mice. Chronic active inflammation, usually minimal in degree, occurred in most of the 100 ppm mice.

In the lung, minimal to moderate bronchus chronic inflammation occurred in most of the mice exposed to 50 or 100 ppm, and this was accompanied by minimal to mild polymorphonuclear cellular infiltration in most of the 100 ppm mice (Table 15). Atypical hyperplasia and atypical squamous metaplasia of the bronchus epithelium occurred in most of the male and female mice exposed to 100 ppm. These atypical epithelial changes were of mild to moderate severity and occurred primarily in the large bronchi. As in other tissues, such as the trachea, the epithelial atypia was characterized by the presence of large, atypical-appearing, irregularly arranged cells with enlarged, hyperchromatic nuclei. Regenerative changes of the bronchus epithelium, consisting of a single layer of flattened to cuboidal epithelium covering the bronchial surface, were also noted in most of the 100 ppm males and females and many of the 50 ppm females; such changes were interpreted as reparative changes following epithelial injury.

Exposure Concentration Selection Rationale: Based on significant reductions in body weights and increased incidences of nonneoplastic lesions of the respiratory tract at 100 ppm, 2,3-butanedione exposure concentrations selected for the 2-year inhalation study in mice were 12.5, 25, and 50 ppm. Although nasal lesions in mice were a concern at 50 ppm, this concentration was included because lower concentrations were not expected to result in sufficient airway exposure and injury to potentially cause bronchiolitis obliterans. In addition, the 50 ppm exposure concentration was selected because it was considered occupationally relevant. Flavoring mixers were exposed to a mean concentration of 57.2 ppm 2,3-butanedione in a microwave popcorn manufacturing plant where some workers developed bronchiolitis obliterans^25^.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 16 and in the Kaplan-Meier survival curves (Figure 6). Survival of 50 ppm males and females was significantly less than that of the chamber control groups; 50% of males and 34% of females survived to the end of the study compared to 70% and 72% in the male and female chamber control groups, respectively. The mean survival days for 50 ppm males and females (637 and 589 days, respectively) were also reduced relative to that of the chamber control groups (697 days for both sexes). The primary cause of early death in mice exposed to 50 ppm was inflammation in the upper respiratory tract (nose, larynx, and/or trachea).

Table 16 Survival of Mice in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 0 | 1 | 0 | 0
Moribund | 6 | 5 | 4 | 14
Natural deaths | 9 | 5 | 9 | 11
Animals surviving to study termination | 35 | 39 | 37 | 25
Percent probability of survival at end of study^b^ | 70 | 80 | 74 | 50
Mean survival (days)^c^ | 697 | 701 | 701 | 637
Survival analysis^d^ | P = 0.007 | P = 0.386N | P = 0.760N | P = 0.049
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 10 | 6 | 4 | 15
Natural deaths | 4 | 4 | 4 | 17
Animals surviving to study termination | 36 | 40 | 42 | 18^e^
Percent probability of survival at end of study | 72 | 80 | 84 | 34
Mean survival (days) | 697 | 718 | 716 | 589
Survival analysis | P < 0.001 | P = 0.415N | P = 0.224N | P < 0.001

^a^ Censored in the survival analysis.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^d^ The result of the life table trend test^81^ is in the chamber control column, and the results of the life table pairwise comparisons^80^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that was euthanized moribund during the last week of the study.

Figure 6

Kaplan-Meier Survival Curves for Mice Exposed to 2,3-Butanedione by Inhalation for Two Years

#### Body Weights and Clinical Observations

At the end of the study, mean body weights of the 50 ppm groups were reduced to 65% (males) and 62% (females) of those of the respective chamber control groups (Figure 7; Table 17, and Table 18). Males exposed to 25 ppm exhibited slightly reduced body weights at the end of the study (94% of chamber controls), while body weights of 12.5 ppm males were similar to those of the chamber controls throughout the study, and body weights of 12.5 and 25 ppm females were slightly increased relative to the chamber controls.

Table 17 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of 2,3-Butanedione

Day | Chamber Control | | | 12.5 ppm | | | | | 25 ppm | | | 50 ppm
Day | Av. Wt. (g) | | No. of Survivors | Av. Wt. (g) | | Wt. (% of Controls) | | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | | 22.8 | 50 | | 22.6 | | 99 | 50 | 22.5 | 99 | 50 | 22.3 | 98 | 50
11 | | 24.6 | 50 | | 24.6 | | 100 | 50 | 24.4 | 99 | 50 | 24.6 | 100 | 50
18 | | 25.8 | 50 | | 25.6 | | 100 | 50 | 25.6 | 99 | 50 | 25.4 | 99 | 50
25 | | 26.9 | 50 | | 26.8 | | 100 | 50 | 26.8 | 100 | 50 | 26.2 | 97 | 50
32 | | 27.8 | 50 | | 27.7 | | 100 | 50 | 27.6 | 99 | 50 | 26.7 | 96 | 50
39 | | 28.7 | 50 | | 28.6 | | 100 | 50 | 28.6 | 100 | 50 | 27.4 | 95 | 50
46 | | 29.4 | 50 | | 29.2 | | 99 | 50 | 29.4 | 100 | 50 | 27.7 | 94 | 50
53 | | 30.1 | 50 | | 30.0 | | 100 | 50 | 30.0 | 100 | 50 | 28.1 | 94 | 50
60 | | 30.9 | 50 | | 30.7 | | 99 | 50 | 30.6 | 99 | 50 | 28.6 | 93 | 50
67 | | 30.8 | 50 | | 31.6 | | 103 | 50 | 31.6 | 103 | 50 | 29.2 | 95 | 50
74 | | 32.4 | 50 | | 32.6 | | 101 | 50 | 32.6 | 101 | 50 | 29.7 | 92 | 50
81 | | 33.9 | 50 | | 33.7 | | 100 | 50 | 33.5 | 99 | 50 | 30.1 | 89 | 50
88 | | 34.6 | 50 | | 34.3 | | 99 | 50 | 33.9 | 98 | 50 | 30.4 | 88 | 50
116 | | 37.4 | 50 | | 37.2 | | 100 | 50 | 37.2 | 100 | 50 | 32.1 | 86 | 50
144 | | 39.0 | 50 | | 38.8 | | 99 | 50 | 39.1 | 100 | 50 | 33.1 | 85 | 49
172 | | 41.0 | 50 | | 40.8 | | 99 | 50 | 41.2 | 101 | 50 | 34.4 | 84 | 49
200 | | 42.7 | 50 | | 42.7 | | 100 | 50 | 42.6 | 100 | 50 | 35.2 | 82 | 49
228 | | 43.8 | 50 | | 44.0 | | 100 | 50 | 43.2 | 99 | 50 | 35.7 | 82 | 49
256 | | 45.1 | 50 | | 45.3 | | 101 | 50 | 44.7 | 99 | 50 | 36.1 | 80 | 49
284 | | 45.6 | 50 | | 45.9 | | 101 | 50 | 45.0 | 99 | 50 | 36.0 | 79 | 48
312 | | 46.4 | 50 | | 46.4 | | 100 | 50 | 45.5 | 98 | 50 | 34.8 | 75 | 48
340 | | 47.6 | 50 | | 47.1 | | 99 | 50 | 46.2 | 97 | 49 | 34.4 | 72 | 45
368 | | 49.1 | 50 | | 48.9 | | 100 | 50 | 47.6 | 97 | 49 | 34.7 | 71 | 45
396 | | 49.2 | 50 | | 48.5 | | 99 | 49 | 47.4 | 96 | 49 | 34.1 | 69 | 45
424 | | 50.1 | 50 | | 49.3 | | 99 | 49 | 48.1 | 96 | 49 | 35.1 | 70 | 42
452 | | 50.3 | 49 | | 50.1 | | 100 | 49 | 48.0 | 95 | 49 | 35.2 | 70 | 42
480 | | 50.7 | 49 | | 51.0 | | 101 | 48 | 48.7 | 96 | 49 | 36.2 | 71 | 41
508 | | 50.3 | 49 | | 51.1 | | 102 | 48 | 48.4 | 96 | 49 | 35.7 | 71 | 40
536 | | 50.7 | 47 | | 51.1 | | 101 | 48 | 48.4 | 95 | 48 | 35.6 | 70 | 40
564 | | 50.9 | 46 | | 51.0 | | 100 | 48 | 48.7 | 96 | 47 | 35.4 | 70 | 38
592 | | 51.1 | 45 | | 51.1 | | 100 | 46 | 48.7 | 95 | 46 | 34.9 | 68 | 38
620 | | 51.0 | 45 | | 51.6 | | 101 | 44 | 48.7 | 96 | 44 | 35.0 | 69 | 37
648 | | 50.8 | 42 | | 50.7 | | 100 | 44 | 47.7 | 94 | 43 | 34.9 | 69 | 37
662 | | 50.9 | 42 | | 51.5 | | 101 | 42 | 47.6 | 94 | 43 | 34.5 | 68 | 35
676 | | 50.6 | 39 | | 51.5 | | 102 | 41 | 47.0 | 93 | 43 | 34.3 | 68 | 33
690 | | 50.3 | 37 | | 50.7 | | 101 | 40 | 46.9 | 93 | 41 | 32.8 | 65 | 30
704 | | 49.8 | 36 | | 50.1 | | 101 | 40 | 46.6 | 94 | 41 | 32.6 | 66 | 29
718 | | 48.3 | 36 | | 49.1 | | 102 | 39 | 45.2 | 94 | 40 | 31.4 | 65 | 26
Mean for Weeks
1-13 | | 29.1 | – | | 29.1 | | 100 | – | 29.0 | 100 | – | 27.4 | 95 | –
14-52 | | 43.2 | – | | 43.1 | | 100 | – | 42.7 | 99 | – | 34.6 | 81 | –
53-103 | | 50.3 | – | | 50.5 | | 101 | – | 47.7 | 95 | – | 34.5 | 69 | –

Table 18 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of 2,3-Butanedione

Day | Chamber Control | | 12.5 ppm | | | 25 ppm | | | 50 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 19.3 | 50 | 19.0 | 98 | 50 | 18.8 | 98 | 50 | 18.6 | 97 | 50
11 | 20.9 | 50 | 21.0 | 101 | 50 | 20.9 | 100 | 50 | 20.6 | 99 | 50
18 | 21.6 | 50 | 21.8 | 101 | 50 | 21.9 | 101 | 50 | 21.8 | 101 | 50
25 | 22.5 | 50 | 22.9 | 102 | 50 | 23.0 | 102 | 50 | 22.6 | 100 | 50
32 | 23.2 | 50 | 23.7 | 102 | 50 | 23.7 | 102 | 50 | 22.7 | 98 | 50
39 | 24.2 | 50 | 24.4 | 101 | 50 | 24.8 | 102 | 50 | 23.4 | 97 | 50
46 | 24.7 | 50 | 25.1 | 102 | 50 | 25.3 | 102 | 50 | 24.0 | 97 | 50
53 | 25.4 | 50 | 25.8 | 102 | 50 | 25.8 | 102 | 50 | 24.6 | 97 | 50
60 | 25.6 | 50 | 26.2 | 103 | 50 | 26.1 | 102 | 50 | 25.0 | 98 | 50
67 | 26.2 | 50 | 26.6 | 102 | 50 | 26.6 | 102 | 50 | 25.3 | 97 | 50
74 | 26.1 | 50 | 27.2 | 104 | 50 | 27.3 | 105 | 50 | 25.8 | 99 | 50
81 | 27.1 | 50 | 27.7 | 102 | 50 | 27.7 | 102 | 50 | 26.2 | 97 | 50
88 | 27.5 | 50 | 28.3 | 103 | 50 | 28.0 | 102 | 50 | 26.2 | 95 | 50
116 | 29.6 | 50 | 30.9 | 104 | 50 | 30.7 | 104 | 50 | 27.6 | 93 | 50
144 | 31.5 | 50 | 33.3 | 106 | 50 | 32.9 | 105 | 50 | 28.3 | 90 | 50
172 | 32.8 | 50 | 34.7 | 106 | 50 | 35.0 | 106 | 50 | 29.3 | 89 | 50
200 | 35.4 | 49 | 37.3 | 105 | 50 | 37.5 | 106 | 50 | 30.3 | 86 | 50
228 | 37.3 | 49 | 39.3 | 105 | 50 | 39.8 | 107 | 50 | 29.9 | 80 | 49
256 | 38.3 | 49 | 40.6 | 106 | 50 | 41.5 | 108 | 50 | 29.0 | 76 | 48
284 | 39.1 | 49 | 42.1 | 108 | 50 | 42.3 | 108 | 50 | 28.4 | 73 | 45
312 | 40.2 | 49 | 43.4 | 108 | 50 | 43.0 | 107 | 50 | 28.3 | 70 | 45
340 | 41.6 | 49 | 44.9 | 108 | 50 | 43.8 | 105 | 50 | 27.5 | 66 | 43
368 | 44.6 | 49 | 48.4 | 109 | 50 | 47.2 | 106 | 50 | 29.8 | 67 | 41
396 | 46.1 | 49 | 50.0 | 109 | 50 | 48.2 | 105 | 50 | 30.1 | 65 | 41
424 | 46.8 | 49 | 50.4 | 108 | 50 | 49.2 | 105 | 50 | 30.3 | 65 | 38
452 | 48.5 | 49 | 51.8 | 107 | 50 | 51.1 | 105 | 50 | 31.4 | 65 | 38
480 | 50.0 | 49 | 53.7 | 108 | 50 | 52.9 | 106 | 50 | 31.9 | 64 | 36
508 | 49.8 | 48 | 53.8 | 108 | 50 | 51.5 | 104 | 50 | 31.9 | 64 | 36
536 | 49.9 | 48 | 53.1 | 106 | 50 | 52.9 | 106 | 50 | 32.4 | 65 | 35
564 | 49.8 | 48 | 53.9 | 108 | 49 | 52.8 | 106 | 50 | 32.2 | 65 | 33
592 | 50.2 | 46 | 54.8 | 109 | 49 | 52.4 | 104 | 48 | 32.2 | 64 | 32
620 | 51.0 | 45 | 55.2 | 108 | 49 | 53.0 | 104 | 45 | 32.8 | 64 | 29
648 | 49.8 | 44 | 56.0 | 113 | 46 | 52.2 | 105 | 44 | 32.7 | 66 | 28
662 | 49.3 | 43 | 55.7 | 113 | 46 | 51.9 | 105 | 44 | 31.6 | 64 | 26
676 | 49.0 | 40 | 54.2 | 111 | 45 | 50.0 | 102 | 44 | 29.7 | 61 | 24
690 | 48.8 | 37 | 53.4 | 109 | 43 | 49.3 | 101 | 44 | 30.2 | 62 | 22
704 | 47.7 | 37 | 52.7 | 110 | 41 | 48.7 | 102 | 44 | 29.8 | 63 | 20
718 | 46.8 | 36 | 50.0 | 107 | 41 | 47.2 | 101 | 42 | 28.9 | 62 | 18
Mean for Weeks
1-13 | 24.2 | – | 24.6 | 102 | – | 24.6 | 102 | – | 23.6 | 98 | –
14-52 | 36.2 | – | 38.5 | 106 | – | 38.5 | 106 | – | 28.7 | 80 | –
53-103 | 48.6 | – | 52.9 | 109 | – | 50.7 | 104 | – | 31.1 | 64 | –

Clinical observations were most prominent in the 50 ppm groups and included abnormal breathing, thinness, sneezing, and eye abnormality in both sexes. Incidences were highest for thinness and eye abnormality. Thinness was observed in 22/50 males and 22/50 females in the 50 ppm groups, as compared to 6/50 and 8/50 in the respective chamber control groups. Eye abnormality was observed in 10/50 males and 35/50 females in the 50 ppm groups, compared to 3/50 and 2/50 in the respective chamber control groups.

#### Gross Observations

At terminal euthanasia, many mice exposed to 50 ppm and some females exposed to 25 ppm were noted to have opaque or pale eye lesions or foci.

Figure 7

Growth Curves for Mice Exposed to 2,3-Butanedione by Inhalation for Two Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the nose, larynx, trachea, lung, eye, bone marrow, spleen, thyroid gland, heart, thymus, lymph nodes, and adrenal gland. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix C for male mice and Appendix D for female mice.

Nose: Adenocarcinomas occurred in two 50 ppm females (Table 19 and Table D-1). Both neoplasms involved all three Levels of the nasal cavity but appeared to arise in Level III in a background of extensive respiratory metaplasia of the olfactory epithelium. One of these neoplasms infiltrated subtly within the lamina propria between the benign respiratory glands and the respiratory metaplastic glands from the dorsal end to the ventral end of the nasal cavity. This neoplasm exhibited little distortion of the architectural features of the nasal cavity, except for focal formation of a bridge between one or more ethmoid turbinates and the nasal septum in Level III (Figure 20). In Level I, the adenocarcinoma occurred within the inflamed soft tissue of the palate, having infiltrated around the free end of the palatal process of the premaxilla in Level II. The second animal with adenocarcinoma presented with a more obvious mass that largely filled the nasal cavity in Level III, encompassing the nasal septum and the ethmoid scrolls (Figure 21). Laterally, this neoplasm invaded through the maxillary or premaxillary bones on both the left and right sides, extending into adjacent soft tissue. Dorsally, the neoplasm appeared to have invaded through both the cribriform plate of the ethmoid bone and the frontal bone, resulting in a 0.5 cm diameter skull deformity that was noted at necropsy. Ventrally, the neoplasm infiltrated between the nasopharyngeal duct and the palatine process of the maxilla and exhibited foci of perineural and vascular wall invasion.

Table 19 Incidences of Neoplasms and Nonneoplastic Lesions of the Nose in Mice in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Number Examined Microscopically | 49 | 48 | 50 | 50
Inflammation, Suppurative^a^ | 2 (1.0)^b^ | 4 (1.0) | 47** (1.4) | 50** (3.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 6* (1.0) | 47** (1.5) | 50** (2.4)
Respiratory Epithelium, Hyperplasia | 1 (1.0) | 0 | 0 | 8** (1.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 34** (1.1) | 50** (1.6)
Glands, Sinus, Metaplasia, Respiratory | 0 | 0 | 1 (2.0) | 13** (1.0)
Mucosa, Regeneration | 0 | 0 | 47** (1.2) | 47** (1.6)
Olfactory Epithelium, Atrophy | 0 | 14** (1.1) | 48** (2.1) | 38** (1.8)
Olfactory Epithelium, Metaplasia, Respiratory | 1 (1.0) | 0 | 39** (1.6) | 45** (2.7)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 19** (2.2)
Turbinate, Atrophy | 0 | 8** (1.1) | 49** (1.2) | 50** (2.3)
Turbinate, Necrosis | 0 | 0 | 4 (1.0) | 27** (1.0)
Septum, Perforation | 0 | 0 | 3 | 11**
Lamina Propria, Fibrosis | 0 | 0 | 44** (1.0) | 50** (2.0)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Inflammation, Suppurative | 3 (1.0) | 20** (1.2) | 50** (1.6) | 50** (3.3)
Respiratory Epithelium, Metaplasia, Squamous | 1 (1.0) | 9* (1.0) | 48** (1.3) | 50** (2.7)
Respiratory Epithelium, Hyperplasia | 0 | 1 (1.0) | 0 | 2 (1.5)
Respiratory Epithelium, Necrosis | 1 (1.0) | 5 (1.0) | 33** (1.2) | 50** (1.8)
Glands, Sinus, Metaplasia, Respiratory | 0 | 0 | 0 | 12** (1.0)
Mucosa, Regeneration | 0 | 0 | 39** (1.2) | 48** (2.1)
Olfactory Epithelium, Atrophy | 0 | 41** (1.6) | 49** (2.2) | 45** (1.4)
Olfactory Epithelium, Metaplasia, Respiratory | 0 | 22** (1.2) | 46** (1.7) | 49** (3.3)
Olfactory Epithelium, Necrosis | 0 | 0 | 1 (2.0) | 20** (1.6)
Turbinate, Atrophy | 0 | 32** (1.0) | 50** (1.1) | 50** (2.1)
Turbinate, Necrosis | 0 | 0 | 1 (1.0) | 11** (1.0)
Septum, Perforation | 0 | 0 | 6* | 5*
Lamina Propria, Fibrosis | 0 | 0 | 47** (1.0) | 49** (1.9)
Adenocarcinoma^c^
Overall rate^d^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate^e^ | 0.0% | 0.0% | 0.0% | 6.2%
Terminal rate^f^ | 0/36 (0%) | 0/40 (0%) | 0/42 (0%) | 1/17 (6%)
First incidence (days) | –^h^ | – | – | 708
Poly-3 test^g^ | P = 0.038 | –^i^ | – | P = 0.171

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for adenocarcinoma of the nose in B6C3F1/N female mice in 2-year inhalation studies with chamber control groups: 0/300; all routes: 0/548.

^d^ Number of animals with neoplasm per number of animals with nose examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal euthanasia.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

Figure 20

Adenocarcinoma in the Nose of a Female B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A, B) This neoplasm infiltrates the lamina propria of the nasal cavity, without mass formation, and without architectural distortion, except focally where there is bridging (arrows) of an ethmoid turbinate with the nasal septum. C) Infiltrating adenocarcinoma (arrows) on one side of the nasal septum in Level III. D) The neoplasm infiltrates between the nasopharyngeal duct (asterisk) and the palatine process of the maxillary bone (arrowhead), exhibiting focal perineural invasion (arrow). E) The neoplasm (arrowhead) invades the inflamed soft tissue of the palate on the ventral side of the premaxillary bone (arrow) in Level I. The nasal cavity is indicated by the asterisk. F) The adenocarcinoma (arrows) is arising in the background of extensive respiratory metaplasia (arrowheads) of the olfactory epithelium in Level III. Original objective magnification: A = 1×, B = 2×, C = 10×, D = 10×, E = 10×, F = 20×.

Figure 21

Adenocarcinoma in the Nose of a Female B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The neoplastic mass largely fills the nasal cavity in Level III and invades through the bony wall on both lateral sides, as well as dorsally (arrowheads). B) The neoplasm invades through the maxillary bone into periosteal soft tissue adjacent to striated muscle (arrow). C) The neoplasm invades through maxillary bone (arrowheads) on the opposite side from B), and into periosteal soft tissue (arrow). D) The neoplasm appears to have invaded dorsally through the cribriform plate of the ethmoid bone as well as the frontal bone, extending near the dorsal surface (arrowheads) in Level III. E) The neoplasm (arrows) invades into the ventral portion of the nasal septum adjacent to the nasopharyngeal duct (bottom of photo) in Level III. F) Higher magnification of the infiltrating neoplasm within an inflamed fibrous stroma. Original objective magnification: A = 1×, B = 4×, C = 4×, D = 4×, E = 4×, F = 20×.

No nasal adenocarcinomas or other nasal neoplasms occurred in 12.5 or 25 ppm females, exposed males, or chamber controls of either sex (Table C-1 and Table D-1). No nasal adenocarcinomas have been recorded in the NTP historical control database (Table 19).

Nonneoplastic lesions of the nose occurred predominantly in the 25 and 50 ppm groups, but some lesions also occurred with lower incidences and severities in the 12.5 ppm groups (Table 19, Table C-3, and Table D-3). Suppurative inflammation occurred in all mice exposed to 50 ppm, in most 25 ppm mice, and in some 12.5 ppm mice. The inflammation was characterized by the presence of neutrophilic exudate and proteinaceous fluid within the nasal cavity and variably dense infiltrates of neutrophils, lymphocytes, and plasma cells within the underlying lamina propria (Figure 22). In association with the inflammation, a variety of epithelial lesions occurred. Squamous metaplasia of the respiratory epithelium in Levels I and II occurred in all 50 ppm mice, most 25 ppm mice, and a few 12.5 ppm mice. Minimal hyperplasia of the respiratory epithelium occurred in a few 50 ppm mice. Respiratory metaplasia of the Steno’s glands surrounding the maxillary sinus occurred in some 50 ppm mice, usually occurring in several small areas of the glands. Necrosis of the respiratory epithelium, usually minimal to mild, occurred in all 50 ppm mice, most 25 ppm mice, a few 12.5 ppm females, and one female chamber control mouse. Regeneration of the mucosa epithelium, probably secondary to previous necrosis or ulceration, occurred in most 25 and 50 ppm mice. Within the olfactory epithelium of Levels II and III, atrophy occurred in most of the animals exposed to 25 or 50 ppm and also occurred in some 12.5 ppm males and most 12.5 ppm females. Respiratory metaplasia of the olfactory epithelium also occurred in most of the 25 and 50 ppm mice and many of the 12.5 ppm females. Minimal to moderate necrosis of the olfactory epithelium occurred in many of the 50 ppm males and females and in one 25 ppm female.

Figure 22

Suppurative Inflammation, Septum Perforation, Turbinate Atrophy, And Lamina Propria Fibrosis in the Nose of a Male B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) This low power view of the nasal cavity, Level I, shows suppurative inflammation (long arrow) within the nasal cavity, a healed septal perforation (asterisk in gap), marked nasoturbinate atrophy (arrowheads), and fibrosis of the lamina propria of the naso- and maxilloturbinates (short arrow). B) Higher magnification of fibrosis (arrow) within the lamina propria of a maxilloturbinate. Original objective magnification: A = 2×, B = 10×.

Turbinate atrophy, primarily involving the naso- and maxilloturbinates, occurred in all exposed groups, with exposure concentration-related increases in incidences and severities (Table 19, Table C-3, and Table D-3). The atrophy was characterized by loss of turbinate tissue, including the bone of the turbinates, resulting in shortening and blunting, with only the base remaining in some cases (Figure 23). Turbinate necrosis was diagnosed when fragments of residual turbinate bone lacking in both osteocytes and osteoblasts occurred; these fragments of necrotic bone were usually small and were sometimes surrounded by neutrophils and/or were being extruded into the nasal cavity (Figure 24A). Turbinate necrosis occurred in many 50 ppm males, some 50 ppm females, and a few 25 ppm mice. Perforation of the nasal septum occurred in 11 males and five females in the 50 ppm groups and in three males and six females in the 25 ppm groups. Septum perforation was characterized by total loss of tissue, including cartilage, in the central part of the nasal septum in Level I, with the exposed tissue edges covered by a layer of squamous epithelium (Figure 22A).

Figure 23

Normal Nasoturbinates, Level I, in the Nose of a Chamber Control Male B6C3F1/N Mouse at Two Years (A), and Turbinate Atrophy in the Nose of a Male B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

A) Long, slender nasoturbinates (arrowheads) with lateral hooks (arrows), in Level I of the nasal cavity. B) Markedly shortened, blunted, and fibrotic nasoturbinates (arrows) in Level I, taken at the same magnification as A. Original objective magnification: A = 4×, B = 4×.

Figure 24

Turbinate Necrosis in the Nose of a Female B6C3F1/N Mouse (A) and Lamina Propria Fibrosis in the Nose of a Male B6C3F1/N Mouse (B) Both Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) The nasoturbinate shows marked inflammation, foci of mucosal ulceration, and loss of the bony hook except for two remnants of necrotic and partially extruded bone (arrows). B) The bony hook of the nasoturbinate has been replaced by dense fibrocollagenous tissue (arrow) which has expanded the thickness of the lamina propria. Original objective magnification: A = 20×, B = 20×.

Fibrosis of the mucosal lamina propria occurred in all of the 50 ppm males and most of the 50 ppm females and 25 ppm males and females (Table 19, Table C-3, and Table D-3). The fibrosis was characterized by increased collagenous tissue immediately beneath the mucosal epithelium of the nasal cavity, primarily in Levels I and II (Figure 24B). The fibrosis was often noted in the tips of atrophic turbinates or beneath the epithelial lining of the lateral walls or septum, associated with obliteration of the glands normally occurring in these sites.

Larynx: Minimal to mild chronic active inflammation occurred in the submucosa of most 50 ppm and many 25 ppm mice (Table 20, Table C-3, and Table D-3). Variable amounts of neutrophilic exudate were sometimes noted in the lumen of the larynx (Figure 25), and in two males and four females in the 50 ppm groups the exudate was estimated to occupy 40% or more of the lumen space and was diagnosed separately as lumen exudate. Moderate squamous metaplasia of the respiratory epithelium occurred in almost all of the 50 ppm mice, and minimal to mild metaplasia occurred in a few 25 ppm mice. The squamous metaplasia occurred more commonly in the cranial portions of the larynx, and occurred consistently in the base of the epiglottis. In two of the female mice, one in the 50 ppm group and the other in the 12.5 ppm group, the squamous metaplastic changes were cytologically atypical and were diagnosed as atypical squamous metaplasia of the respiratory epithelium. Exposure concentration-related increases in incidences and severities of hyperplasia of the squamous epithelium overlying the arytenoid cartilages occurred, particularly in Level I. Hyperplasia of the respiratory epithelium also occurred in a few animals, primarily in the 50 ppm group of males. Foci of epithelial necrosis, often occurring in the respiratory epithelium of Levels II and III and sometimes in the squamous epithelium overlying the arytenoid cartilages, occurred in most of the mice exposed to 50 ppm and in some exposed to 25 ppm (Figure 25B). Regeneration of the respiratory epithelium, probably secondary to previous necrosis, occurred in most 50 ppm mice and in three 25 ppm female mice.

Table 20 Incidences of Nonneoplastic Lesions of the Respiratory System in Mice in the Two-year Inhalation Studyof 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Larynx^a^ | 49 | 49 | 49 | 50
Inflammation, Chronic Active^b^ | 4 (1.0)^c^ | 2 (1.0) | 11* (1.2) | 42** (1.6)
Lumen, Exudate | 0 | 0 | 0 | 2 (3.5)
Respiratory Epithelium, Metaplasia, Squamous | 3 (1.0) | 0 | 6 (1.2) | 50** (3.1)
Respiratory Epithelium, Hyperplasia | 1 (1.0) | 0 | 0 | 11** (1.3)
Respiratory Epithelium, Necrosis | 2 (1.0) | 1 (1.0) | 9* (1.0) | 34** (1.2)
Respiratory Epithelium, Regeneration | 0 | 0 | 0 | 32** (1.8)
Squamous Epithelium, Hyperplasia | 3 (1.3) | 7 (1.3) | 15** (1.4) | 42** (1.8)
Trachea | 48 | 49 | 49 | 49
Inflammation, Chronic Active | 0 | 0 | 2 (1.0) | 45** (1.6)
Lumen, Exudate | 0 | 0 | 0 | 4* (3.0)
Necrosis | 0 | 0 | 0 | 47** (1.5)
Epithelium, Regeneration | 0 | 0 | 0 | 45** (2.9)
Epithelium, Hyperplasia | 0 | 0 | 0 | 6* (2.0)
Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 5* (1.0)
Submucosa, Fibrosis | 0 | 0 | 0 | 46** (2.3)
Carina, Submucosa, Fibrosis | 0 | 0 | 0 | 16** (1.7)
Carina, Submucosa, Mineralization | 0 | 0 | 0 | 15** (1.9)
Carina, Submucosa, Inflammation, Chronic Active | 0 | 0 | 0 | 4* (1.8)
Lung | 50 | 49 | 50 | 50
Bronchus, Epithelium, Regeneration | 0 | 0 | 0 | 34** (1.9)
Bronchus, Epithelium, Necrosis | 0 | 0 | 0 | 2 (1.5)
Inflammation, Suppurative | 0 | 0 | 0 | 3 (2.3)
Pleura, Inflammation, Suppurative | 0 | 0 | 0 | 2 (1.5)
Mediastinum, Inflammation, Suppurative | 0 | 0 | 0 | 3 (1.3)
Mediastinum, Inflammation, Chronic Active | 1 (1.0) | 0 | 0 | 8** (1.1)
Female
Larynx | 49 | 50 | 50 | 49
Inflammation, Chronic Active | 4 (1.3) | 5 (1.2) | 22** (1.2) | 36** (2.1)
Lumen, Exudate | 0 | 0 | 0 | 4* (3.8)
Respiratory Epithelium, Metaplasia, Squamous | 2 (1.0) | 0 | 6 (1.7) | 48** (3.0)
Respiratory Epithelium, Metaplasia, Atypical, Squamous | 0 | 1 (3.0) | 0 | 1 (3.0)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 4 (1.3) | 1 (2.0)
Respiratory Epithelium, Necrosis | 1 (1.0) | 1 (1.0) | 14** (1.1) | 32** (1.5)
Respiratory Epithelium, Regeneration | 0 | 0 | 3 (1.0) | 30** (1.4)
Squamous Epithelium, Hyperplasia | 4 (1.3) | 13* (1.2) | 34** (1.5) | 40** (2.1)
Trachea | 50 | 49 | 50 | 50
Inflammation, Chronic Active | 1 (1.0) | 0 | 4 (1.5) | 42** (2.1)
Lumen, Exudate | 0 | 0 | 0 | 12** (3.4)
Necrosis | 0 | 0 | 3 (1.0) | 48** (1.9)
Epithelium, Regeneration | 0 | 0 | 9** (1.1) | 45** (3.0)
Epithelium, Hyperplasia | 0 | 0 | 1 (2.0) | 1 (2.0)
Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 2 (1.5)
Submucosa, Fibrosis | 0 | 0 | 0 | 44** (2.3)
Carina, Submucosa, Fibrosis | 0 | 0 | 0 | 6** (1.3)
Carina, Submucosa, Mineralization | 0 | 0 | 0 | 5* (1.8)
Lung | 50 | 50 | 50 | 50
Bronchus, Epithelium, Regeneration | 2 (1.0) | 0 | 0 | 38** (2.8)
Bronchus, Epithelium, Necrosis | 2 (1.0) | 0 | 0 | 5 (1.4)
Bronchus, Submucosa, Fibrosis | 0 | 0 | 0 | 5* (1.2)
Inflammation, Suppurative | 0 | 1 (1.0) | 0 | 5* (1.8)
Pleura, Inflammation, Suppurative | 0 | 0 | 0 | 5* (2.0)
Mediastinum, Inflammation, Suppurative | 0 | 1 (1.0) | 1 (1.0) | 8** (2.0)
Mediastinum, Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 7** (1.7)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 25

Lumen Exudate and Respiratory Epithelium Necrosis in the Larynx of a Female B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (H&E)

A) Much of the laryngeal wall is infiltrated by a dense infiltrate of inflammatory cells (arrows), and there is inflammatory exudate in the lumen. B) Higher magnification reveals necrosis and ulceration of the mucosal epithelium (arrow), with bacterial colonies (arrowhead) on the ulcerated surface. Original objective magnification: A = 4×, B = 10×.

Trachea: Lesions occurred primarily in the 50 ppm groups, in a few 25 ppm mice, and did not occur in the 12.5 ppm groups (Table 20, Table C-3, and Table D-3). Chronic active inflammation occurred in most of the mice exposed to 50 ppm and in a few exposed to 25 ppm. Grading of the inflammation was based upon both the intensity and the intramural depth of the inflammatory cell infiltrates, ranging from minimal when localized to the submucosa, mild when the muscularis was involved, moderate for extension to the cartilage, and marked in those cases in which the inflammation extended through the tracheal wall and into the surrounding thyroid gland, connective tissue, and/or the periesophageal tissues. Some animals with marked inflammation also had neutrophilic exudate in the tracheal lumen. When it appeared that 40% or more of the lumen was occupied by exudate, a separate diagnosis of lumen exudate was made because the airflow would have been partially obstructed; four males and 12 females in the 50 ppm groups were found to have this level of exudate. Most of the mice exposed to 50 ppm and three females exposed to 25 ppm exhibited varying degrees of necrosis, usually graded as minimal to mild. However, in some of the 50 ppm animals the necrosis was marked, with ulceration and replacement of most or all of the epithelium by neutrophilic exudate and variable extension of the necrosis and suppurative inflammation into the sub-mucosa, cartilage, and peritracheal tissue. Epithelium regeneration, probably secondary to the necrosis, occurred in most 50 ppm mice and to a minimal extent in nine 25 ppm females. Minimal to mild epithelium hyperplasia and/or squamous metaplasia occurred in a few mice exposed to 50 ppm.

Mild to moderate submucosa fibrosis occurred in most of the mice in the 50 ppm groups and did not occur in the lower exposure concentration groups or in the chamber controls (Table 20, Table C-3, and Table D-3). In mildly affected mice, the fibrosis expanded the submucosa and replaced the glands. In some of the more severely affected animals, the fibrosis extended around the cartilage rings or completely replaced the cartilage and extended into the surrounding tissue (Figure 26). The fibrosis also resulted in narrowing of the tracheal lumen in some cases. In addition to the fibrosis noted in the proximal tracheal section, sections of the distal trachea revealed the occurrence of submucosa fibrosis of the carina in some 50 ppm mice (Figure 27). Fibrosis of the carina was diagnosed separately because the carina is the most distal portion of the trachea, situated at the point of bifurcation into the left and right extrapulmonary bronchi. The fibrosis in the carina partially replaced the smooth muscle in some cases and was often accompanied by submucosa mineralization (calcium deposits) and sometimes by submucosa chronic active inflammation.

Figure 26

Normal Trachea of a Chamber Control Female B6C3F1/N Mouse at Two Years (A) and Submucosa Fibrosis in the Trachea of a Male B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

B) Marked fibrosis of the entire tracheal wall (arrow), with loss of most of the cartilage and marked narrowing of the lumen. The lumenal area of the trachea in this exposed B6C3F1/N mouse is approximately one-fifth of that of the chamber control B6C3F1/N mouse. Original objective magnification: A = 10×, B = 10×.

Figure 27

Normal Tracheal Carina of a Chamber Control Male B6C3F1/N Mouse at Two Years (A) and Submucosa Fibrosis and Mineralization in the Tracheal Carina of a Male B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

A) The carina shows subepithelial smooth muscle (arrow) and respiratory epithelium (arrowhead) on the surface. B) The subepithelial smooth muscle has been replaced by fibrosis (long arrow), containing foci of mineralization (short arrow). A flat regenerative epithelium (arrowhead) lines the surface of the carina. Original objective magnification: A = 20×, B = 20×.

Lung: Lesions of the bronchi and lung parenchyma occurred predominantly in the 50 ppm groups (Table 20, Table C-3, and Table D-3). The most common bronchial lesion in both male and female mice was minimal to moderate extrapulmonary bronchus epithelium regeneration that occurred in most of the animals exposed to 50 ppm. Regeneration was characterized by a single cell layer of elongated, flattened epithelial cells with the long axis parallel to the basement membrane, which was interpreted as cells attempting to cover a basement membrane that had probably been previously exposed by epithelial cell necrosis with denudation (Figure 28). Minimal to mild extrapulmonary bronchus epithelium necrosis occurred in two males and five females exposed to 50 ppm. Bronchus submucosa fibrosis, characterized by small, focal raised areas of dense collagenous tissue in the submucosa of the extrapulmonary bronchi, occurred in five 50 ppm females (Figure 29).

Figure 28

Normal Bronchus of a Chamber Control Male B6C3F1/N Mouse at Two Years (A) and Epithelium Regeneration in the Bronchus of a Male B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

A) An extrapulmonary bronchus lined by columnar, ciliated respiratory epithelium (arrowhead). B) The respiratory epithelium has been eroded (arrow) and is partially replaced by a flattened to cuboidal regenerating epithelium (arrowheads). Original objective magnification: A = 40×, B = 40×.

Figure 29

Normal Mainstem Bronchus and Bifurcation Knob of a Chamber Control Female B6C3F1/N Mouse at Two Years (A) and Submucosa Fibrosis in the Mainstem Bronchus and Bifurcation Knob of a Female B6C3F1/N Mouse Exposed to 50 ppm 2,3-Butanedione by Inhalation for Two Years (B) (H&E)

A) Respiratory epithelium is on the surface (arrowhead), with underlying smooth muscle (arrow). B) The surface epithelium is slightly attenuated (arrowhead), and the subepithelial muscle has been replaced by dense fibrous tissue (arrow). Original objective magnification: A = 20×, B = 20×.

Lesions of the alveolar parenchyma of the lung were limited to a few animals, primarily in the 50 ppm groups (Table 20, Table C-3, and Table D-3). Suppurative inflammation was used as a combining term for the presence of neutrophilic exudate in the lung, whether located predominantly in the bronchi, bronchioles, alveolar spaces, perivascular tissue, or pleura with spillover into the lung. Bacteria were frequently present in areas of suppuration. The suppurative inflammation in the lung could have resulted from one or more factors, including aspiration of exudate from the upper respiratory tract, mediastinal and secondary pleural inflammation from peritracheal extension of suppurative tracheitis, and/or loss or reduction in the normal nasal function of warming, humidifying, and filtering of inspired air because of the nasal inflammation and other lesions. Minimal to moderate suppurative inflammation of the lung occurred in three males and five females in the 50 ppm groups. Suppurative inflammation of the pleura occurred in two males and five females exposed to 50 ppm. In the 50 ppm groups, suppurative inflammation of the mediastinum occurred in three males and eight females, and chronic active inflammation of the mediastinum occurred in eight males and seven females.

Eye: Minimal to mild acute inflammation of the cornea occurred in 17 males and 23 females exposed to 50 ppm, one male and 20 females exposed to 25 ppm, two females exposed to 12.5 ppm, and two male and one female chamber controls (Table 21, Table C-3, and Table D-3). Grading of the inflammation was based upon the estimated percentage of corneal stroma infiltrated by neutrophils. Minimal to mild epithelium ulcer of the cornea occurred in three males and 10 females exposed to 50 ppm and in 10 females exposed to 25 ppm. Necrosis of the cornea occurred in six females in the 50 ppm group in which necrotic corneal epithelial cells were still attached to or were lifting off from the underlying corneal basement membrane. Mineralization (presumptive calcium deposits) occurred in the superficial portion of the corneal stroma in a few males and several females in the 50 ppm groups and in several 25 ppm females. The mineral deposits were fairly well circumscribed and were often located immediately below areas of corneal ulceration. Epithelium hyperplasia of the cornea was diagnosed when there were six or more layers of epithelial nuclei; this lesion occurred in several mice in the 50 ppm groups, several 25 ppm females, two 12.5 ppm females, two chamber control females, and one chamber control male. The hyperplastic epithelium was sometimes seen at the edges of ulcers of the corneal epithelium. Suppurative inflammation of the anterior chamber occurred in a few of the 50 ppm mice and a few of the 25 ppm females.

Table 21 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Male
Eye^a^ | 49 | 49 | 50 | 50
Cornea, Inflammation, Acute^b^ | 2 (1.5)^c^ | 0 | 1 (1.0) | 17** (1.4)
Cornea, Epithelium, Ulcer | 0 | 0 | 0 | 3 (2.0)
Cornea, Mineralization | 0 | 0 | 0 | 5* (1.4)
Cornea, Epithelium, Hyperplasia | 1 (1.0) | 0 | 0 | 9** (1.2)
Anterior Chamber, Inflammation, Suppurative | 0 | 0 | 0 | 5* (2.0)
Bone Marrow | 48 | 47 | 50 | 49
Myeloid Cell, Hyperplasia | 9 (2.1) | 8 (1.4) | 20* (1.3) | 39** (2.5)
Spleen | 48 | 49 | 50 | 50
Hematopoietic Cell Proliferation | 11 (2.2) | 12 (1.7) | 15 (1.8) | 25** (2.0)
Female
Eye | 50 | 49 | 50 | 49
Cornea, Inflammation, Acute | 1 (1.0) | 2 (1.0) | 20** (1.2) | 23** (1.1)
Cornea, Epithelium, Ulcer | 0 | 0 | 10** (1.4) | 10** (1.6)
Cornea, Necrosis | 0 | 0 | 0 | 6** (1.3)
Cornea, Mineralization | 0 | 0 | 13** (1.0) | 16** (1.3)
Cornea, Epithelium, Hyperplasia | 2 (1.5) | 2 (1.0) | 10* (1.1) | 9** (1.1)
Anterior Chamber, Inflammation, Suppurative | 0 | 0 | 4 (1.8) | 3 (1.0)
Bone Marrow | 50 | 50 | 50 | 49
Myeloid Cell, Hyperplasia | 3 (2.3) | 2 (1.0) | 7 (2.1) | 33** (2.2)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bone Marrow: Significantly increased incidences of myeloid cell hyperplasia occurred in the 50 ppm groups and in 25 ppm males (Table 21, Table C-3, and Table D-3). All stages of maturation were well represented. The erythroid cells often appeared decreased in number as the myeloid hyperplasia increased in severity, likely due to the space-occupying effect of the myeloid cell hyperplasia. The increase in myeloid cells probably represented a secondary reactive response of the marrow to the inflammatory changes in the respiratory tract.

Spleen: A significant increase in the incidence of hematopoietic cell proliferation occurred in 50 ppm males, and the lesion was thought to be a secondary reactive response to the inflammatory changes in the respiratory tract (Table 21 and Table C-3). The proliferation was characterized by an increase in myeloid cells, erythroid cells, and megakaryocytes in the red pulp of the spleen.

Thyroid Gland, Heart, Thymus, and Lymph Nodes: Significantly increased incidences of a few nonneoplastic lesions were considered to be secondary reactions to the respiratory tract inflammation in adjacent or regional tissues. The incidence of chronic active inflammation in the thyroid gland was significantly increased in 50 ppm females (0/50, 0/49, 0/48, 9/50; Table D-3) due to extension of the inflammatory process in the trachea through the tracheal wall and into the adjacent thyroid gland. Similarly, the incidence of chronic active inflammation was significantly increased in the heart of male (0/50, 0/50, 1/50, 5/49; Table C-3) and female (0/50, 2/50, 1/50, 7/50; Table D-3) 50 ppm mice as a result of extension of mediastinal inflammation into either the base of the heart or the wall of an atrium. In the thymus, the incidences of chronic active inflammation (0/47, 0/50, 0/49, 8/45) and atrophy (4/47, 5/50, 2/49, 12/45) were significantly increased in 50 ppm females (Table D-3). Two incidences of chronic inflammation of the thymus were noted in female chamber controls. Increased incidences of thymic inflammation appeared to be secondary to the mediastinal inflammation. Increased incidences of thymic atrophy may have been related to stress. Lymph nodes in the region of the respiratory tract sometimes exhibited lymphoid hyperplasia, as did the mandibular nodes in males (2/36, 5/33, 11/30, 10/32; Table C-3) and females (4/39, 5/47, 12/45, 12/39; Table D-3) and the deep cervical nodes in a few females (0/11, 0/10, 1/11, 4/7; Table D-3). Inflammatory infiltrates sometimes occurred in regional lymph nodes, such as chronic active inflammation in bronchial lymph nodes of a few 50 ppm females (0/40, 0/42, 0/43, 5/43; Table D-3) and plasma cell infiltrates in mandibular lymph nodes of 50 ppm males (1/36, 0/33, 2/30, 14/32; Table C-3).

Adrenal Gland: The incidence of adrenal cortical adenoma was significantly increased in 12.5 ppm males (2/50, 8/49, 3/50, 2/50; Table C-1 and Table C-2), but there was no exposure concentration-response, and the increase in the 12.5 ppm males was within the historical control range. Adrenal cortical adenomas did not occur in exposed female mice.

## Genetic Toxicology

2,3-Butanedione was tested in two bacterial reverse mutation assays, an acute-exposure mouse bone marrow micronucleus test, and subchronic exposure peripheral blood micronucleus tests in rats and mice. Results in both the bacterial assays were positive, and the rodent micronucleus tests were negative.

In the first bacterial mutation assay (Table E-1), a weak positive response (less than twofold increase in revertants, but a clear, reproducible, dose-related increase that approached the twofold level) was observed in Salmonella typhimurium strain TA97 in the absence of liver metabolic activation enzymes (S9 mix) and in the presence of 10% and 30% induced hamster and rat liver S9 mixes. The dose range over which the response was observed in TA97 ranged from 10 to 333 µg/plate. No mutagenic responses were observed in any other strain, although some trials were concluded to demonstrate an equivocal response. These equivocal responses were not easily replicated, unlike the weak positive responses seen in strain TA97.

In the second bacterial mutation assay, conducted with the same lot of 2,3-butanedione that was used in the 2-year rodent bioassay, a positive response was seen in S. typhimurium strain TA97a in the absence of exogenous metabolic activation, and a response concluded to be equivocal was seen with exogenous metabolic activation (10% induced rat liver S9 mix) (Table E-2). In the Escherichia coli strain (WP2 uvrA/pKM101) that was included in this second assay, clearly positive responses were seen in all trials conducted with and without S9 mix, suggesting that 2,3-butanedione is a direct-acting mutagen that is not detoxified by induced rat liver S9. The E. coli strain reverts via base substitution at the tryptophan locus at an AT base pair. Equivocal results were obtained in S. typhimurium strain TA100, with and without S9, and no mutagenicity was observed with strain TA98, with or without S9.

In an acute micronucleus test conducted in male mice, the frequency of micronucleated polychromatic erythrocytes (PCEs) was measured in bone marrow following intra-peritoneal injection of 2,3-butanedione once daily for 3 days (Table E-3). In this test, no increases in micro-nucleated PCEs were observed over the dose range of 7.812 to 500 mg 2,3-butanedione/kg body weight per day.

At the end of the 3-month inhalation studies, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated PCEs and normochromatic erythrocytes (NCEs) (Table E-4 and Table E-5). In these studies, no increases in the frequencies of micronucleated PCEs or NCEs occurred in either sex or species exposed to 2,3-butanedione. The percentage of PCEs among circulating red blood cells was unaffected by exposure to 2,3-butanedione, suggesting the chemical had no effect on erythropoiesis.