# Materials and Methods

## Procurement and Characterization of 2,3-Butanedione

2,3-Butanedione was obtained from Sigma-Aldrich (Aldrich Chemical Co., Inc., Sheboygan Falls, WI) in two lots (10815TD and 03798LJ). Lot 10815TD was used in the 3-month studies, and lot 03798LJ was used in the 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix H). Reports on analyses performed in support of the 2,3-butanedione studies are on file at the National Institute of Environmental Health Sciences.

The test chemical, a yellow liquid, was identified as 2,3-butanedione by the analytical chemistry laboratory and the study laboratory using Fourier transform infrared spectroscopy and by the analytical chemistry laboratory using proton nuclear magnetic resonance spectroscopy. All spectra were consistent with the structure and composition of 2,3-butanedione.

Elemental analysis was performed by Galbraith Laboratories (Knoxville, TN), and water content was determined by the analytical chemistry laboratory using Karl Fischer titration. The relative purity and area percent purity were determined by the study laboratory using gas chromatography (GC) with flame ionization detection (FID).

For lot 10815TD, elemental analyses for carbon, hydrogen, nitrogen, and sulfur were consistent with theoretical values for 2,3-butanedione. Karl Fischer titration indicated 0.1% water content. In samples collected from the top, middle, and bottom of the drum, GC/FID indicated an average purity of 98.7% and four minor peaks with areas greater than 0.1% of the total peak area. These impurities were identified as ethyl acetate (0.39%), 2-butanone (0.51%), acetonitrile (0.24%), and acetic acid (0.12%), based on the retention time relative to authentic standards.

For lot 03798LJ, elemental analyses for carbon, hydrogen, nitrogen, and sulfur were consistent with theoretical values for 2,3-butanedione. Karl Fischer titration indicated 0.42% water content. Average purity in samples taken from the top, middle, and bottom of the drum was 99.1% using GC/FID, and four minor peaks with areas greater than or equal to 0.1% of the total peak area were indicated. Three of the four impurities were identified as acetaldehyde (0.1%), acetic acid (0.3%), and acetoin (0.3%).

To ensure stability, the test chemical was stored at refrigerated temperatures in metal drums under a nitrogen headspace. Periodic reanalyses of the test chemical were performed by the study laboratory using GC/FID prior to and after the 3-month and 2-year studies and approximately every 6 months during the 2-year studies; no degradation of the test chemical was detected.

## Vapor Generation and Exposure Systems

2,3-Butanedione was pumped onto glass beads in a heated glass column where it was vaporized. Heated nitrogen flowed through the column and carried the vapor to a short vapor-distribution manifold, where concentration was controlled by the chemical pump and nitrogen flow rates. For the 2-year studies, the nitrogen-chemical mixture was diluted with heated air (~140°F) before entering the distribution manifold. Pressure in the distribution manifold was fixed to ensure constant flows through the manifold and into the chambers.

Individual Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small-particle detector (Model 3022A; TSI, Inc., St. Paul, MN) was used with and without animals present in the exposure chambers to ensure that 2,3-butanedione vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Chamber concentrations of 2,3-butanedione were monitored using an online GC/FID. Samples were drawn from each exposure chamber approximately every 20 minutes during each 6-hour exposure period using Hasteloy-C stream-select and gas-sampling valves (VALCO Instruments Co., Houston, TX) in a separate, heated valve oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromato-graph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard of 2,3-butanedione in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was calibrated prior to the start of each study and monthly during the 3-month and 2-year studies by a comparison of chamber concentration data to data from grab samples that were collected with sorbent gas sampling tubes containing silica gel (ORBO-53; Supelco, Bellefonte, PA) followed by a sampling tube containing activated coconut charcoal (ORBO-32; Supelco), extracted with acetone containing 2-methyl-1-propanol as an internal standard, and analyzed using an off-line gas chromatograph. The volumes of gas were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of 2,3-butanedione and the internal standard 2-methyl-1-propanol in acetone.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. For rats and mice in the 3-month studies, T_90_ values ranged from 9 to 11 minutes without animals present and from 9 to 13 minutes with animals present; T_10_ values ranged from 9 to 11 minutes without animals present and from 10 to 11 minutes with animals present. For rats and mice in the 2-year studies, T_90_ values ranged from 8 to 9 minutes without animals present and from 10 to 12 minutes with animals present; T_10_ values ranged from 8 to 10 minutes without animals present and from 10 to 11 minutes with animals present. A T_90_ value of 10 minutes was selected for the 3-month studies, and a T_90_ value of 12 minutes was selected for the 2-year studies.

The persistence of 2,3-butanedione in the chambers after vapor delivery ended was determined by monitoring the postexposure vapor concentration in the 100 ppm rat/mouse chamber in the 3-month studies and the 50 ppm chambers in the 2-year studies without animals present in the chambers. In the 3-month studies, the concentration decreased to 1% of the target concentration within 20 minutes without animals present. During the 2-year studies in the rat only chambers, the concentration decreased to 1% of the target concentration within 21 minutes without animals present and 35 minutes with animals present. In the rat/mouse chambers, the concentration decreased to 1% of the target concentration within 19 minutes without animals present and 95 minutes with animals present.

The uniformity of 2,3-butanedione vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; concentration uniformity with animals present in the chambers was measured once during the 3-month studies and approximately every 3 months during the 2-year studies. The vapor concentration was measured using the on-line gas chromatograph with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. During the 3-month studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. During the 2-year studies, concentrations were measured at the regular monitoring port and from all sample ports where animals were present. Chamber concentration uniformity was maintained throughout the studies.

Samples of the test atmosphere from the distribution lines and low and high exposure concentration chambers were collected prior to the 3-month and 2-year studies without animals, and also at the beginning of the 3-month and 2-year studies with animals. The atmosphere samples were collected at the beginning and the end of the exposure day with sorbent gas sampling tubes containing silica gel (ORBO-53; Supelco) and extracted with acetone. All of the samples were analyzed using GC/FID to measure the stability and purity of 2,3-butanedione in the generation and delivery system. To assess whether impurities or degradation products co-eluted with 2,3-butanedione or the solvent, a second GC/FID analysis was performed on samples extracted with dimethyl formamide. In conjunction with the stability and purity measurements described above, the purity of 2,3-butanedione in the generator reservoir was measured using GC/FID. To demonstrate the resolution and sensitivity of the system to detect low levels of possible impurity or degradation products, a 0.1% solution of acetoin, 2-butanone, 2,3-butanediol, 3-methyl-2-4-pen-tanedione, ethyl acetate, acetonitrile, and acetic acid was analyzed. During the 2-year studies, GC/FID used to detect impurities was unable to determine the presence of ethyl acetate or 2-butanone due to a contaminant peak that eluted at the same retention times. GC with mass spectrometry detection was used, and results indicated that ethyl acetate and 2-butanone were less than 0.1% in the distribution line, 50 ppm chambers, generator reservoir, and test chemical samples and less than 0.5% in the 12.5 ppm chambers.

## Animal Source

Male and female Wistar Han [Crl:WI (Han)] rats were obtained from Charles River Laboratories (Raleigh, NC) and male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 3-month and 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to 2,3-butanedione and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 or 13 days and were approximately 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Groups of 10 male and 10 female rats and mice were exposed by whole body inhalation to 2,3-butanedione vapor at concentrations of 0, 6.25, 12.5, 25, 50, or 100 ppm, 6 hours plus T_90_ (10 minutes) per day, 5 days per week for 14 weeks. These exposure concentrations were selected based upon results of previous 2- and 12 week studies in rats and mice, respectively^47; 50^. Additional groups of 10 male and 10 female rats were exposed to the same concentrations for 23 days for clinical pathology analyses. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical observations were recorded weekly beginning on day 8 (female rats) or day 9 (male rats; mice) and at the end of the studies. The animals were weighed initially, on day 8 (female rats) or 9 (male rats; mice), weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2.

Table 2 Experimental Design and Materials and Methods in the Inhalation Studies of 2,3-Butanedione

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Wistar Han [Crl:WI (Han)] rats B6C3F1/N mice | Wistar Han [Crl:WI (Han)] rats B6C3F1/N mice
Animal Source
Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 or 13 days Mice: 12 days | 12 days
Average Age When Studies Began
6 weeks | 5 to 6 weeks
Date of First Exposure
Rats: July 28 (males) or 29 (females), 2008 Mice: July 28, 2008 | Rats: August 17, 2009 Mice: August 31, 2009
Exposure Duration
6 hours plus T90 (10 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T90 (12 minutes) per day, 5 days per week, for 105 weeks
Date of Last Exposure
Rats: October 27 (males) or 28 (females), 2008 Mice: October 29 (males) or 30 (females), 2008 | Rats: August 18, 2011 Mice: September 1, 2011
Necropsy Dates
Rats: October 28 (males) or 29 (females), 2008 Mice: October 30 (males) or 31 (females), 2008 | Rats: August 15 to 19, 2011 Mice: August 29 to September 2, 2011
Average Age at Necropsy
19 weeks | 109 to 111 weeks
Size of Study Groups
10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum except during exposure periods | Same as 3-month studies
Water
Tap water (City of Richland, WA) via automatic watering system (Edstrom Industries; Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Stainless steel wire-bottom (Lab Products, Inc., Seaford, DE), changed and rotated weekly | Same as 3-month studies
Cageboard
Techboard Ultra untreated paper pan liner (Shepherd Specialty Papers, Watertown, TN) | Same as 3-month studies
Chamber Air Supply Filters
Single HEPA (open stock); charcoal (RSE, Inc., New Baltimore, MI); Purafil (Environmental Systems, Lynwood, WA), new at study start | Same as 3-month studies, except single HEPA changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc.), excreta pans changed daily, chambers changed weekly | Same as 3-month studies
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 3-month studies
Exposure Concentrations
0, 6.25, 12.5, 25, 50, and 100 ppm | 0, 12.5, 25, and 50 ppm
Type and Frequency of Observation
Observed twice daily; core study animals were weighed initially, and core study animals were weighed and clinical observations were recorded on day 8 (female rats), day 9 (male rats; mice), weekly thereafter, and at the end of the studies. | Observed twice daily; clinical findings were recorded at week 5, at 4-week intervals through week 93, every 2 weeks thereafter, and at terminal euthanasia; animals were weighed on day 1, weekly thereafter for the first 13 weeks, at 4-week intervals through week 93, every 2 weeks thereafter, and at terminal euthanasia.
Method of Euthanasia
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all animals. Organs weighed from core study animals were heart, right kidney, liver, lung, spleen, right testis, and thymus | Necropsies were performed on all animals.
Clinical Pathology
Blood was collected from the retroorbital plexus of clinical pathology rats on days 3 and 23 and of core study rats at the end of the study for hematology and clinical chemistry. Blood was collected from the retroorbital sinus of mice at the end of the study for hematology. Hematology: hematocrit; packed cell volume; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; Howell-Jolly bodies (mice only); mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen; creatinine, glucose, total protein, albumin, globulin, cholesterol, triglyceride, alanine aminotransferase, alkaline phosphatase, sorbitol dehydrogenase, creatine kinase, bile acids | None
Histopathology
Complete histopathology was performed on 0 and 100 ppm core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung with bronchus, lymph nodes (bronchial, mandibular, mesenteric, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. Respiratory system tissues were examined to a no-effect level in the remaining exposed groups. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung with bronchus, lymph nodes (bronchial, mandibular, mesenteric, and mediastinal), mammary gland (females only), nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.

Blood was collected from clinical pathology rats on days 3 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats) analyses. Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice anesthetized with carbon dioxide. Blood for hematology was placed in tubes containing potassium EDTA (Microtainer; Becton Dickinson; Franklin Lakes, NJ), and blood for clinical chemistry was placed in tubes containing a separator gel (Vacutainer; Becton Dickinson; Franklin Lakes, NJ). Hematology analyses were performed on an Abbott Cell-Dyn 3700 analyzer (Abbott Diagnostics Systems, Abbott Park, IL), except manual hematocrit determinations were performed using a microcentrifuge (Heraeus Holding GmbH., Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA). Platelet, leukocyte, and erythrocyte morphology and nucleated erythrocytes were assessed using smears stained with a Romanowsky-type aqueous stain in a Wescor 7120 aerospray slide stainer (Wescor, Inc., Logan, UT). Reticulocytes were stained with new methylene blue and counted using the Miller disc method^74^. Samples for clinical chemistry analyses were centrifuged, and parameters were measured using a Roche Hitachi 912 system (Roche Diagnostic Corp., Indianapolis, IN). Table 2 lists the clinical pathology parameters measured.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, testes, vaginal tunics, and epididymides were first fixed in Davidson’s solution or a modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on chamber control and 100 ppm groups of rats and mice; respiratory system tissues were examined to a no-effect level in the remaining exposed groups. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^75^ and Boorman et al.^76^.

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats and mice were exposed by whole body inhalation to 2,3-butanedione vapor at concentrations of 0, 12.5, 25, or 50 ppm, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 105 weeks.

Rats and mice were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats and mice were approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Animals were housed individually. Feed was available ad libitum except during exposure periods; water was available ad libitum. Cages were rotated within chambers weekly. Further details of animal maintenance are given in Table 2. Information on feed composition and contaminants is provided in Appendix I.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical observations were recorded at week 5, at 4-week intervals through week 93, every 2 weeks thereafter, and at terminal euthanasia. Body weights were recorded on day 1, weekly thereafter for the first 13 weeks, at 4-week intervals through week 93, every 2 weeks thereafter, and at terminal euthanasia.

Complete necropsies and microscopic examinations were performed on all rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution and testes, vaginal tunics, and epidymides were first fixed in modified Davidson’s solution). All tissue samples were processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 2.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the eye, lung, nose, larynx, and trachea of rats and mice; the adrenal gland of mice; and the uterus of female rats.

The QA report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^75^ and Boorman et al.^76^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^77^.

Because a recent report in the literature More et al.^78^ noted an exacerbation of β-amyloid cytotoxicity in cell cultures by 2,3-butanedione, the histologic sections of the brain of all rats and mice exposed to 50 ppm 2,3-butanedione were reviewed and compared to the brains of the chamber control animals. In addition, subsets of 10 randomly selected male and female rats exposed to 50 ppm and 10 male and female chamber control rats, as well as equal numbers of randomly chosen high concentration and chamber control mice were selected for Bielschowsky silver staining and immuno-histochemical staining for β-amyloid-40 and -42 on histologic sections of the brain. No neurofibrillary tangles, neuritic plaques, or vascular amyloid were identified.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of^79^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^80^ method for testing two groups for equality and Tarone’s life table test^81^ to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-3, Table C-1, Table C-3, Table D-1, and Table D-3 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^82-84^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^83^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^83^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice^85^. Bailer and Portier^83^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^86^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^87^ and Williams^88; 89^. Hematology and clinical chemistry data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^90^ (as modified by Williams^91^) and Dunn^92^. Jonckheere’s test^93^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^94^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^95-97^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current studies.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^98^. In addition, the 3-month and 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of 2,3-butanedione was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli, micronucleated erythrocytes in mouse bone marrow, and increases in the frequency of micro-nucleated erythrocytes in rat and mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^99; 100^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^101^ and the somatic mutation theory of cancer^102; 103^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites^104^. A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens)^105; 106^. Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test^107; 108^.However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^109^. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.