# Introduction

Figure 1

2,3-Butanedione (CASRN 431-03-8; Chemical Formula: C_4_H_6_O_2_; Molecular Weight: 86.09)

Synonyms: Biacetyl; butane-2,3-dione; butanedione; diacetyl; dimethylglyoxal.

Trade name: NSC 8750.

## Chemical and Physical Properties

2,3-Butanedione is a yellow liquid at room temperature with an intense quinone-like odor. The vapor has a butter odor that at high concentrations has been described as a chlorine, or rancid butter odor^1^. The odor threshold for 2,3-butanedione has been reported to be approximately 50 ppb^2^, although this value varies depending upon the method of assessment^3; 4^. 2,3-Butanedione is relatively water soluble (200 g/L at 15°C) and volatile (vapor pressure = 56.8 mm Hg at 25°C)^5^.

2,3-Butanedione is classified as a 1,2-diketone and is the simplest member of this chemical class. The two ketone groups of the 1,2-diketones are located on adjacent or vicinal carbons. A distinctive feature of 2,3-butanedione and other 1,2-diketones is the long C-C bond linking the adjacent ketone groups. This bond distance is about 1.54 Å, compared to 1.45 Å for a molecule containing a conjugated system of double bonds. The unusual bond length of the 1,2-diketones is attributed to the high electronegativity of the oxygen atoms and the resulting repulsion between the partial positive charges of the carbonyl carbon atoms^6^. The positively charged carbonyl carbons are susceptible to attack by nucleophiles such as the amines. Resonance between the electron-deficient oxygen atoms on adjacent carbons contributes to the reactivity of 2,3-butanedione.

## Production, Use, and Human Exposure

2,3-Butanedione is produced and supplied domestically in both bulk and smaller specialty quantities by many manufacturers and distributors; however, specific information on recent annual production volumes was not found in the available literature. The Flavor & Extract Manufacturers Association (FEMA) reported estimated production of 211,000 pounds in 1995, 228,000 pounds in 2005, 85,000 pounds in 2010^7^, and about 30,200 pounds in 2015 (John Hallagan, personal communication). According to the United States Environmental Protection Agency (USEPA) Non-Confidential Inventory Updating Report, 2,3-butanedione had an aggregate production volume between 10,000 and 500,000 pounds in 2002^8^. 2,3-Butanedione is also imported, but little specific information on annual import volumes could be found in the available literature.

2,3-Butanedione occurs naturally in butter, various fruits, coffee, honey, and other foods and as a fermentation by-product in wine, beer, and dairy products. During fermentation, 2,3-butanedione is produced by decarboxylation of α-acetolactate by some species of the lactic acid bacteria family. The butter flavor in some foods is increased by adding 2,3-butanedione in the form of a concentrated starter distillate^9; 10^. Starter distillate is prepared by fermenting milk with bacterial starter cultures. The steam distillate contains 1% to 5% 2,3-butanedione^11^.

2,3-Butanedione is commonly used by the flavor manufacturing industry for production of artificial flavor formulations. 2,3-Butanedione is typically used as a liquid component in flavoring solutions but can also be encapsulated in powders for addition to dry mixtures^12^. Examples of flavored food products include cake mixes, flour, beer, wine, margarines and soft spreads, cheese, candy, bakery products, crackers, pop-corn, cookies, ice cream, frozen foods, and many other food and beverage products^13^.

2,3-Butanedione is also used as a chemical modifier of arginine residues in proteins in studying glycation (the nonenzymatic browning of foods or the nonenzymatic binding of sugar and protein molecules in the body)^14^. Other uses for 2,3-butanedione include reactant/starting material in chemical or biochemical reactions, analytical reagent, anti-microbial/preservative, electron stabilizing compound, modifier of radiation response for chemical and biological systems, and photoinitiator/photosensitizer in polymerizations^5^.

2,3-Butanedione is an ingredient in many different food products, and nonoccupational exposure occurs primarily by ingestion. Consumption of 2,3-butanedione at low levels commonly added to food has not been reported to cause adverse health effects. Three consumers of butter-flavored microwave popcorn with biopsy-confirmed bronchiolitis obliterans have been reported^15^. Estimated exposures of 2 to 24 ppm 2,3-butanedione were based upon peak exposures and individual consumption habits. These cases likely represent a subgroup of susceptible individuals. Nonoccupational inhalation exposure to 2,3-butanedione also can occur from cigarette smoking^16^, the use of electronic cigarettes^17-19^, and from the use of flavored tobacco in hookah water pipes^20; 21^.

Occupational exposure to 2,3-butanedione occurs primarily by inhalation of vapors, especially where artificial flavorings containing 2,3-butanedione are mixed or heated^22; 23^. Occupational exposure to 2,3-butanedione was first recognized as a health hazard at microwave popcorn production facilities that used artificial butter flavoring^22; 24^.

Another group of exposed workers was identified in flavoring manufacturing facilities^23^. According to FEMA, whose members produce approximately 95% of all flavors in the United States, a total of 6,520 employees work directly in flavor manufacturing or laboratory activities in membership companies (Personal communication, J. Hallagan, FEMA General Counsel, to L. McKernan, CDC, October 19, 2010). In microwave popcorn plants and in flavoring manufacturing facilities, workers were exposed to open vessels of flavoring containing 2,3-butanedione, and in some cases, workers were exposed to heated vessels of flavoring mixtures. The headspace of a heated vessel containing heated flavoring mixture at a microwave popcorn plant was reported to contain a peak concentration of 1,230 ppm 2,3-butanedione^22^. The mean 2,3-butanedione air concentrations measured at this microwave popcorn facility were 57.2 ppm (range: 5.43 to 147 ppm) in the mixing room, followed by 2.8 ppm (range: 0.48 to 8.2 ppm) in the packaging area for machine operators. Workers in both areas of the plant had symptoms of obstructive lung disease^25^.

Occupational exposure to 2,3-butanedione vapors has also been reported in coffee processing facilities. 2,3-Butanedione is released when coffee beans are roasted^26^ and when roasted coffee beans are ground^27-29^. Worker exposure can also occur when adding artificial flavorings to some flavored coffee. Other food industries with potential worker exposure to 2,3-butanedione include snack food production plants, commercial and retail bakeries, baking mix production, margarine and other vegetable oil-based cooking products, butter and other dairy products, and candy manufacturers^30^.

Dermal exposure of workers to toxic levels of 2,3-butanedione has been reported in the microwave popcorn packaging and flavor manufacturing industries. Reported dermatologic problems ranged from 12% at one of the six microwave popcorn plants evaluated to 36% among production workers at a flavoring plant^31^. Skin problems were reported by 60% of workers who primarily made liquid flavorings at this plant^32^.

## Regulatory Status

2,3-Butanedione is regulated by the FDA and was granted “generally recognized as safe” (GRAS) status when used as a direct food ingredient^11^. Following reports of respiratory disease in the popcorn and flavoring industries, California promulgated a regulation for occupational exposure to food flavorings containing 2,3-butanedione that requires installation of exposure controls to reduce exposures to the lowest feasible levels. In 2015, the American Conference of Governmental Industrial Hygienists (ACGIH) published a threshold limit value of 0.010 ppm 8-hour time weighted-average (TWA) with a short-term exposure limit (STEL) of 0.020 ppm for 2,3-butanedione^33^. NIOSH published its recommended exposure limits for 2,3-butanedione (5 ppb 8-hour TWA, 25 ppb STEL) in October 2016^34^. There currently is no established OSHA permissible exposure limit for 2,3-butanedione.

## Absorption, Distribution, Metabolism, and Excretion

There were no data available on the absorption, distribution, metabolism, or excretion (ADME) of inhaled 2,3-butanedione. NTP conducted limited ADME studies following 2,3-butanedione administration by intratracheal instillation, oropharyngeal aspiration, and gavage. Uptake of ^14^C-2,3-butanedione from the lung and binding to hemoglobin and albumin were determined following intratracheal instillation in Harlan Sprague Dawley^®^ rats (100 mg/kg) and oropharyngeal aspiration in B6C3F1/N mice (157 mg/kg)^35^. Blood and plasma were collected 24 hours later and analyzed for ^14^C content. In rats, 0.88% of the administered dose was in blood and 0.66% in plasma. Binding to albumin and hemoglobin accounted for 0.26% and 0.30% of the administered dose, respectively. In mice, 0.38% of the administered dose occurred in blood with 0.17% in plasma. Binding to albumin and hemoglobin accounted for 0.09% and 0.14%, respectively. ^14^C-2,3-butanedione binding sites on albumin and hemoglobin were determined by mass spectroscopy to be arginine residues.

2,3-Butanedione distribution and excretion were evaluated after administration of a single gavage dose of 1.58, 15.8, or 158 mg ^14^C-2,3-butanedione/kg body weight to rats (NTP, unpublished studies). The majority of the radioactivity (54% to 82%) was excreted as carbon dioxide at all doses. With increasing dose, the percentage excreted as carbon dioxide decreased and urinary excretion of radioactivity increased (7% to 34%), suggesting that metabolic pathways leading to carbon dioxide were saturated at higher doses. Elimination via fecal excretion accounted for up to 2.24%, and exhalation of volatile organics in breath accounted for 0.8% of the administered dose at 158 mg/kg. Analysis of urine samples obtained from rats administered 158 mg/kg yielded three major ^14^C-labeled components, one of which coeluted with uric acid. Treatment of the urine samples with β-glucuronidase/sulfatase suggested the presence of conjugated metabolites. Identification of urinary metabolites was not pursued.

2,3-Butanedione uptake efficiency of the upper airways was measured in a surgically isolated rat upper respiratory tract model^36^. Uptake efficiency of the upper airways in this model was reported as moderate (25% to 75%) relative to uptake efficiencies in excess of 95% for water-soluble weak acids (e.g., acetic acid and butyric acid). 2,3-Butanedione metabolism was measured in homogenates of rat nasal olfactory mucosa, nasal respiratory mucosa, and tracheal mucosa. Metabolism was about fourfold greater in nasal olfactory tissue than in nasal respiratory or tracheal tissue. 2,3-Butanedione was metabolized in nasal and tracheal tissues by a NADPH-dependent pathway, presumably by dicarbonyl/L-xylulose reductase (DCXR). Computational modeling of these uptake and metabolism data was used to extrapolate to humans. The model predicted that 2,3-butanedione scrubbing was less efficient in the nose-breathing human than in the rat. The concentration of 2,3-butanedione reaching the bronchi in mouth-breathing humans was estimated to be 1.5-fold greater than in nose-breathing rats.

The inhalation dosimetry of 2,3-butanedione in the airways of rats and humans was investigated using a computational fluid dynamic and physiologically based pharmacokinetic model^37^. Metabolism kinetics and direct reaction rates were determined in vitro using rat respiratory tract tissue homogenates. In the absence of metabolism, the model estimated 40% to 50% of inspired 2,3-butanedione was scrubbed by the rat nose with 20% to 30% reaching the bronchioles. The effects of metabolism were dependent upon the 2,3-butanedione concentration. At 1 ppm, 20% was estimated to penetrate the nose with less than 2% reaching the bronchioles. At higher 2,3-butanedione concentrations, increased amounts reach distal sites, possibly due to saturation of metabolic pathways. Less than 2% of inspired 2,3-butanedione was estimated to reach the bronchioles of the rat, whereas 24% was estimated to penetrate to the bronchioles in lightly exercising humans. The amount of 2,3-butanedione in human bronchiolar tissue was estimated to be 40-fold greater than in rat bronchiolar tissue following exposure to the same concentration. Estimated tissue concentrations in the resting nose-breathing human were fivefold greater than in the nose-breathing rat. These results indicate that direct extrapolation of 2,3-butanedione data from the nose-breathing rat may underestimate the risks of small airway injury in humans.

Studies of 2,3-butanedione and acetoin metabolism in mammalian liver slices and extracts showed inter-conversion of acetoin with 2,3-butanedione and 2,3-butanediol^38^. In the perfused liver, 2,3-butanediol is metabolized to carbon dioxide and acetate^39^. 2,3-Butanedione is metabolized in rat and hamster hepatocytes to acetoin in a reaction catalyzed by DCXR with either NADH or NADPH as coenzymes^40-42^. Acetoin can be further reduced to 2,3-butanediol in a NADH-dependent manner^41^. DCXR also catalyzes the metabolism of several other dicarbonyl compounds, including 2,3-pentanedione, 2,3-hexanedione, 2,3-hep-tanedione and 3,4-hexanedione^42^. Low affinity, high capacity and high affinity, low capacity pathways for 2,3-butanedione metabolism were identified in the respiratory tract of the rat^37^. The high affinity pathway was inhibited by sodium benzoate indicating that it is DCXR. The low affinity pathway is not believed to play a major role at 2,3-butanedione concentrations associated with most exposures. 2,3-Butanedione metabolism in the rat lung can also be catalyzed by AKR1C15, an aldo-keto reductase that metabolizes α-diketones^43^.

## Toxicity

### Experimental Animals

The oral toxicity of 2,3-butanedione was investigated in rats following gavage administration of a 20% 2,3-butanedione solution in water^44^. The LD_50_ for a single gavage dose of 2,3-butanedione was estimated to be 3 g/kg in female rats and 3.4 g/kg in male rats. Subchronic (90 day) gavage administration of 540 mg 2,3-butanedione/kg body weight per day to rats caused decreased body weight, increased water consumption, increased adrenal weight, increased relative kidney and liver weights (in females absolute kidney and liver weights were also increased), decreased blood hemoglobin concentration, and gastric ulceration. No adverse effects were noted at the next highest dose level, which was 90 mg/kg per day. On a mg/kg basis, 90 mg/kg was estimated to be roughly 500-fold greater than the estimated human maximum daily intake of 2,3-butanedione from foods consumed at that time, with 50 ppm 2,3-butanedione being the highest estimated concentration in any food.

Concerns over the toxicity of inhaled 2,3-butanedione vapors were prompted by the finding of obstructive lung disease (bronchiolitis obliterans) in microwave popcorn workers exposed to artificial butter flavoring vapors^22^. The acute inhalation toxicity of artificial butter flavoring vapors was investigated by exposing male Sprague Dawley [Hla: (SD) CVF] rats to artificial butter flavoring vapors containing 2,3-butanedione^45^. Rats were exposed for 6 hours to vapors containing average concentrations of 203, 285, or 352 ppm 2,3-butanedione. A fourth group received pulsed exposures to vapors containing an average of 371 ppm 2,3-butanedione. Animals were necropsied the day following exposure. The most severe lesions were present in the nasal cavity of exposed rats. Butter flavoring vapors containing 203 to 371 ppm 2,3-butanedione caused necrosuppurative rhinitis in all four levels of the nose. In the lung, vapors containing 285 to 371 ppm caused multifocal necrotizing bronchitis, and there was no effect on the alveoli. In a subsequent study, acute 6-hour exposure of rats to 2,3-butanedione alone also caused epithelial necrosis and inflammation in bronchi at concentrations greater than 295 ppm and caused epithelial necrosis and inflammation in the trachea and larynx at concentrations greater than or equal to 224 ppm^46^. Although bronchiolitis obliterans was not observed following these acute exposures, these results demonstrated that 2,3-butanedione in artificial butter flavoring vapors was associated with severe injury to the epithelium lining the respiratory tract.

The respiratory toxicity of 2,3-butanedione vapor was investigated in mice using several exposure profiles relevant to workplace conditions at microwave popcorn packaging plants^47^. Male C57Bl/6 mice were exposed to inhaled 2,3-butanedione across several concentrations and duration profiles or by direct oropharyngeal aspiration. Subacute exposure to 200 or 400 ppm 2,3-butanedione for 5 days caused deaths, necrotizing rhinitis, necrotizing laryngitis, and bronchitis. Reducing the exposure to 1 hour/day (100, 200, or 400 ppm) for 4 weeks resulted in less nasal and laryngeal toxicity but led to peribronchial and peribronchiolar lymphocytic inflammation. A similar pattern was observed with intermittent high-dose exposures at 1,200 ppm (15 minutes, twice a day, for 4 weeks). Subchronic exposures (6 hours/day for 12 weeks) of C57Bl/6 mice to 100 ppm 2,3-butanedione caused moderate nasal injury and lymphocytic bronchiolitis accompanied by epithelial atrophy, denudation, and regeneration. Subchronic (12 weeks) exposure to 2,3-butanedione did not cause bronchiolitis obliterans in mice; however, lymphocytic bronchiolitis is considered to be a potential precursor to bronchiolitis obliterans in lung transplant patients^48^.

Because rodents are obligate nose breathers and because the rodent nasal cavity is highly efficient in scrubbing reactive components like 2,3-butanedione from the inspired air, some studies were conducted where 2,3-butanedione was administered by intratracheal instillation (rats) or oropharyngeal aspiration (mice) to bypass the nose. A single treatment of C57Bl/6 mice with 400 mg/kg 2,3-butanedione by oropharyngeal aspiration caused foci of fibrohistiocytic proliferation with little or no inflammation at the junction of the terminal bronchiole and alveolar duct^47^. A single intratracheal instillation of 2,3-butanedione (125 mg/kg) in male Sprague Dawley rats resulted in development of bronchiolitis obliterans^49^. In the rat, 2,3-butanedione-induced bronchiolitis obliterans was associated with necrosis of the bronchiolar epithelium followed by dysregulated repair of the injured epithelium and excessive deposition of the extracellular matrix component tenascin C. This study demonstrated that rats were more susceptible than mice to 2,3-butanedione-induced bronchiolitis obliterans and that 2,3-butanedione can cause bronchiolitis obliterans. In a subsequent inhalation study, Wistar Han rats exposed for 2 weeks to 200 ppm 2,3-butanedione or 2,3-pentane-dione, a related flavoring agent, developed bronchiolitis obliterans-like lesions similar to those occurring in humans^50^.

Cutaneous sensitization by 2,3-butanedione may be initiated through haptenation of 2,3-butanedione with proteins containing the amino acids lysine and arginine^51^. Topical application of 2,3-butanedione caused sensitization based on a murine local lymph node assay^51-53^. Based on results of the local lymph node assay and immune cell phenotyping, it was suggested that 2,3-butanedione is a dermal sensitizer^52^.

There is considerable interest in finding a safe chemical alternative to 2,3-butanedione because of the strong association with lung disease and the significant potential for human exposure. Only a limited number of chemicals produce butter flavor, and many of these chemicals are structurally related to 2,3-butanedione. 2,3-Pentanedione and 2,3-hexanedione are α-diketone flavoring ingredients that may be used as potential substitutes for 2,3-butanedione. Inhalation studies demonstrated that 2,3-pentanedione causes significant respiratory toxicity in rats and mice similar to that caused by 2,3-butanedione^50; 54^.

The respiratory toxicity and chemical reactivity of 2,3-butanedione, 2,3-pentanedione, and 2,3-hexanedione were compared in a recent inhalation study^55^. Chemical reactivity of the diketones with an arginine substrate decreased with increasing chain length (2,3-butanedione ≥ 2,3-pentanedione > 2,3-hexanedione). Animals were evaluated the day after a 2-week exposure to 0, 100, 150, or 200 ppm 2,3-butanedione, 2,3-pentanedione, or 2,3-hexanedione (postexposure groups) or 2 weeks later (recovery groups). Bronchial fibrosis was observed in all 2,3-butanedione and 2,3-pentanedione rats at 200 ppm and in most 2,3-butanedione and all 2,3-pentanedione rats at 150 ppm in the postexposure groups. Bronchial fibrosis was not observed in 2,3-hexanedione-exposed rats, except for a minimal focus of fibrosis in two rats in the 200 ppm postexposure group. Patchy interstitial fibrosis in the lungs of recovery groups exposed to 150 or 200 ppm 2,3-pentanedione or 2,3-butanedione correlated with pulmonary function deficits. Minimal interstitial fibrosis occurred in two of the recovery group rats exposed to 200 ppm 2,3-hexanedione. These results indicated that 2,3-butanedione and 2,3-pentanedione were of similar reactivity and potency in causing bronchial fibrosis. 2,3-Hexanedione (and possibly longer chain α-diketones) exhibits toxicity, but it is less toxic than 2,3-butanedione or 2,3-pentanedione for the respiratory tract of rats.

Acetoin, the partial reduction product of 2,3-butanedione, is also used to produce butter flavor in foods. Acetoin was detected along with 2,3-butanedione in many of the workplaces where bronchiolitis obliterans occurred in workers who make or use 2,3-butanedione^23; 56^. Sub-chronic (13-week) inhalation studies of acetoin were conducted in male and female Wistar Han rats and B6C3F1/N mice (https://ntp.niehs.nih.gov/testing/status/agents/ts-m990018.html). No exposure-related effects on survival, body weights, organ weights, clinical pathology, or histopathology were observed in rats or mice following exposure to acetoin concentrations up to 800 ppm.

### Humans

There are no epidemiological data on workers exposed to 2,3-butanedione alone. A retrospective study evaluated workers who were employed between 1960 and 2003 in a chemical plant producing 2,3-butanedione^23^. At least four cases of bronchiolitis obliterans were found in 206 workers employed in this 2,3-butanedione production facility. However, in addition to 2,3-butanedione, workers may also have been exposed to acetoin and acetaldehyde.

Bronchiolitis obliterans was initially diagnosed in a number of young, otherwise healthy, microwave popcorn workers^24^. Subsequent NIOSH medical and environmental surveys conducted at flavoring manufacturing plants and microwave popcorn packaging facilities have provided much of the information on the human health effects of artificial butter flavoring containing 2,3-butanedione^32; 57-60^. The main symptoms of affected workers at these sites were progressive shortness of breath on exertion, chronic nonproductive cough, and wheezing^22; 24^. Although skin, eye, nose, and throat irritation were reported by some microwave popcorn workers, the primary site of injury was the distal airways; the onset of symptoms was usually gradual over months or years^22^. Airway obstruction in affected workers was diagnosed as bronchiolitis obliterans, an uncommon lung disease characterized by pulmonary function changes that are associated with scarring and constriction of the small airways^61^.

## Reproductive and Developmental Toxicity

### Experimental Animals

When given by gavage to pregnant mice for 10 days, 2,3-butanedione (1.6 g starter distillate/kg) had no effect on maternal or fetal survival or nidation. There were no statistically significant changes in the number of fetal abnormalities compared to controls. Tests in hamsters and rats gave similar results^1^.

### Humans

No case reports were found in the literature that reported reproductive or developmental toxicity of 2,3-butanedione in humans.

## Carcinogenicity

### Experimental Animals

Inhalation studies evaluating the carcinogenic potential of 2,3-butanedione vapor were not found in the literature. Administration of 2,3-butanedione by intraperitoneal injection (1.7 or 8.4 mg/kg) to male and female A/He mice once weekly for 24 weeks did not induce any lung tumors^62^.

Furihata et al.^63^ studied potential initiating and promoting activities of 2,3-butanedione in the rat glandular stomach. 2,3-Butanedione administered at 150 to 400 mg/kg by gavage to male F344 rats induced increases up to 100-fold in ornithine decarboxylase activity after 16 hours. Treatment with 2,3-butanedione also induced a greater than 10-fold increase in DNA synthesis. The authors concluded that 2,3-butanedione has potential tumor-promoting activity.

### Humans

No epidemiological studies were found in the literature that evaluated the carcinogenic potential of 2,3-butanedione in humans.

## Genetic Toxicity

2,3-Butanedione has been shown to be mutagenic in Salmonella typhimurium base-substitution strains TA100, TA102, and TA104, with and without rat liver S9 activation^64-66^; no mutagenicity was shown in the frameshift strain TA98, with or without S9^64,66^. In tests carried out in the yeast Saccharomyces cerevisiae, 2,3-butanedione (173 to 393 μg/mL) did not induce chromosome loss, mitotic recombination, or respiratory deficient mutants when cultures were tested at 28°C or under conditions of cold shock, which has been shown to enhance the effects of some chemicals in this assay^67^.

In mammalian cell test systems, significant increases in the number of sister chromatid exchanges (SCE) (suggestive of DNA damage) were observed in Chinese hamster ovary AUXB1 cells treated with 2,3-butanedione (125 or 250 μM)^68^. In a follow-up investigation, up to 82% of the SCE-inducing activity of 2,3-butanedione (at the 125 μM dose) was blocked in the presence of 1 mM bisulfite, which reacts with 1,2-dicarbonyl compounds to eliminate the carbonyl moiety, believed to be the active subgroup responsible for genotoxicity^68^. 2,3-Butanedione was also strongly mutagenic in mouse lymphoma L5178Y TK^+/-^ cells at doses of 200 and 250 μg/mL when tested in the presence of pooled human S9 mix^69^; no testing was conducted in the absence of S9.

## Study Rationale

Artificial butter flavoring, and two major volatile components, 2,3-butanedione and acetoin, were nominated by the United Food and Commercial Workers Union for long-term inhalation studies. This nomination was based on outbreaks of bronchiolitis obliterans, a severe fibroproliferative disease of the small airways, in workers exposed to artificial butter flavoring vapors. Occupational exposure limits and inhalation toxicity data for these chemicals did not exist. Because inhalation studies on the artificial butter flavor mixture were being conducted by NIOSH, NTP conducted separate studies on two major volatile components, 2,3-butanedione and acetoin, as well as 2,3-pentanedione, a potential replacement for 2,3-butanedione. The results of NTP Laboratory and NIOSH short-term studies investigating the mechanism(s) by which 2,3-butanedione and 2,3-pentanedione cause respiratory toxicity were published in the peer-reviewed literature. These studies demonstrated that short-term (2-week) exposure to 2,3-butanedione concentrations greater than or equal to 150 ppm caused bronchiolitis obliterans-like lesions in rats. However, there was no information available on the potential toxicity of subchronic or chronic exposure to lower concentrations of 2,3-butanedione. NTP 3-month inhalation studies were conducted on 2,3-butanedione, acetoin, and 2,3-pentanedione for comparison of toxicity. NTP chronic toxicology and carcinogenicity studies were only conducted on 2,3-butanedione because of the greater potential for human exposure relative to other components of artificial butter flavoring.

Table 1 Summary of NIOSH and NTP Studies of Artificial Butter Flavoring Constituents

Substance | Exposure Duration | Study
NIOSH Studies^a^
Artificial butter flavoring | 6 hours | Hubbs et al.^45^
2,3-Butanedione | 6 hours constant, intermittent | Hubbs et al.^46^
2,3-Butanedione | NA | Morris and Hubbs^36^
2,3-Butanedione | 6 hours | Hubbs et al.^70^
2,3-Butanedione | 6 hours | Hubbs et al.^54^
2,3-Pentanedione | 6 hours | Hubbs et al.^54^
NIEHS Studies
NTP Guideline Studies
Acetoin | 2 weeks and 3 months | NTP^b^ (in preparation)
2,3-Butanedione | 3 months and 2 years | NTP (current Technical Report)
2,3-Pentanedione | 3 months | NTP^c^ (in preparation)
NTP Research Program^a^
2,3-Butanedione | 5 days to 12 weeks | Morgan et al.^47^
2,3-Butanedione | NA | Mathews et al.^71^
2,3-Butanedione | 1 week (ITI) | Palmer et al.^49^
2,3-Butanedione | 1 week (ITI) | Kelly et al.^72^
^14^C-2,3-Butanedione | 24 hours (ITI) | Fennell et al.^35^
2,3-Pentanedione | 2 weeks | Morgan et al.^50^
2,3-Pentanedione | 2 weeks | Morgan et al.^73^
2,3-Butanedione | 2 weeks | Morgan et al.^55^
2,3-Hexanedione | 2 weeks | Morgan et al.^55^
2,3-Pentanedione | 2 weeks | Morgan et al.^55^

^a^ Full citations appear in the reference list for this report.

^b^ https://ntp.niehs.nih.gov/testing/status/agents/ts-m990018.html.

^c^ https://ntp.niehs.nih.gov/testing/status/agents/ts-08010.html.

NA – not applicable; ITI – Single intratracheal instillation.