# Appendix K Summary of Peer Review Panel Comments

On July 13, 2017, the draft Technical Report on the toxicology and carcinogenesis studies of 2,3-butanedione received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. D.L. Morgan, NIEHS, introduced the toxicology and carcinogenesis studies of 2,3-butanedione by describing the uses of the chemical, the study designs, and the results of the studies in rats and mice, including nonneoplastic and neoplastic lesions in test animals. The proposed conclusions were some evidence of carcinogenic activity of 2,3-butanedione in male and female Wistar Han rats, no evidence of carcinogenic activity of 2,3-butanedione in male B6C3F1/N mice, and equivocal evidence of carcinogenic activity of 2,3-butanedione in female B6C3F1/N mice.

Dr. Gordon asked about the 10-day study where bronchiolitis obliterans had been found at 150 ppm. He found it surprising that the disease was not observed at the slightly lower doses used in the 3-month studies. Dr. Morgan said that the compound has a very steep dose-response curve, and it took some time to find the breaking point in terms of dosage. Dr. Gordon asked about the choice to use the vapor phase, as in the popcorn workers it seemed there was considerable dust. Dr. Morgan agreed but noted that dust would be an almost totally separate test agent, and would have to be studied separately.

Dr. Conner, the first primary reviewer, noted that the studies were complicated and reminiscent of formaldehyde studies, in which dosimetry was affected by breathing patterns. He suggested adding an estimate of dose to the report. He said the studies were well-conducted. He recommended upgrading the conclusion for combined incidences of squamous cell papilloma and squamous cell carcinoma of the nose in male rats from some evidence to clear evidence, based on the number of tumors seen. Similarly, he recommended upgrading the conclusion for adenocarcinoma of the nose in female mice from equivocal evidence to some evidence.

Dr. Morgan said that adding an estimate of dose would potentially be misleading in this instance. He discussed the reasoning behind the conclusions mentioned by Dr. Conner. Dr. Conner felt that the number of instances of such a rare tumor would justify the upgrade he suggested. Dr. Morgan agreed that interpretation of the incidences of rare tumors is challenging.

Dr. Gordon, the second primary reviewer, said the study design was excellent, with appropriate choices for the 2-year exposure concentrations. He felt that the data presentation was clear in both the text and the tables, with statistical comparisons appropriate as described. He agreed with the some evidence conclusion for the rare tumors.

Dr. Dybdal, the third primary reviewer, also felt that the study design was well done, and the experimental results were presented fully and clearly. She said she was concerned whether the rodent model was the correct model to look at the disease, given the compound’s background and its effect on the lung. She noted that although bronchiolitis obliterans was not seen, a very clear impact on respiratory tract damage was seen, along with fibrosis. Thus, it is a shame within the confines of the reporting system that that point could not be emphasized more in the report, she observed, “Because I think there is a smoking gun in this data that supports that this compound could well be problematic to the workers.” She agreed with the level of evidence conclusions.

Dr. Morgan noted that issues associated with use of rodents are inherent in all inhalation studies, but modelers have done well in extrapolation efforts. Dr. Flake, NIEHS, said that there had been an effort to highlight the fibrosis in the report, in that it was anticipated that the animals would not develop bronchiolitis obliterans at the dosages used. The finding of fibrosis in the nose was unusual in itself, he added. Dr. Walker, NIEHS, asked Dr. Dybdal if she was recommending adding detail to the discussion of the fibrotic responses. She said that would be advantageous.

Dr. Miles, the fourth primary reviewer, also thought that the study was well-designed and comprehensive and evaluated doses relevant to human exposures. She found interesting the sex difference seen in the studies and wondered if there were any reports of sex differences in the development of bronchiolitis obliterans in the literature. She suggested investigating whether there are any reports in the literature of nasal or respiratory cancer in the workers. She asked why the specific strains of rats and mice were chosen, and why data for female spleen was not included in one of the tables. She noted that she agreed with the conclusions stated in the report.

Dr. Morgan said there are no data available on nasal cancer in workers, nor is there reference to sex difference in the bronchiolitis obliterans literature. He explained that the Wistar Han rat was the strain being used at the time, and the mouse strain was the standard. Dr. Flake said that no alterations in the spleen were seen in the females.

Dr. Miles mentioned that it would be helpful to include concentrations reported from other types of processing facilities, such as coffee roasters. Dr. Morgan said that type of data should be available through NIOSH, and he would work to include it.