# Appendix J Sentinel Animal Program

## J.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately with serology testing performed in-house or sent to the Research Animal Diagnostic Laboratory (RADIL), University of Missouri, Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point EXCEPT at the following times:18-month collection: five male rats and four female rats.

Table J-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
ELISA: In-House
Mycoplasma pulmonis | 3 weeks postarrival
Pneumonia virus of mice (PVM) | 3 weeks postarrival
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | 3 weeks postarrival
Rat parvovirus (RPV) | 3 weeks postarrival
Sendai | 3 weeks postarrival
Multiplex Fluorescent Immunoassay (MFI): RADIL
Kilham’s rat virus (KRV) | Study termination
M. pulmonis | Study termination
Parvo NS-1 | Study termination
PVM | Study termination
RCV/SDA | Study termination
Rat minute virus (RMV) | Study termination
RPV | Study termination
Rat theilovirus (RTV) | Study termination
Sendai | Study termination
Theiler’s murine encephalomyelitis virus (TMEV) | Study termination
Toolans H-1 | Study termination
Two-year Study
MFI: RADIL
KRV | 3 weeks postarrival, 6, 12, and 18 months, study termination
M. pulmonis | 3 weeks postarrival, 6, 12, and 18 months, study termination
Parvo NS-1 | 3 weeks postarrival, 6 months
PVM | 3 weeks postarrival, 6, 12, and 18 months, study termination
RCV/SDA | 3 weeks postarrival, 6, 12, and 18 months, study termination
RMV | 3 weeks postarrival, 6, 12, and 18 months, study termination
RPV | 3 weeks postarrival, 6, 12, and 18 months, study termination
RTV | 3 weeks postarrival, 6, 12, and 18 months, study termination
Sendai | 3 weeks postarrival, 6, 12, and 18 months, study termination
TMEV | 3 weeks postarrival, 6 months
Toolan’s H-1 | 3 weeks postarrival, 6, 12, and 18 months, study termination
IFA: RADIL
KRV | 12 months
RMV | 12 months
RPV | 12 months, study termination
Toolan’s H-1 | 12 months
M. pulmonis | 18 months, study termination
Mice
Three-month Study
ELISA: In-House
Mouse hepatitis virus (MHV) | 3 weeks postarrival
Mouse parvovirus | 3 weeks postarrival
M. pulmonis | 3 weeks postarrival
Pneumonia virus of mice (PVM) | 3 weeks postarrival
Sendai | 3 weeks postarrival
Theiler’s murine encephalomyelitis virus – Mouse poliovirus, strain GDVII (TMEV GDVII) | 3 weeks postarrival
MFI: RADIL
Ectromelia virus | Study termination
Epizootic diarrhea of infant mice (EDIM) | Study termination
Lymphocytic choriomeningitis virus (LCMV) | Study termination
M. pulmonis | Study termination
MHV | Study termination
Mouse norovirus (MNV) | Study termination
Mouse parvovirus (MPV) | Study termination
Minute virus of mice (MVM) | Study termination
Parvo NS-1 | Study termination
PVM | Study termination
Reovirus 3 | Study termination
Sendai | Study termination
TMEV GDVII | Study termination
Two-year Study
MFI: RADIL
Ectromelia virus | 3 weeks postarrival, 6, 12, and 18 months, study termination
EDIM | 3 weeks postarrival, 6, 12, and 18 months, study termination
LCMV | 3 weeks postarrival, 6, 12, and 18 months, study termination
M. pulmonis | 3 weeks postarrival, 6, 12, and 18 months, study termination
MHV | 3 weeks postarrival, 6, 12, and 18 months, study termination
MNV | 3 weeks postarrival, 6, 12, and 18 months, study termination
Parvo NS-1 | 3 weeks postarrival, 6 months
MPV | 3 weeks postarrival, 6, 12, and 18 months, study termination
MVM | 3 weeks postarrival, 6, 12, and 18 months, study termination
PVM | 3 weeks postarrival, 6, 12, and 18 months, study termination
Reovirus 3 | 3 weeks postarrival, 6, 12, and 18 months, study termination
Sendai | 3 weeks postarrival, 6, 12, and 18 months, study termination
TMEV GDVII | 3 weeks postarrival, 6, 12, and 18 months, study termination
IFA: RADIL
EDIM | 18 months, study termination
LCMV | Study termination
M. pulmonis | Study termination
MHV | Study termination
MNV | 18 months, study termination
MPV | Study termination
MVM | Study termination
Reovirus 3 | Study termination
TMEV GDVII | Study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## J.2 Results

All test results were negative.