# Appendix H Chemical Characterization and Generation of Chamber Concentrations

## H.1 Procurement and Characterization of 2,3-Butanedione

2,3-Butanedione was obtained from Sigma-Aldrich (Aldrich Chemical Co., Inc., Sheboygan Falls, WI) in two lots (10815TD and 03798LJ). Lot 10815TD was used in the 3-month studies, and lot 03798LJ was used in the 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the 2,3-butanedione studies are on file at the National Institute of Environmental Health Sciences.

Lots 10815TD and 03798LJ of the test chemical, a yellow liquid, were identified as 2,3-butanedione by the analytical chemistry laboratory and the study laboratory, respectively, using Fourier transform infrared (FTIR) spectroscopy and by the analytical chemistry laboratory using proton nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with the structure and composition of 2,3-butanedione. Representative FTIR and NMR spectra are presented in Figure H-1 and Figure H-2.

Elemental analysis was performed by Galbraith Laboratories (Knoxville, TN), and water content was determined by the analytical chemistry laboratory using Karl Fischer titration. The relative purity and area percent purity were determined by the study laboratory using gas chromatography (GC) with flame ionization detection (FID) by system A or B, respectively (Table H-1).

For lot 10815TD, elemental analyses for carbon, hydrogen, nitrogen, and sulfur were consistent with theoretical values for 2,3-butanedione. Karl Fischer titration indicated 0.1% water content. In samples taken from the top, middle, and bottom of the drum, GC/FID (System A) indicated an average purity of 98.7% and four minor peaks with areas greater than 0.1% of the total peak area. These impurities were identified as ethyl acetate (0.39%), 2-butanone (0.51%), acetonitrile (0.24%), and acetic acid (0.12%) by comparing to the retention times of authentic standards.

For lot 03798LJ, elemental analyses for carbon, hydrogen, nitrogen, and sulfur were consistent with theoretical values for 2,3-butanedione. Karl Fischer titration indicated 0.42% water content. Average purity in samples taken from the top, middle, and bottom of the drum was 99.1% using GC/FID system A and four minor peaks with areas greater than or equal to 0.1% of the total peak area were indicated. Three of the peaks were identified as acetaldehyde (0.1%), acetic acid (0.3%), and acetoin (0.3%) by comparing to the retention times of authentic standards.

To ensure stability, the test chemical was stored at refrigerated temperatures in metal drums under a nitrogen headspace. Periodic reanalyses of the test chemical were performed by the study laboratory using GC/FID by systems A or B prior to and after the 3-month and 2-year studies and approximately every 6 months during the 2-year studies; no degradation of the test chemical was detected.

## H.2 Vapor Generation and Exposure Systems

Diagrams of the vapor generation and delivery systems used in the 3-month and 2-year studies are shown in Figure H-3 and Figure H-4, respectively. 2,3-Butanedione was pumped onto glass beads in a heated glass column where it was vaporized. Heated nitrogen flowed through the column and carried the vapor to a short vapor-distribution manifold, where concentration was controlled by the chemical pump and nitrogen flow rates. For the 2-year studies, the nitrogen-chemical mixture was diluted with heated air (~140°F) before entering the distribution manifold. Pressure in the distribution manifold was fixed to ensure constant flows through the manifold and into the chambers.

Individual Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small-particle detector (Model 3022A; TSI, Inc., St. Paul, MN) was used with and without animals present in the exposure chambers to ensure that 2,3-butadione vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## H.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table H-2 and Table H-3. Chamber concentrations of 2,3-butanedione were monitored using an online gas chromatograph with FID (system C; Table H-1). Samples were drawn from each exposure chamber approximately every 20 minutes during each 6-hour exposure period using Hasteloy-C stream-select and gas-sampling valves (VALCO Instruments Co., Houston, TX) in a separate, heated valve oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An inline flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The online gas chromatograph was checked throughout the day for instrument drift against an online standard of 2,3-butanedione in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The online gas chromatograph was calibrated prior to the start of each study and monthly during the 3-month and 2-year studies by a comparison of chamber concentration data to data from grab samples that were collected with sorbent gas sampling tubes containing silica gel (ORBO-53; Supelco, Bellefonte, PA) followed by a sampling tube containing activated coconut charcoal (ORBO-32; Supelco), extracted with acetone containing 2-methyl-1-propanol as an internal standard, and analyzed using an offline gas chromatograph (system B, Table H-1). The volumes of gas were sampled at a constant flow rate ensured by a calibrated critical orifice. The offline gas chromatograph was calibrated with gravimetrically prepared standards of 2,3-butanedione and the internal standard 2-methyl-1-propanol in acetone.

## H.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical values for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) were approximately 9.2 minutes. For rats and mice in the 3-month studies, T_90_ values ranged from 9 to 11 minutes without animals present and from 9 to 13 minutes with animals present; T_10_ values ranged from 9 to 11 minutes without animals present and from 10 to 11 minutes with animals present. For rats and mice in the 2-year studies, T_90_ values ranged from 8 to 9 minutes without animals present and from 10 to 12 minutes with animals present; T_10_ values ranged from 8 to 10 minutes without animals present and from 10 to 11 minutes with animals present. A T_90_ value of 10 minutes was selected for the 3-month studies, and a T_90_ value of 12 minutes was selected for the 2-year studies.

The uniformity of 2,3-butanedione vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; concentration uniformity with animals present in the chambers was measured once during the 3-month studies and approximately every 3 months during the 2-year studies (Table H-2 and Table H-3). The vapor concentration was measured using the on-line gas chromatograph (system B, Table H-1) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. During the 3-month studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. During the 2-year studies, concentrations were measured at the regular monitoring port and from all sample ports where animals were present. Chamber concentration uniformity was maintained throughout the studies.

The persistence of 2,3-butanedione in the chambers after vapor delivery ended was determined by monitoring the postexposure vapor concentration in the 100 ppm rat/mouse chamber in the 3-month studies and the 50 ppm chambers in the 2-year studies without animals present in the chambers. In the 3-month studies, the concentration decreased to 1% of the target concentration within 20 minutes without animals present. During the 2-year studies in the rat only chambers, the concentration decreased to 1% of the target concentration within 21 minutes without animals present and 35 minutes with animals present. In the rat/mouse chambers, the concentration decreased to 1% of the target concentration within 19 minutes without animals present and 95 minutes with animals present.

Samples of the test atmosphere from the distribution lines and low and high exposure concentration chambers were collected prior to the 3-month and 2-year studies and also at the beginning and end of each generation day during the 3-month and 2-year studies; the atmosphere samples were collected with sorbent gas sampling tubes containing silica gel (ORBO-53; Supelco) and extracted with acetone. All of the samples were analyzed using GC/FID by system D (Table H-1) to measure the stability and purity of 2,3-butanedione in the generation and delivery system. To assess whether impurities or degradation products co-eluted with 2,3-butanedione or the solvent, a second GC/FID analysis was performed on samples extracted with dimethyl formamide. In conjunction with the stability and purity measurements described above, the relative purity of 2,3-butanedione in the generator reservoir was measured using GC/FID by system D. To demonstrate the resolution and sensitivity of the system to detect low levels of possible impurity or degradation products, a 0.1% solution of acetoin, 2-butanone, 2,3-butanediol, 3-methyl-2-4-pentanedione, ethyl acetate, acetonitrile, and acetic acid was analyzed. During the 2-year studies, GC/FID used to detect impurities was unable to determine the presence of ethyl acetate or 2-butanone due to a contaminant peak that eluted at the same retention times. GC with mass spectrometry detection (system E; Table H-1) was used, and results indicated that ethyl acetate and 2-butanone were less than 0.1% in the distribution line, 50 ppm chambers, generator reservoir, and test chemical samples and less than 0.5% in the 12.5 ppm chambers.

Table H-1 Gas Chromatography Systems Used in the Inhalation Studies of 2,3-Butanedione^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | Stabilwax-DA^®^, 30 m × 250 µm, 0.50 µm film (Restek, Bellefonte, PA) | Helium at 1 mL/minute | 40°C for 4 minutes, then 6°C/minute to 240°C, held for 5 minutes
System B
Flame ionization | Stabilwax-DA^®^, 30 m × 250 µm, 0.50 µm film (Restek) | Helium at 1 mL/minute | 45°C for 2 minutes, then 6°C/minute to 110°C, then 15°C/minute to 180°C
System C
Flame ionization | Stabilwax ^®^, 15 m × 0.53 mm, 2.0 µm film (Restek) | Nitrogen at 25 mL/minute | 65°C isothermal
System D
Flame ionization | DB-Wax ETR, 30 m × 530 µm, 1.5 µm film (J&W Scientific, Folsom, CA) | Helium at 2.6 mL/minute | 40°C for 2 minutes, then 6°C/minute to 235°C, held for 5 minutes
System E
Mass spectrometry | DB-Wax ETR, 30 m × 250 µm, 0.25 µm film (J&W Scientific) | Helium at 0.7 mL/minute | 40°C for 2 minutes, then 6°C/minute to 70°C, then 15°C/minute to 240°C, held for 3 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table H-2 Summary of Chamber Concentrations in the Three-month Inhalation Studies of 2,3-Butanedione

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a (^ppm)
Male Rat Chambers
| 6.25 | 1,280 | 6.2 ± 0.2
| 12.5 | 1,295 | 12.3 ± 0.4
| 25 | 1,293 | 24.9 ± 0.6
| 50 | 1,308 | 49.8 ± 1.2
| 100 | 1,317 | 99.5 ± 2.2
Female Rat and Mouse Chambers
| 6.25 | 1,319 | 6.2 ± 0.2
| 12.5 | 1,334 | 12.3 ± 0.4
| 25 | 1,332 | 24.9 ± 0.6
| 50 | 1,347 | 49.8 ± 1.1
| 100 | 1,356 | 99.5 ± 2.2

^a^ Mean ± standard deviation.

Table H-3 Summary of Chamber Concentrations in the Two-year Inhalation Studies of 2,3-Butanedione

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a (^ppm)
Male Rat Chambers
| 12.5 | 8,003 | 12.5 ± 0.3
| 25 | 8,040 | 25.0 ± 0.7
| 50 | 8,084 | 50.1 ± 1.5
Female Rat and Mouse Chambers
| 12.5 | 8,241 | 12.5 ± 0.4
| 25 | 8,073 | 24.9 ± 0.7
| 50 | 8,098 | 49.9 ± 1.5

^a^ Mean ± standard deviation.

Figure H-1

Infrared Absorption Spectrum of 2,3-Butanedione

Figure H-2

Nuclear Magnetic Resonance Spectrum of 2,3-Butanedione

Figure H-3

Schematic of the Vapor Generation and Delivery System in the Three-month Inhalation Studies of 2,3-Butanedione

Figure H-4

Schematic of the Vapor Generation and Delivery System in the Two-year Inhalation Studies of 2,3-Butanedione