# Appendix G Organ Weight and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 8
Necropsy body wt | 410 ± 8 | 401 ± 13 | 386 ± 8 | 407 ± 16 | 387 ± 8 | 333 ± 12**
Heart
Absolute | 1.11 ± 0.02 | 1.05 ± 0.02 | 1.03 ± 0.03 | 1.08 ± 0.03 | 1.12 ± 0.03 | 1.00 ± 0.03*
Relative | 2.723 ± 0.047 | 2.621 ± 0.063 | 2.666 ± 0.046 | 2.651 ± 0.064 | 2.890 ± 0.054 | 3.001 ± 0.075**
R. Kidney
Absolute | 1.27 ± 0.02 | 1.24 ± 0.04 | 1.21 ± 0.03 | 1.31 ± 0.03 | 1.23 ± 0.03 | 1.10 ± 0.02**
Relative | 3.105 ± 0.060 | 3.092 ± 0.075 | 3.131 ± 0.055 | 3.248 ± 0.087 | 3.182 ± 0.077 | 3.308 ± 0.066
Liver
Absolute | 12.50 ± 0.35 | 12.14 ± 0.53 | 11.83 ± 0.41 | 12.72 ± 0.81 | 11.68 ± 0.33 | 9.58 ± 0.36**
Relative | 30.510 ± 0.684 | 30.186 ± 0.426 | 30.585 ± 0.719 | 31.023 ± 1.015 | 30.218 ± 0.685 | 28.822 ± 0.807
Lung
Absolute | 2.45 ± 0.08 | 2.40 ± 0.11 | 2.29 ± 0.08 | 2.46 ± 0.15 | 2.47 ± 0.10 | 2.25 ± 0.08
Relative | 5.988 ± 0.162 | 6.005 ± 0.268 | 5.935 ± 0.164 | 6.036 ± 0.307 | 6.404 ± 0.270 | 6.810 ± 0.358
Spleen
Absolute | 0.570 ± 0.026 | 0.600 ± 0.035 | 0.570 ± 0.022 | 0.605 ± 0.023 | 0.606 ± 0.020 | 0.488 ± 0.026
Relative | 1.389 ± 0.048 | 1.510 ± 0.097 | 1.478 ± 0.059 | 1.491 ± 0.048 | 1.568 ± 0.048 | 1.462 ± 0.057
R. Testis
Absolute | 1.819 ± 0.053 | 1.831 ± 0.058 | 1.778 ± 0.053 | 1.784 ± 0.057 | 1.826 ± 0.031 | 1.646 ± 0.055
Relative | 4.448 ± 0.135 | 4.600 ± 0.185 | 4.604 ± 0.113 | 4.405 ± 0.133 | 4.735 ± 0.116 | 4.966 ± 0.185
Thymus
Absolute | 0.448 ± 0.027 | 0.449 ± 0.022 | 0.509 ± 0.030 | 0.467 ± 0.039 | 0.417 ± 0.020 | 0.340 ± 0.022*
Relative | 1.088 ± 0.055 | 1.129 ± 0.073 | 1.324 ± 0.088 | 1.144 ± 0.083 | 1.076 ± 0.042 | 1.035 ± 0.085
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 236 ± 6 | 235 ± 5 | 228 ± 4 | 226 ± 4 | 232 ± 6 | 208 ± 9**
Heart
Absolute | 0.77 ± 0.01 | 0.74 ± 0.02 | 0.74 ± 0.01 | 0.77 ± 0.05 | 0.74 ± 0.02 | 0.73 ± 0.02
Relative | 3.257 ± 0.070 | 3.139 ± 0.049 | 3.242 ± 0.039 | 3.419 ± 0.203 | 3.206 ± 0.055 | 3.550 ± 0.087
R. Kidney
Absolute | 0.85 ± 0.02 | 0.82 ± 0.03 | 0.81 ± 0.02 | 0.80 ± 0.02 | 0.79 ± 0.03 | 0.77 ± 0.03
Relative | 3.597 ± 0.085 | 3.468 ± 0.084 | 3.568 ± 0.069 | 3.531 ± 0.052 | 3.429 ± 0.110 | 3.747 ± 0.116
Liver
Absolute | 7.42 ± 0.25 | 7.21 ± 0.26 | 7.03 ± 0.17 | 6.93 ± 0.20 | 7.04 ± 0.16 | 6.41 ± 0.41*
Relative | 31.390 ± 0.711 | 30.626 ± 0.700 | 30.802 ± 0.470 | 30.730 ± 0.872 | 30.446 ± 0.703 | 30.671 ± 1.153
Lung
Absolute | 1.63 ± 0.06 | 1.49 ± 0.06 | 1.53 ± 0.07 | 1.50 ± 0.07 | 1.72 ± 0.12 | 1.64 ± 0.06
Relative | 6.943 ± 0.309 | 6.343 ± 0.228 | 6.740 ± 0.332 | 6.652 ± 0.252 | 7.370 ± 0.394 | 8.003 ± 0.395*
Spleen
Absolute | 0.413 ± 0.014 | 0.426 ± 0.012 | 0.408 ± 0.019 | 0.376 ± 0.017 | 0.422 ± 0.020 | 0.368 ± 0.025
Relative | 1.756 ± 0.070 | 1.818 ± 0.053 | 1.786 ± 0.071 | 1.661 ± 0.058 | 1.822 ± 0.081 | 1.766 ± 0.084
Thymus
Absolute | 0.401 ± 0.020 | 0.406 ± 0.025 | 0.402 ± 0.011 | 0.409 ± 0.016 | 0.393 ± 0.019 | 0.304 ± 0.039*
Relative | 1.701 ± 0.083 | 1.724 ± 0.090 | 1.763 ± 0.042 | 1.808 ± 0.053 | 1.702 ± 0.091 | 1.404 ± 0.165

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.8 ± 1.2 | 38.0 ± 1.3 | 37.8 ± 0.7 | 39.1 ± 0.6 | 34.2 ± 1.1* | 27.9 ± 0.6**
Heart
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.14 ± 0.00** | 0.12 ± 0.00**
Relative | 4.277 ± 0.095 | 4.200 ± 0.092 | 4.396 ± 0.122 | 4.303 ± 0.112 | 4.111 ± 0.075 | 4.395 ± 0.109
R. Kidney
Absolute | 0.32 ± 0.01 | 0.32 ± 0.01 | 0.33 ± 0.01 | 0.34 ± 0.01 | 0.29 ± 0.01** | 0.23 ± 0.01**
Relative | 8.591 ± 0.231 | 8.543 ± 0.200 | 8.796 ± 0.217 | 8.655 ± 0.213 | 8.444 ± 0.163 | 8.263 ± 0.178
Liver
Absolute | 1.57 ± 0.05 | 1.59 ± 0.05 | 1.68 ± 0.06 | 1.68 ± 0.05 | 1.36 ± 0.04** | 1.12 ± 0.04**
Relative | 41.525 ± 0.628 | 41.855 ± 0.688 | 44.455 ± 1.272 | 42.818 ± 1.033 | 39.908 ± 0.642 | 40.206 ± 0.985
Lung
Absolute | 0.21 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.00 | 0.23 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.00
Relative | 5.632 ± 0.157 | 5.924 ± 0.162 | 5.925 ± 0.081 | 5.962 ± 0.140 | 6.302 ± 0.248* | 7.243 ± 0.223**
Spleen
Absolute | 0.067 ± 0.002 | 0.068 ± 0.002 | 0.073 ± 0.003 | 0.069 ± 0.002 | 0.065 ± 0.004 | 0.063 ± 0.003
Relative | 1.786 ± 0.070 | 1.802 ± 0.064 | 1.939 ± 0.099 | 1.765 ± 0.055 | 1.916 ± 0.128 | 2.263 ± 0.101**
R. Testis
Absolute | 0.114 ± 0.002 | 0.116 ± 0.002 | 0.118 ± 0.002 | 0.116 ± 0.003 | 0.111 ± 0.001 | 0.108 ± 0.001*
Relative | 3.044 ± 0.107 | 3.061 ± 0.076 | 3.116 ± 0.041 | 2.981 ± 0.082 | 3.289 ± 0.111 | 3.880 ± 0.070**
Thymus
Absolute | 0.053 ± 0.004 | 0.055 ± 0.003 | 0.050 ± 0.002 | 0.052 ± 0.005 | 0.046 ± 0.003 | 0.047 ± 0.002
Relative | 1.383 ± 0.076 | 1.454 ± 0.100 | 1.324 ± 0.042 | 1.311 ± 0.116 | 1.352 ± 0.064 | 1.674 ± 0.047*
Female
Necropsy body wt | 33.0 ± 0.9 | 31.8 ± 0.7 | 30.9 ± 0.6* | 29.4 ± 0.7** | 27.6 ± 0.5** | 23.8 ± 0.5**
Heart
Absolute | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00 | 0.13 ± 0.00** | 0.12 ± 0.00**
Relative | 4.534 ± 0.160 | 4.662 ± 0.080 | 4.834 ± 0.123 | 4.772 ± 0.084 | 4.710 ± 0.096 | 4.847 ± 0.100
R. Kidney
Absolute | 0.22 ± 0.00 | 0.21 ± 0.01 | 0.22 ± 0.00 | 0.21 ± 0.00 | 0.19 ± 0.00** | 0.18 ± 0.01**
Relative | 6.569 ± 0.194 | 6.582 ± 0.140 | 7.012 ± 0.183 | 7.119 ± 0.120* | 7.020 ± 0.097* | 7.446 ± 0.170**
Liver
Absolute | 1.49 ± 0.05 | 1.49 ± 0.05 | 1.51 ± 0.04 | 1.38 ± 0.04 | 1.21 ± 0.03** | 1.01 ± 0.04**
Relative | 45.214 ± 1.240 | 46.788 ± 1.220 | 48.971 ± 0.700 | 46.724 ± 0.813 | 43.696 ± 0.758 | 42.284 ± 1.420
Lung
Absolute | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.00 | 0.21 ± 0.00 | 0.21 ± 0.01 | 0.21 ± 0.01
Relative | 6.959 ± 0.349 | 7.045 ± 0.206 | 7.271 ± 0.176 | 7.242 ± 0.103 | 7.565 ± 0.146 | 8.759 ± 0.186**
Spleen
Absolute | 0.099 ± 0.003 | 0.096 ± 0.003 | 0.094 ± 0.003 | 0.094 ± 0.002 | 0.081 ± 0.002** | 0.074 ± 0.003**
Relative | 3.017 ± 0.134 | 3.028 ± 0.095 | 3.056 ± 0.132 | 3.204 ± 0.087 | 2.938 ± 0.096 | 3.113 ± 0.123
Thymus
Absolute | 0.065 ± 0.004 | 0.056 ± 0.001* | 0.056 ± 0.003* | 0.054 ± 0.002** | 0.048 ± 0.002** | 0.048 ± 0.002**
Relative | 1.954 ± 0.106 | 1.772 ± 0.056 | 1.819 ± 0.085 | 1.826 ± 0.055 | 1.747 ± 0.061 | 2.017 ± 0.076

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).