# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | | 25 ppm | 50 ppm | | 100 ppm
Male
Hematology
n
Day 3 | 10 | 10 | 10 | | 10 | 10 | | 10
Day 23 | 10 | 10 | 10 | | 10 | 10 | | 10
Week 14 | 10 | 10 | 10 | | 10 | 10 | | 7
Hematocrit (%)
Day 3 | 46.3 ± 0.5 | 45.2 ± 0.4 | 43.7 ± 0.6* | | 44.6 ± 0.6 | 44.2 ± 0.5 | | 44.8 ± 0.8
Day 23 | 48.5 ± 0.8 | 47.6 ± 0.7 | 47.8 ± 0.6 | | 48.1 ± 0.8 | 47.6 ± 0.6 | | 48.5 ± 0.6
Week 14 | 49.0 ± 0.6 | 48.2 ± 0.5 | 48.2 ± 0.7 | | 49.5 ± 1.2 | 50.4 ± 0.8 | | 51.4 ± 1.1
Packed cell volume (%)
Day 3 | 44.1 ± 0.6 | 43.0 ± 0.5 | 41.4 ± 0.6* | | 42.1 ± 0.5 | 42.4 ± 0.4 | | 42.7 ± 0.7
Day 23 | 46.8 ± 0.7 | 46.0 ± 0.6 | 46.5 ± 0.7 | | 46.6 ± 0.9 | 45.9 ± 0.7 | | 47.0 ± 0.8
Week 14 | 47.2 ± 0.7 | 47.3 ± 0.6 | 47.5 ± 0.7 | | 48.6 ± 1.2 | 49.4 ± 0.8* | | 50.3 ± 1.1*
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.2 | 13.4 ± 0.2 | 13.1 ± 0.2 | | 13.3 ± 0.2 | 13.3 ± 0.1 | | 13.4 ± 0.2
Day 23 | 14.7 ± 0.2 | 14.6 ± 0.2 | 14.7 ± 0.2 | | 14.8 ± 0.3 | 14.4 ± 0.2 | | 14.9 ± 0.2
Week 14 | 15.2 ± 0.2 | 15.3 ± 0.2 | 15.4 ± 0.2 | | 15.7 ± 0.3 | 15.7 ± 0.2* | | 16.3 ± 0.4**
Erythrocytes (10^6^/μL)
Day 3 | 7.07 ± 0.10 | 6.86 ± 0.12 | 6.68 ± 0.11 | | 6.89 ± 0.09 | 6.96 ± 0.09 | | 6.96 ± 0.14
Day 23 | 7.80 ± 0.11 | 7.64 ± 0.15 | 7.67 ± 0.13 | | 7.80 ± 0.12 | 7.75 ± 0.11 | | 7.98 ± 0.16
Week 14 | 8.82 ± 0.14 | 8.86 ± 0.13 | 8.97 ± 0.10 | | 8.93 ± 0.25 | 9.14 ± 0.16 | | 9.57 ± 0.19**
Reticulocytes (10^3^/μL)
Day 3 | 457.8 ± 15.8 | 435.9 ± 18.5 | 476.5 ± 8.9 | | 477.3 ± 14.9 | 470.1 ± 20.8 | | 468.8 ± 19.6
Day 23 | 176.1 ± 7.7 | 179.6 ± 10.2 | 183.2 ± 8.7 | | 207.2 ± 12.6 | 201.1 ± 10.7 | | 213.7 ± 19.3
Week 14 | 214.4 ± 9.1 | 175.4 ± 10.3 | 180.6 ± 12.5 | | 182.1 ± 8.5 | 188.0 ± 7.8 | | 177.4 ± 15.2
Reticulocytes/1,000 erythrocytes
Day 3 | 64.70 ± 1.99 | 63.50 ± 2.35 | 71.50 ± 1.60 | | 69.40 ± 2.27 | 67.40 ± 2.41 | | 67.50 ± 2.94
Day 23 | 22.60 ± 0.93 | 23.50 ± 1.22 | 23.90 ± 1.15 | | 26.60 ± 1.69 | 25.90 ± 1.24 | | 26.80 ± 2.39
Week 14 | 24.30 ± 0.91 | 19.80 ± 1.16* | 20.10 ± 1.29 | | 20.40 ± 0.85 | 20.60 ± 0.81 | | 18.57 ± 1.56*
Nucleated erythrocytes (10^3^/µL)
Day 3 | 9.28 ± 0.58 | 8.42 ± 0.60 | 8.63 ± 0.62 | | 8.90 ± 0.40 | 8.43 ± 0.55 | | 9.14 ± 0.45
Day 23 | 9.22 ± 0.64 | 7.53 ± 0.27 | 8.54 ± 0.42 | | 9.27 ± 0.45 | 8.35 ± 0.78 | | 9.53 ± 0.71
Week 14 | 7.33 ± 0.60 | 7.20 ± 0.37 | 7.68 ± 0.36 | | 7.05 ± 0.60 | 9.02 ± 0.76 | | 7.25 ± 0.65
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.4 ± 0.2 | 0.0 ± 0.0 | 0.1 ± 0.1 | | 0.4 ± 0.2 | 0.0 ± 0.0 | | 0.2 ± 0.1
Day 23 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0
Week 14 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0
Mean cell volume (fL)
Day 3 | 62.4 ± 0.6 | 62.8 ± 0.9 | 62.0 ± 0.6 | | 61.2 ± 0.7 | 61.0 ± 0.6 | | 61.4 ± 0.7
Day 23 | 60.1 ± 0.3 | 60.3 ± 0.9 | 60.6 ± 0.6 | | 59.7 ± 0.6 | 59.2 ± 0.4 | | 58.9 ± 0.7
Week 14 | 53.5 ± 0.5 | 53.5 ± 0.5 | 53.0 ± 0.6 | | 54.5 ± 0.5 | 54.0 ± 0.4 | | 52.6 ± 0.4
Mean cell hemoglobin (pg)
Day 3 | 19.3 ± 0.2 | 19.5 ± 0.3 | 19.6 ± 0.2 | | 19.3 ± 0.2 | 19.1 ± 0.2 | | 19.2 ± 0.2
Day 23 | 18.9 ± 0.1 | 19.1 ± 0.3 | 19.2 ± 0.2 | | 19.0 ± 0.2 | 18.6 ± 0.1 | | 18.7 ± 0.2
Week 14 | 17.2 ± 0.2 | 17.2 ± 0.1 | 17.1 ± 0.1 | | 17.6 ± 0.2 | 17.2 ± 0.1 | | 17.0 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 30.9 ± 0.2 | 31.1 ± 0.1 | 31.6 ± 0.1** | | 31.5 ± 0.1* | 31.3 ± 0.1 | | 31.3 ± 0.1
Day 23 | 31.4 ± 0.1 | 31.7 ± 0.1 | 31.6 ± 0.1 | | 31.8 ± 0.1 | 31.5 ± 0.2 | | 31.7 ± 0.2
Week 14 | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.3 ± 0.2 | | 32.4 ± 0.2 | 31.8 ± 0.1 | | 32.3 ± 0.3
Platelets (10^3^/μL)
Day 3 | 798 ± 30 | 898 ± 38 | 837 ± 30 | | 821 ± 16 | 820 ± 36 | | 870 ± 22
Day 23 | 697 ± 31 | 698 ± 20 | 692 ± 21 | | 697 ± 24 | 712 ± 29 | | 725 ± 34
Week 14 | 722 ± 29 | 726 ± 19 | 721 ± 36 | | 710 ± 30 | 712 ± 20 | | 692 ± 21
Leukocytes (10^3^/μL)
Day 3 | 9.24 ± 0.57 | 8.42 ± 0.59 | 8.62 ± 0.62 | | 8.86 ± 0.39 | 8.43 ± 0.55 | | 9.13 ± 0.45
Day 23 | 9.22 ± 0.64 | 7.53 ± 0.27 | 8.54 ± 0.42 | | 9.27 ± 0.45 | 8.35 ± 0.78 | | 9.53 ± 0.71
Week 14 | 7.33 ± 0.60 | 7.20 ± 0.37 | 7.68 ± 0.36 | | 7.05 ± 0.60 | 9.02 ± 0.76 | | 7.25 ± 0.65
Segmented neutrophils (10^3^/μL)
Day 3 | 1.03 ± 0.08 | 0.75 ± 0.07 | 0.84 ± 0.07 | | 0.87 ± 0.05 | 0.93 ± 0.08 | | 0.95 ± 0.09
Day 23 | 1.22 ± 0.11 | 0.86 ± 0.07 | 0.95 ± 0.10 | | 1.02 ± 0.10 | 1.76 ± 0.38 | | 1.65 ± 0.20
Week 14 | 1.47 ± 0.15 | 1.16 ± 0.10 | 1.29 ± 0.12 | | 1.31 ± 0.11 | 2.48 ± 0.47 | | 2.10 ± 0.21
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 3 | 7.92 ± 0.54 | 7.43 ± 0.51 | 7.54 ± 0.58 | | 7.69 ± 0.38 | 7.27 ± 0.50 | | 7.90 ± 0.45
Day 23 | 7.79 ± 0.55 | 6.49 ± 0.24 | 7.41 ± 0.40 | | 8.07 ± 0.41 | 6.39 ± 0.58 | | 7.71 ± 0.61
Week 14 | 5.66 ± 0.48 | 5.77 ± 0.33 | 6.06 ± 0.34 | | 5.47 ± 0.62 | 6.37 ± 0.52 | | 4.96 ± 0.50
Monocytes (10^3^/μL)
Day 3 | 0.17 ± 0.03 | 0.13 ± 0.03 | 0.13 ± 0.02 | | 0.18 ± 0.02 | 0.13 ± 0.02 | | 0.14 ± 0.02
Day 23 | 0.09 ± 0.03 | 0.08 ± 0.02 | 0.07 ± 0.01 | | 0.07 ± 0.02 | 0.11 ± 0.06 | | 0.06 ± 0.01
Week 14 | 0.05 ± 0.02 | 0.10 ± 0.04 | 0.15 ± 0.05 | | 0.10 ± 0.04 | 0.05 ± 0.01 | | 0.05 ± 0.01
Basophils (10^3^/μL)
Day 3 | 0.02 ± 0.00 | 0.03 ± 0.01 | 0.02 ± 0.00 | | 0.02 ± 0.00 | 0.02 ± 0.00 | | 0.03 ± 0.00
Day 23 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | | 0.02 ± 0.00 | 0.02 ± 0.00 | | 0.02 ± 0.00
Week 14 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.00 | | 0.02 ± 0.00 | 0.01 ± 0.00 | | 0.01 ± 0.00
Eosinophils (10^3^/μL)
Day 3 | 0.11 ± 0.04 | 0.08 ± 0.01 | 0.10 ± 0.02 | | 0.10 ± 0.01 | 0.07 ± 0.01 | | 0.09 ± 0.01
Day 23 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | | 0.08 ± 0.01 | 0.08 ± 0.01 | | 0.08 ± 0.02
Week 14 | 0.14 ± 0.02 | 0.15 ± 0.03 | 0.17 ± 0.02 | | 0.15 ± 0.02 | 0.12 ± 0.03 | | 0.12 ± 0.02
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | | 10 | 10 | | 10
Day 23 | 10 | 10 | 10 | | 10 | 10 | | 10
Week 14 | 10 | 10 | 10 | | 10 | 10 | | 8
Urea nitrogen (mg/dL)
Day 3 | 8.9 ± 0.8 | 8.1 ± 0.6 | 9.3 ± 0.8 | | 8.1 ± 0.6 | 9.1 ± 0.8 | | 7.6 ± 0.3
Day 23 | 12.6 ± 0.7 | 11.7 ± 0.4 | 11.9 ± 0.5 | | 10.8 ± 0.4 | 10.5 ± 0.4* | | 9.1 ± 0.5**
Week 14 | 16.3 ± 0.6 | 16.7 ± 0.6 | 16.3 ± 0.6 | | 17.7 ± 0.6 | 16.4 ± 0.5 | | 16.9 ± 1.0
Creatinine (mg/dL)
Day 3 | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.24 ± 0.02 | | 0.22 ± 0.01 | 0.22 ± 0.02 | | 0.24 ± 0.02
Day 23 | 0.32 ± 0.01 | 0.34 ± 0.03 | 0.31 ± 0.02 | | 0.30 ± 0.01 | 0.32 ± 0.01 | | 0.30 ± 0.01
Glucose (mg/dL)
Day 3 | 149 ± 7 | 147 ± 6 | 139 ± 1 | | 150 ± 7 | 141 ± 3 | | 135 ± 2*
Day 23 | 140 ± 6 | 148 ± 7 | 130 ± 3 | | 139 ± 6 | 147 ± 7 | | 131 ± 5
Week 14 | 146 ± 7 | 135 ± 3 | 132 ± 4 | | 128 ± 5 | 132 ± 6 | | 144 ± 7
Total protein (g/dL)
Day 3 | 6.0 ± 0.0 | 5.9 ± 0.1 | 5.9 ± 0.1 | | 5.8 ± 0.1 | 5.9 ± 0.1 | | 6.0 ± 0.1
Day 23 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | | 6.4 ± 0.1 | 6.4 ± 0.1 | | 6.4 ± 0.1
Week 14 | 7.0 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1 | | 7.2 ± 0.2 | 7.3 ± 0.1 | | 7.1 ± 0.1
Albumin (g/dL)
Day 3 | 4.4 ± 0.0 | 4.3 ± 0.1 | 4.4 ± 0.0 | | 4.3 ± 0.0 | 4.3 ± 0.1 | | 4.3 ± 0.0
Day 23 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.0 | | 4.4 ± 0.1 | 4.3 ± 0.1 | | 4.5 ± 0.1
Week 14 | 4.7 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.1 | | 4.8 ± 0.1 | 4.7 ± 0.1 | | 4.5 ± 0.1
Globulin (g/dL)
Day 3 | 1.6 ± 0.0 | 1.6 ± 0.1 | 1.5 ± 0.1 | | 1.5 ± 0.1 | 1.6 ± 0.0 | | 1.6 ± 0.1
Day 23 | 2.0 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | | 1.9 ± 0.1 | 2.0 ± 0.1 | | 1.9 ± 0.1
Week 14 | 2.4 ± 0.1 | 2.4 ± 0.1 | 2.4 ± 0.1 | | 2.4 ± 0.1 | 2.6 ± 0.1 | | 2.6 ± 0.1
Albumin/globulin ratio
Day 3 | 2.8 ± 0.1 | 2.8 ± 0.1 | 2.9 ± 0.1 | | 2.9 ± 0.1 | 2.8 ± 0.1 | | 2.7 ± 0.1
Day 23 | 2.3 ± 0.1 | 2.3 ± 0.1 | 2.4 ± 0.1 | | 2.3 ± 0.1 | 2.2 ± 0.1 | | 2.4 ± 0.1
Week 14 | 2.0 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | | 2.0 ± 0.1 | 1.8 ± 0.1 | | 1.8 ± 0.1
Cholesterol (mg/dL)
Day 3 | 100 ± 5 | 91 ± 4 | 92 ± 5 | | 92 ± 4 | 95 ± 4 | | 91 ± 5
Day 23 | 81 ± 4 | 72 ± 3 | 75 ± 4 | | 82 ± 4 | 80 ± 5 | | 81 ± 6
Week 14 | 82 ± 7 | 93 ± 5 | 88 ± 6 | | 93 ± 6 | 91 ± 4 | | 77 ± 4
Triglycerides (mg/dL)
Day 3 | 113 ± 18 | 80 ± 9 | 74 ± 9 | | 75 ± 15 | 68 ± 8 | | 57 ± 9**
Day 23 | 102 ± 15 | 91 ± 9 | 94 ± 13 | | 114 ± 17 | 82 ± 11 | | 83 ± 13
Week 14 | 115 ± 20 | 99 ± 9 | 105 ± 13 | | 134 ± 25 | 101 ± 6 | | 105 ± 21
Alanine aminotransferase (IU/L)
Day 3 | 41 ± 2 | 45 ± 2 | 45 ± 3 | | 42 ± 2 | 39 ± 1 | | 39 ± 2
Day 23 | 32 ± 1 | 31 ± 1 | 33 ± 2 | | 33 ± 2 | 31 ± 2 | | 33 ± 2
Week 14 | 34 ± 1 | 31 ± 2 | 33 ± 2 | | 33 ± 2 | 35 ± 2 | | 37 ± 5
Alkaline phosphatase (IU/L)
Day 3 | 269 ± 18 | 267 ± 19 | 239 ± 7 | | 275 ± 16 | 269 ± 25 | | 271 ± 18
Day 23 | 187 ± 13 | 190 ± 13 | 168 ± 6 | | 200 ± 14 | 196 ± 14 | | 205 ± 13
Week 14 | 123 ± 8 | 137 ± 7 | 119 ± 8 | | 115 ± 7 | 131 ± 6 | | 147 ± 12
Creatine kinase (IU/L)
Day 3 | 368 ± 64 | 384 ± 46 | 256 ± 15 | | 351 ± 45 | 298 ± 16 | | 269 ± 21
Day 23 | 319 ± 26 | 503 ± 177 | 241 ± 18 | | 341 ± 41 | 376 ± 39 | | 344 ± 32
Week 14 | 155 ± 15 | 134 ± 8 | 161 ± 22 | | 233 ± 33 | 151 ± 22 | | 205 ± 24
Sorbitol dehydrogenase (IU/L)
Day 3 | 14 ± 1 | 15 ± 0 | 13 ± 0 | | 14 ± 0 | 14 ± 1 | | 14 ± 1
Day 23 | 15 ± 1 | 14 ± 1 | 13 ± 1 | | 15 ± 1 | 13 ± 1 | | 13 ± 0
Week 14 | 13 ± 0 | 12 ± 1 | f | | 11 ± 1 | 12 ± 1 | | 13 ± 1
Bile acids (µmol/L)
Day 3 | 27.6 ± 5.5 | 21.5 ± 2.1 | 30.5 ± 5.3 | | 25.7 ± 3.5 | 20.1 ± 3.6 | | 16.2 ± 3.2
Day 23 | 22.7 ± 3.9 | 20.9 ± 2.3 | 20.3 ± 4.0 | | 20.3 ± 4.7 | 18.2 ± 4.3 | | 10.2 ± 1.8*
Week 14 | 5.5 ± 1.8 | 4.7 ± 1.4 | 5.4 ± 1.7 | | 3.3 ± 0.6 | 4.6 ± 1.0 | | 6.4 ± 1.7
Female
n | 10 | 10 | 10 | | 10 | 10 | 10
Hematology
Hematocrit (%)
Day 3 | 45.2 ± 0.5 | 45.7 ± 0.3 | 45.4 ± 0.4 | | 44.0 ± 0.7 | 45.2 ± 0.5 | 44.6 ± 0.9
Day 23 | 47.2 ± 0.2 | 47.3 ± 0.4 | 48.1 ± 0.7 | | 47.6 ± 0.6 | 48.3 ± 0.5 | 48.9 ± 0.5**
Week 14 | 46.3 ± 0.5 | 45.8 ± 0.6 | 46.8 ± 0.7 | | 46.1 ± 0.3 | 47.8 ± 0.4 | 48.1 ± 0.8
Packed cell volume (%)
Day 3 | 43.7 ± 0.5 | 43.6 ± 0.4 | 43.0 ± 0.4 | | 41.8 ± 0.5 | 43.3 ± 0.5 | 42.8 ± 0.8
Day 23 | 45.4 ± 0.2 | 45.8 ± 0.3 | 46.4 ± 0.6 | | 45.9 ± 0.5 | 46.4 ± 0.5 | 47.5 ± 0.5**
Week 14 | 45.7 ± 0.3 | 45.7 ± 0.4 | 46.9 ± 0.6 | | 45.7 ± 0.4 | 47.1 ± 0.5 | 47.6 ± 0.6*
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.2 | 13.7 ± 0.1 | 13.6 ± 0.1 | | 13.1 ± 0.2 | 13.8 ± 0.2 | 13.6 ± 0.2
Day 23 | 14.8 ± 0.1 | 14.9 ± 0.1 | 15.1 ± 0.1 | | 14.9 ± 0.2 | 15.2 ± 0.2 | 15.4 ± 0.2**
Week 14 | 14.8 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.2 | | 14.7 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.3
Erythrocytes (10^6^/μL)
Day 3 | 7.15 ± 0.13 | 7.10 ± 0.07 | 7.08 ± 0.12 | | 6.93 ± 0.11 | 7.19 ± 0.05 | 7.12 ± 0.17
Day 23 | 7.68 ± 0.06 | 7.68 ± 0.05 | 7.88 ± 0.11 | | 7.82 ± 0.11 | 7.90 ± 0.11 | 8.07 ± 0.14*
Week 14 | 8.17 ± 0.09 | 8.18 ± 0.09 | 8.36 ± 0.12 | | 8.16 ± 0.07 | 8.54 ± 0.11* | 8.67 ± 0.17*
Reticulocytes (103/μL)
Day 3 | 386.3 ± 12.63 | 412.0 ± 21.9 | 398.0 ± 15.8 | | 383.4 ± 22.7 | 397.7 ± 20.7 | 399.4 ± 16.2
Day 23 | 201.0 ± 9.5 | 191.1 ± 7.3 | 195.1 ± 9.0 | | 195.8 ± 11.2 | 210.1 ± 12.1 | 226.7 ± 9.5
Week 14 | 225.7 ± 8.5 | 193.3 ± 8.9 | 199.6 ± 7.9 | | 204.1 ± 12.5 | 204.5 ± 10.9 | 203.5 ± 10.6
Reticulocytes/1,000 erythrocytes
Day 3 | 54.20 ± 2.13 | 58.00 ± 2.96 | 56.40 ± 2.61 | | 55.20 ± 2.90 | 55.30 ± 2.80 | 56.10 ± 1.76
Day 23 | 26.20 ± 1.23 | 24.90 ± 0.96 | 24.70 ± 0.88 | | 25.00 ± 1.30 | 26.60 ± 1.52 | 28.20 ± 1.40
Week 14 | 27.60 ± 0.92 | 23.60 ± 1.01 | 23.90 ± 0.95 | | 25.10 ± 1.66 | 24.00 ± 1.34 | 23.50 ± 1.20
Nucleated erythrocytes (10^3^/µL)
Day 3 | 8.97 ± 0.50 | 7.45 ± 0.69 | 7.90 ± 0.62 | | 7.52 ± 0.42 | 7.72 ± 0.74 | 8.31 ± 0.42
Day 23 | 6.91 ± 0.38 | 6.40 ± 0.62 | 6.59 ± 0.38 | | 6.58 ± 0.47 | 8.10 ± 0.75 | 8.31 ± 0.36
Week 14 | 7.17 ± 0.57 | 6.25 ± 0.36 | 6.79 ± 0.30 | | 6.19 ± 0.62 | 7.96 ± 0.73 | 7.88 ± 0.56
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.10 ± 0.1 | | 0.10 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0
Day 23 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.00 ± 0.0 | | 0.00 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Week 14 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.20 ± 0.1 | | 0.00 ± 0.0 | 0.1 ± 0.1 | 0.0 ± 0.0
Mean cell volume (fL)
Day 3 | 61.2 ± 0.6 | 61.4 ± 0.3 | 60.8 ± 0.7 | | 60.4 ± 0.7 | 60.2 ± 0.6 | 60.3 ± 0.8
Day 23 | 59.2 ± 0.4 | 59.7 ± 0.3 | 58.9 ± 0.7 | | 58.8 ± 0.6 | 58.8 ± 0.7 | 58.9 ± 0.6
Week 14 | 56.0 ± 0.5 | 55.9 ± 0.5 | 56.1 ± 0.4 | | 56.0 ± 0.2 | 55.3 ± 0.5 | 55.0 ± 0.5
Mean cell hemoglobin (pg)
Day 3 | 19.2 ± 0.2 | 19.2 ± 0.2 | 19.2 ± 0.2 | | 18.9 ± 0.2 | 19.2 ± 0.2 | 19.1 ± 0.3
Day 23 | 19.3 ± 0.1 | 19.4 ± 0.1 | 19.1 ± 0.2 | | 19.1 ± 0.2 | 19.2 ± 0.2 | 19.1 ± 0.2
Week 14 | 18.1 ± 0.2 | 18.2 ± 0.2 | 18.0 ± 0.2 | | 18.1 ± 0.1 | 17.9 ± 0.1 | 17.7 ± 0.3
Mean cell hemoglobin concentration (g/dL)
Day 3 | 31.3 ± 0.1 | 31.3 ± 0.1 | 31.5 ± 0.2 | | 31.3 ± 0.1 | 31.9 ± 0.1** | | 31.8 ± 0.2*
Day 23 | 32.6 ± 0.1 | 32.5 ± 0.1 | 32.5 ± 0.1 | | 32.4 ± 0.1 | 32.7 ± 0.1 | | 32.5 ± 0.1
Week 14 | 32.3 ± 0.1 | 32.6 ± 0.1 | 32.1 ± 0.1 | | 32.3 ± 0.1 | 32.4 ± 0.1 | | 32.1 ± 0.5
Platelets (10^3^/μL)
Day 3 | 917 ± 38 | 884 ± 36 | 1,006 ± 32 | | 909 ± 23 | 902 ± 20 | | 906 ± 35
Day 23 | 732 ± 25 | 692 ± 27 | 760 ± 19 | | 708 ± 17 | 768 ± 26 | | 795 ± 23
Week 14 | 788 ± 32 | 732 ± 34 | 726 ± 25 | | 734 ± 37 | 791 ± 24 | | 772 ± 24
Leukocytes (10^3^/μL)
Day 3 | 8.97 ± 0.49 | 7.45 ± 0.69 | 7.89 ± 0.62 | | 7.51 ± 0.42 | 7.72 ± 0.74 | | 8.31 ± 0.42
Day 23 | 6.91 ± 0.38 | 6.40 ± 0.62 | 6.59 ± 0.38 | | 6.58 ± 0.47 | 8.10 ± 0.75 | | 8.31 ± 0.36
Week 14 | 7.16 ± 0.57 | 6.25 ± 0.36 | 6.78 ± 0.30 | | 6.19 ± 0.62 | 7.95 ± 0.73 | | 7.88 ± 0.56
Segmented neutrophils (10^3^/μL)
Day 3 | 0.90 ± 0.11 | 0.76 ± 0.10 | 0.65 ± 0.06 | | 0.69 ± 0.08 | 0.77 ± 0.06 | | 1.03 ± 0.14
Day 23 | 0.90 ± 0.09 | 0.82 ± 0.09 | 0.63 ± 0.08 | | 0.75 ± 0.10 | 1.82 ± 0.35 | | 1.59 ± 0.24*
Week 14 | 1.54 ± 0.21 | 1.27 ± 0.15 | 1.24 ± 0.08 | | 1.32 ± 0.27 | 2.19 ± 0.27 | | 3.48 ± 0.42**
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 3 | 7.72 ± 0.48 | 6.46 ± 0.65 | 7.05 ± 0.58 | | 6.56 ± 0.37 | 6.69 ± 0.70 | | 7.04 ± 0.35
Day 23 | 5.78 ± 0.33 | 5.36 ± 0.58 | 5.82 ± 0.38 | | 5.66 ± 0.43 | 6.10 ± 0.70 | | 6.51 ± 0.36
Week 14 | 5.38 ± 0.39 | 4.82 ± 0.29 | 5.31 ± 0.31 | | 4.68 ± 0.47 | 5.46 ± 0.60 | | 4.15 ± 0.41
Monocytes (10^3^/μL)
Day 3 | 0.19 ± 0.02 | 0.12 ± 0.02 | 0.09 ± 0.02* | | 0.16 ± 0.04 | 0.12 ± 0.02 | | 0.13 ± 0.04
Day 23 | 0.07 ± 0.01 | 0.09 ± 0.03 | 0.06 ± 0.01 | | 0.05 ± 0.01 | 0.07 ± 0.03 | | 0.08 ± 0.02
Week 14 | 0.13 ± 0.05 | 0.05 ± 0.01 | 0.12 ± 0.04 | | 0.07 ± 0.02 | 0.16 ± 0.05 | | 0.12 ± 0.04
Basophils (10^3^/μL)
Day 3 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.00 | | 0.02 ± 0.00 | 0.01 ± 0.00 | | 0.02 ± 0.00
Day 23 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | | 0.01 ± 0.00 | 0.01 ± 0.00 | | 0.02 ± 0.01
Week 14 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | | 0.01 ± 0.00 | 0.01 ± 0.00 | | 0.02 ± 0.00
Eosinophils (10^3^/μL)
Day 3 | 0.14 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01* | | 0.08 ± 0.01** | 0.13 ± 0.02 | | 0.09 ± 0.01**
Day 23 | 0.15 ± 0.02 | 0.12 ± 0.02 | 0.07 ± 0.01** | | 0.12 ± 0.02 | 0.09 ± 0.02 | | 0.11 ± 0.01
Week 14 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.02 | | 0.11 ± 0.02 | 0.13 ± 0.02 | | 0.12 ± 0.02
n | 10 | 10 | 10 | | 10 | 10 | | 10
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 10.6 ± 1.0 | 9.9 ± 1.0 | 9.6 ± 0.7 | | 10.4 ± 0.8 | 11.2 ± 0.4 | | 8.1 ± 0.6
Day 23 | 14.5 ± 0.9 | 13.5 ± 1.2 | 12.3 ± 0.6 | | 14.1 ± 1.0 | 14.7 ± 0.9 | | 10.4 ± 0.9**
Week 14 | 18.1 ± 1.1 | 18.4 ± 0.7 | 17.1 ± 0.6 | | 19.0 ± 0.7 | 17.5 ± 0.5 | | 18.4 ± 1.8
Creatinine (mg/dL)
Day 3 | 0.28 ± 0.02 | 0.27 ± 0.02 | 0.30 ± 0.01 | | 0.28 ± 0.02 | 0.31 ± 0.02 | | 0.27 ± 0.02
Day 23 | 0.35 ± 0.03 | 0.36 ± 0.02 | 0.38 ± 0.02 | | 0.37 ± 0.03 | 0.38 ± 0.02 | | 0.36 ± 0.02
Week 14 | 0.45 ± 0.02 | 0.46 ± 0.02 | 0.45 ± 0.02 | | 0.45 ± 0.02 | 0.46 ± 0.03 | | 0.40 ± 0.02
Glucose (mg/dL)
Day 3 | 134 ± 4 | 132 ± 3 | 143 ± 5 | | 131 ± 3 | 140 ± 6 | | 135 ± 4
Day 23 | 127 ± 7 | 131 ± 5 | 123 ± 3 | | 125 ± 2 | 128 ± 3 | | 136 ± 6
Week 14 | 138 ± 8 | 142 ± 5 | 132 ± 3 | | 139 ± 9 | 136 ± 3 | | 139 ± 6
Total protein (g/dL)
Day 3 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | | 6.3 ± 0.1 | 6.3 ± 0.1 | | 6.1 ± 0.1
Day 23 | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.6 ± 0.1 | | 6.9 ± 0.1 | 6.7 ± 0.1 | | 6.6 ± 0.1
Week 14 | 7.5 ± 0.1 | 7.5 ± 0.1 | 7.3 ± 0.1 | | 7.4 ± 0.1 | 7.6 ± 0.1 | | 7.4 ± 0.2
Albumin (g/dL)
Day 3 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | | 4.7 ± 0.1 | 4.8 ± 0.0 | | 4.6 ± 0.1
Day 23 | 4.9 ± 0.1 | 4.9 ± 0.1 | 5.0 ± 0.1 | | 5.0 ± 0.0 | 4.9 ± 0.1 | | 4.8 ± 0.1
Week 14 | 5.4 ± 0.1 | 5.4 ± 0.1 | 5.3 ± 0.1 | | 5.3 ± 0.1 | 5.3 ± 0.1 | | 5.1 ± 0.2
Globulin (g/dL)
Day 3 | 1.6 ± 0.1 | 1.6 ± 0.0 | 1.4 ± 0.1 | | 1.5 ± 0.0 | 1.6 ± 0.1 | | 1.5 ± 0.0
Day 23 | 1.8 ± 0.1 | 1.8 ± 0.1 | 1.7 ± 0.1 | | 1.9 ± 0.1 | 1.8 ± 0.1 | | 1.8 ± 0.1
Week 14 | 2.1 ± 0.1 | 2.1 ± 0.1 | 2.0 ± 0.1 | | 2.1 ± 0.0 | 2.3 ± 0.1 | | 2.3 ± 0.1
Albumin/globulin ratio
Day 3 | 3.0 ± 0.1 | 3.0 ± 0.1 | 3.3 ± 0.1 | | 3.1 ± 0.1 | 3.1 ± 0.1 | | 3.2 ± 0.1
Day 23 | 2.8 ± 0.1 | 2.8 ± 0.1 | 3.0 ± 0.1 | | 2.7 ± 0.1 | 2.8 ± 0.1 | | 2.8 ± 0.1
Week 14 | 2.6 ± 0.1 | 2.6 ± 0.1 | 2.7 ± 0.1 | | 2.5 ± 0.1 | 2.4 ± 0.1 | | 2.3 ± 0.1
Cholesterol (mg/dL)
Day 3 | 78 ± 3 | 81 ± 5 | 79 ± 5 | | 73 ± 4 | 74 ± 3 | | 74 ± 5
Day 23 | 65 ± 3 | 68 ± 5 | 66 ± 4 | | 63 ± 4 | 63 ± 3 | | 70 ± 5
Week 14 | 66 ± 4 | 62 ± 2 | 60 ± 2 | | 62 ± 3 | 62 ± 4 | | 55 ± 7
Triglycerides (mg/dL)
Day 3 | 61 ± 4 | 63 ± 4 | 53 ± 4 | | 55 ± 4 | 61 ± 6 | | 43 ± 3*
Day 23 | 55 ± 7 | 52 ± 3 | 59 ± 6 | | 76 ± 16 | 57 ± 7 | | 55 ± 4
Week 14 | 50 ± 5 | 57 ± 6 | 45 ± 4 | | 56 ± 4 | 55 ± 5 | | 60 ± 10
Alanine aminotransferase (IU/L)
Day 3 | 29 ± 2 | 31 ± 1 | 34 ± 2 | | 31 ± 2 | 34 ± 2 | | 30 ± 2
Day 23 | 29 ± 4 | 28 ± 2 | 28 ± 2 | | 25 ± 2 | 26 ± 2 | | 25 ± 2
Week 14 | 36 ± 3 | 28 ± 2 | 32 ± 4 | | 35 ± 4 | 34 ± 2 | | 34 ± 3
Alkaline phosphatase (IU/L)
Day 3 | 181 ± 9 | 193 ± 13 | 197 ± 16 | | 159 ± 14 | 167 ± 10 | | 168 ± 9
Day 23 | 100 ± 7 | 104 ± 8 | 114 ± 9 | | 87 ± 7 | 97 ± 7 | | 107 ± 7
Week 14 | 73 ± 8 | 74 ± 8 | 62 ± 7 | | 68 ± 8 | 62 ± 8 | | 89 ± 8
Creatine kinase (IU/L)
Day 3 | 337 ± 25 | 340 ± 49 | 323 ± 42 | | 337 ± 41 | 361 ± 46 | | 380 ± 41
Day 23 | 331 ± 44 | 399 ± 75 | 331 ± 38 | | 319 ± 31 | 328 ± 24 | | 351 ± 29
Week 14 | 198 ± 18 | 271 ± 44 | 192 ± 25 | | 341 ± 148 | 281 ± 48 | | 251 ± 34
Sorbitol dehydrogenase (IU/L)
Day 3 | 13 ± 1 | 14 ± 1 | 14 ± 1 | | 13 ± 0 | 14 ± 1 | | 13 ± 1
Day 23 | 13 ± 1 | 12 ± 1 | 15 ± 1 | | 15 ± 1 | 16 ± 1 | | 15 ± 1
Week 14 | 14 ± 1 | 12 ± 1 | 13 ± 1 | | 13 ± 1 | 12 ± 1 | | 11 ± 1
Bile acids (µmol/L)
Day 3 | 16.3 ± 1.9 | 12.9 ± 1.8 | 18.5 ± 4.1 | | 13.0 ± 1.7 | 23.6 ± 6.7 | | 14.5 ± 2.8
Day 23 | 29.6 ± 8.0 | 14.9 ± 2.3 | 15.2 ± 2.6 | | 19.0 ± 3.9 | 15.2 ± 2.6 | | 12.5 ± 3.3*
Week 14 | 7.9 ± 2.0 | 6.9 ± 2.1 | 4.7 ± 0.7 | | 14.3 ± 7.0 | 4.7 ± 0.7 | | 11.5 ± 3.3

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

Table F-2 Hematology Data for Mice in the Three-month Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 49.4 ± 0.4 | 50.0 ± 0.4 | 50.0 ± 0.4 | 49.5 ± 0.4 | 49.1 ± 0.5 | 48.8 ± 0.4
Packed cell volume (%) | 50.3 ± 0.4 | 51.1 ± 0.3 | 50.8 ± 0.4 | 50.6 ± 0.3 | 49.8 ± 0.5 | 49.2 ± 0.4
Hemoglobin (g/dL) | 15.6 ± 0.1 | 15.8 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.1 | 15.5 ± 0.2 | 15.4 ± 0.1
Erythrocytes (10^6^/µL) | 10.33 ± 0.07 | 10.59 ± 0.06 | 10.38 ± 0.11 | 10.38 ± 0.07 | 10.42 ± 0.10 | 10.57 ± 0.08
Reticulocytes (10^6^/µL) | 286.1 ± 15.5 | 277.8 ± 13.3 | 277.4 ± 11.8 | 275.2 ± 11.7 | 275.8 ± 12.6 | 284.3 ± 10.5
Reticulocytes/1,000 erythrocytes | 27.70 ± 1.51 | 26.20 ± 1.18 | 26.70 ± 1.10 | 26.50 ± 1.10 | 26.50 ± 1.22 | 26.90 ± 0.96
Nucleated erythrocytes (10^3^/µL) | 3.13 ± 0.30 | 3.05 ± 0.31 | 2.95 ± 0.18 | 3.03 ± 0.15 | 4.16 ± 0.76 | 3.67 ± 0.22
Nucleated erythrocytes /100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.1 ± 0.0* | 0.1 ± 0.0** | 0.1 ± 0.0** | 0.1 ± 0.0 | 0.1 ± 0.0*
Mean cell volume (fL) | 48.7 ± 0.2 | 48.3 ± 0.3 | 48.9 ± 0.3 | 48.8 ± 0.1 | 47.8 ± 0.3* | 46.6 ± 0.3**
Mean cell hemoglobin (pg) | 15.1 ± 0.1 | 14.9 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1* | 14.6 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 31.1 ± 0.1 | 30.9 ± 0.1 | 30.9 ± 0.1 | 30.9 ± 0.1 | 31.1 ± 0.1 | 31.4 ± 0.1
Platelets (10^3^/µL) | 859 ± 11 | 856 ± 16 | 877 ± 16 | 874 ± 12 | 913 ± 33 | 925 ± 22*
Leukocytes (10^3^/µL) | 3.13 ± 0.30 | 3.05 ± 0.31 | 2.95 ± 0.18 | 3.03 ± 0.15 | 4.16 ± 0.76 | 3.67 ± 0.22
Segmented neutrophils (10^3^/µL) | 0.42 ± 0.05 | 0.38 ± 0.03 | 0.42 ± 0.06 | 0.42 ± 0.03 | 1.22 ± 0.57* | 0.96 ± 0.20**
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.61 ± 0.24 | 2.57 ± 0.29 | 2.40 ± 0.15 | 2.47 ± 0.15 | 2.79 ± 0.26 | 2.57 ± 0.11
Monocytes (10^3^/µL) | 0.05 ± 0.02 | 0.05 ± 0.02 | 0.07 ± 0.02 | 0.08 ± 0.02 | 0.06 ± 0.02 | 0.07 ± 0.02
Basophils (10^3^/µL) | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.00
Eosinophils (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.08 ± 0.01 | 0.06 ± 0.01
Female
Hematocrit (%) | 49.4 ± 0.3 | 49.7 ± 0.3 | 50.6 ± 0.4 | 49.7 ± 0.4 | 49.2 ± 0.4 | 48.8 ± 0.4
Packed cell volume (%) | 50.3 ± 0.5 | 50.5 ± 0.3 | 51.0 ± 0.4 | 50.6 ± 0.5 | 49.5 ± 0.3 | 49.3 ± 0.4
Hemoglobin (g/dL) | 15.8 ± 0.2 | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 15.6 ± 0.1 | 15.5 ± 0.1
Erythrocytes (10^6^/µL) | 10.25 ± 0.10 | 10.28 ± 0.06 | 10.39 ± 0.09 | 10.30 ± 0.10 | 10.20 ± 0.07 | 10.43 ± 0.07
Reticulocytes (10^6^/µL) | 260.7 ± 11.6 | 269.6 ± 9.9 | 256.7 ± 8.1 | 262.5 ± 10.1 | 263.2 ± 5.0 | 270.3 ± 9.1
Reticulocytes/1,000 erythrocytes | 25.40 ± 1.01 | 26.20 ± 0.92 | 24.70 ± 0.75 | 25.50 ± 1.02 | 25.80 ± 0.47 | 25.90 ± 0.85
Nucleated erythrocytes (10^3^/µL) | 3.92 ± 0.53 | 3.79 ± 0.30 | 3.60 ± 0.28 | 4.80 ± 0.47 | 3.86 ± 0.32 | 3.86 ± 0.40
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.1 ± 0.0* | 0.1 ± 0.0* | 0.1 ± 0.0 | 0.1 ± 0.0* | 0.1 ± 0.0
Mean cell volume (fL) | 49.0 ± 0.2 | 49.1 ± 0.1 | 49.2 ± 0.2 | 49.1 ± 0.2 | 48.6 ± 0.1 | 47.2 ± 0.2**
Mean cell hemoglobin (pg) | 15.4 ± 0.1 | 15.4 ± 0.0 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.0 | 14.8 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 31.4 ± 0.1 | 31.4 ± 0.1 | 31.3 ± 0.1 | 31.4 ± 0.2 | 31.5 ± 0.1 | 31.4 ± 0.2
Platelets (10^3^/µL) | 799 ± 19 | 808 ± 9 | 850 ± 9 | 786 ± 25 | 861 ± 16* | 889 ± 26**
Leukocytes (10^3^/µL) | 3.92 ± 0.53 | 3.79 ± 0.30 | 3.60 ± 0.28 | 4.80 ± 0.47 | 3.86 ± 0.32 | 3.86 ± 0.40
Segmented neutrophils (10^3^/µL) | 0.53 ± 0.08 | 0.47 ± 0.06 | 0.42 ± 0.06 | 0.59 ± 0.08 | 0.79 ± 0.16 | 1.04 ± 0.19*
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 3.29 ± 0.48 | 3.22 ± 0.24 | 3.08 ± 0.23 | 4.08 ± 0.41 | 2.91 ± 0.21 | 2.65 ± 0.27
Monocytes (10^3^/µL) | 0.06 ± 0.02 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.06 ± 0.02 | 0.09 ± 0.02 | 0.09 ± 0.02
Basophils (10^3^/µL) | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.02
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.