# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

2,3-Butanedione was tested in two independent bacterial gene mutation assays. In the first assay, testing procedures followed protocols reported by Zeiger et al.^157^. Briefly, a commercially obtained sample of 2,3-butanedione was sent to the laboratory under code. It was incubated with each of the Salmonella typhimurium tester strains (TA97, TA98, TA100, TA1535) either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

In the second assay, a sample of the same lot of 2,3-butanedione that was used in the 2-year bioassays was sent to the testing laboratory for assessment of mutagenicity in S. typhimurium strains TA100, TA97a, and TA98 and in Escherichia coli strain WP2 uvrA/pKM101. Incubation in either buffer or S9 mix (from induced Sprague Dawley rat liver) and plating on minimal glucose agar plates was carried out as described above. Histidine-independent (S. typhimurium strains) or tryptophan-independent (E. coli strain) mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

For all strains, each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of 2,3-butanedione. The high dose was limited by toxicity to 1,666 µg/plate in the first assay and 2,000 µg/plate in the second assay.

In these assays, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Bone Marrow Micronucleus Test Protocol

Published LD_50_ information was used to select the range of doses employed. The high dose was set at two times the stated LD__50__, and six additional lower doses were tested, for a total of seven treated groups. The standard three-exposure protocol is described in detail by Shelby et al.^107^. Male B6C3F1/N mice were injected intraperitoneally (three times at 24-hour intervals) with 2,3-butanedione dissolved in phosphate buffered saline. Vehicle control animals were injected with phosphate buffered saline only. The positive control animals received injections of 15 mg/kg cyclophosphamide. The animals were euthanized 24 hours after the third injection, and blood smears were prepared from bone marrow cells obtained from the femurs. Air-dried smears were fixed and stained; 2,000 polychromatic erythrocytes (PCEs; reticulocytes) were scored for the frequency of micronucleated cells in each of five mice per dose group. In addition, the percentage of PCEs among the total erythrocyte population in the bone marrow was scored for each dose group as a measure of toxicity. There was no lethality in any of the seven treatment groups, but animals in the 500 mg/kg group showed clinical signs of toxicity, indicating that the maximum tolerated dose had been tested.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among PCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Rat and Mouse Peripheral Blood Micronucleus Test Protocol

The procedures used for the rat and mouse peripheral blood micronucleus assay have been described in detail.^158-160^. Briefly, at the termination of the 3-month studies, one to two drops of blood from five male and five female rats and mice exposed to 0 to 100 ppm 2,3-butanedione were collected in microtubes with EDTA and shipped on cool packs to the genetic toxicity testing laboratory for processing and fixation in ultracold methanol, as per procedures described in the MicroFlow^PLUS^ Kit for mouse or rat blood samples (Litron Laboratories, Rochester, NY). A FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA) was used to analyze of the samples. PCEs were identified by the presence of an active transferrin receptor (CD71+) on the cell surface and normochromatic erythrocytes (NCEs; mature erythrocytes) were CD71–. For the rat samples, only PCEs with the highest CD71 activity were evaluated due to the speed and efficiency with which the rat spleen removes damaged PCEs from circulation. Thus, although micronucleus frequency was evaluated in both PCEs and NCEs, the appropriate cell population for this assessment in rats is the young PCE population. Micronuclei were detected using propidium iodide (a DNA stain) in conjunction with RNase treatment. Approximately 1 × 10^6^ NCEs (CD71–), and 20,000 PCEs (CD71+) were evaluated per animal for the presence of micronuclei (propidium iodide-associated fluorescence). In addition, for each blood sample, the percentage of PCEs in 1 × 10^6^ erythrocytes was determined as a measure of 2,3-butanedione-associated bone marrow toxicity.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques^161^, it is reasonable to assume that the proportion of micronucleated cells is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025. In the micronucleus assay, a positive response is preferably based on the observation of both a significant trend as well an observation of at least one dose group significantly elevated over the concurrent control group. If only one statistical test (trend or pairwise) is significant, the micronucleus assay is judged to be equivocal. The absence of both a significant trend and a significant dose results in a negative call for the assay. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

## E.4 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.5 Results

2,3-Butanedione was tested in bacterial reverse mutation assays, an acute-exposure mouse bone marrow micronucleus test, and subchronic exposure peripheral blood micronucleus tests. 2,3-Butanedione was mutagenic in both the bacterial mutagenicity assays, with and without S9 mix.

In the first bacterial mutation assay (Table E-1), a weak positive response (less than twofold increase in revertants, but a clear, reproducible, dose-related increase that approached the twofold level) was observed in S. typhimurium strain TA97 in the absence of S9 mix and in the presence of 10% and 30% induced hamster and rat liver S9 mixes. The dose range over which the response was observed in TA97 ranged from 10 to 333 µg/plate. No mutagenic responses were observed in any other strain, although some trials were concluded to demonstrate an equivocal response. These equivocal responses were not easily replicated, unlike the weak positive responses seen in strain TA97.

In the second bacterial mutation assay (Table E-2), conducted with the same lot of 2,3-butanedione that was used in the 2-year rodent bioassay, a positive response was seen in S. typhimurium strain TA97a in the absence of exogenous metabolic activation (10% induced rat liver S9 mix), and a response that was equivocal was seen with metabolic activation. In the E. coli strain (WP2 uvrA pKM101) that was included in this second assay, clearly positive responses were seen in all trials conducted with and without S9 mix, suggesting that 2,3-butanedione is a direct-acting mutagen that is not detoxified by induced rat liver S9. The E. coli strain reverts via base substitution at the tryptophan locus at an AT base pair. Equivocal results were obtained in S. typhimurium strain TA100, with and without S9, and no mutagenicity was observed with strain TA98, with and without S9.

In an acute micronucleus test conducted in male mice, the frequency of micronucleated PCEs was measured in bone marrow following intraperitoneal injection of 2,3-butanedione once daily for 3 days (Table E-3). In this test, no increases in micronucleated PCEs were observed over the dose range of 7.812 to 500 mg 2,3-butanedione/kg body weight per day.

At the end of the 3-month studies, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated PCEs and NCEs (Table E-4 and Table E-5). In these studies, no increases in the frequencies of PCEs or NCEs occurred in either sex or species exposed to 2,3-butanedione. The percentage of PCEs among circulating red blood cells was unaffected by exposure to 2,3-butanedione, suggesting the chemical had no effect on erythropoiesis.

Table E-1 Mutagenicity of 2,3-Butanedione in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 5% Hamster S9 | With 5% Hamster S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 30% Hamster S9 | With 5% Rat S9 | With 5% Rat S9 | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9 | With 30% Rat S9
TA100 | 0 | 139 ± 5 | | 109 ± 9 | 167 ± 16 | 95 ± 2 | 159 ± 4 | 135 ± 6 | 104 ± 6 | 100 ± 7 | 162 ± 6 | 103 ± 13 | 169 ± 8 | 125 ± 12 | 110 ± 16
| 10 | 138 ± 2 | | | 158 ± 5 | | 159 ± 0 | | | | 156 ± 1 | | 157 ± 5
| 33 | 131 ± 7 | | 113 ± 9 | 161 ± 3 | 104 ± 6 | 164 ± 3 | | 103 ± 7 | 105 ± 0 | 168 ± 6 | 98 ± 4 | 170 ± 7 | | 113 ± 2
| 66 | | | 113 ± 6 | 163 ± 8 | 123 ± 4 | 168 ± 5 | | 100 ± 8 | 119 ± 6 | 148 ± 0 | 101 ± 1 | 168 ± 6 | | 117 ± 4
| 100 | 138 ± 7 | | 129 ± 8 | 157 ± 1 | 111 ± 7 | 167 ± 8 | 164 ± 7 | 95 ± 5 | 102 ± 2 | 155 ± 7 | 107 ± 11 | 165 ± 4 | 166 ± 8 | 117 ± 2
| 166 | | | 139 ± 4 | 167 ± 10 | 111 ± 12 | 155 ± 6 | | 107 ± 10 | 126 ± 9 | 167 ± 5 | 95 ± 8 | 156 ± 8 | | 133 ± 6
| 333 | 120 ± 9^b^ | | 156 ± 8 | 118 ± 6 | 145 ± 11 | 131 ± 9 | 179 ± 13 | 111 ± 8 | 142 ± 4 | 131 ± 2 | 139 ± 1 | 152 ± 10 | 195 ± 6 | 139 ± 2
| 666 | 79 ± 18^b^ | | | | | | 137 ± 4 | | | | | | 95 ± 3
| 1,000 | | | | | | | 77 ± 5^b^ | | | | | | 95 ± 3
| 1,666 | | | | | | | 0^c^ | | | | | | 0^c^
Trial summary | | Negative | | Equivocal | Negative | Equivocal | Negative | Equivocal | Negative | Equivocal | Negative | Equivocal | Negative | Equivocal | Equivocal
Positive control^d^ | | 905 ± 20 | | 819 ± 17 | 760 ± 68 | 560 ± 3 | 550 ± 23 | 508 ± 8 | 548 ± 11 | 919 ± 56 | 728 ± 49 | 811 ± 39 | 647 ± 30 | 394 ± 38 | 673 ± 41
TA97 | 0 | 138 ± 4 | 147 ± 9 | 161 ± 4 | | 165 ± 7 | | 167 ± 4 | 174 ± 8 | 158 ± 5 | | 181 ± 3 | | 200 ± 11 | 167 ± 4
| 10 | 162 ± 6 | 175 ± 14 | 183 ± 5 | | 156 ± 7 | | 169 ± 11 | 182 ± 4 | 201 ± 6 | | 171 ± 12 | | 226 ± 6 | 176 ± 3
| 33 | 187 ± 6 | 181 ± 4 | 209 ± 10 | | 188 ± 1 | | 178 ± 10 | 206 ± 7 | 221 ± 14 | | 208 ± 4 | | 254 ± 7 | 206 ± 10
| 100 | 205 ± 9 | 227 ± 7 | 213 ± 1 | | 212 ± 8 | | 226 ± 14 | 250 ± 5 | 269 ± 16 | | 235 ± 9 | | 284 ± 19 | 227 ± 40
| 333 | 237 ± 13 | 235 ± 8 | 211 ± 8 | | 268 ± 16 | | 270 ± 7 | 274 ± 4 | 284 ± 4 | | 267 ± 5 | | 282 ± 9 | 288 ± 1
| 666 | 34 ± 16^c^ | 155 ± 18^c^ | 60 ± 17^b^ | | 61 ± 12^b^ | | | 145 ± 22^b^ | 87 ± 12^b^ | | 226 ± 18^b^ | | | 166 ± 24^b^
| 1,000 | | | | | | | 50 ± 5^c^ | | | | | | 40 ± 17^b^
Trial summary | | Weakly positive | Weakly positive | Equivocal | | Weakly positive | | Weakly positive | Weakly positive | Weakly positive | | Weakly positive | | Weakly positive | Weakly positive
Positive control | | 487 ± 28 | 512 ± 8 | 701 ± 8 | | 655 ± 11 | | 690 ± 25 | 589 ± 23 | 620 ± 21 | | 630 ± 15 | | 628 ± 11 | 548 ± 18
TA98 | 0 | 25 ± 7 | | | | | | 20 ± 3 | | | | | | 23 ± 3
| 10 | 25 ± 4
| 33 | 22 ± 2
| 100 | 23 ± 4 | | | | | | 24 ± 6 | | | | | | 22 ± 1
| 333 | 20 ± 1 | | | | | | 21 ± 4 | | | | | | 23 ± 3
| 666 | 9 ± 5^b^ | | | | | | 19 ± 2 | | | | | | 18 ± 3
| 1,000 | | | | | | | 14 ± 3^b^ | | | | | | 14 ± 3^b^
| 1,666 | | | | | | | 0^c^ | | | | | | 0^c^
Trial summary | | Negative | | | | | | Negative | | | | | | Negative
Positive control | | 394 ± 13 | | | | | | 661 ± 32 | | | | | | 495 ± 11
TA1535 | 0 | 19 ± 0 | | 10 ± 1 | | 12 ± 1 | | 15 ± 1 | | 10 ± 1 | | 13 ± 3 | | 15 ± 1
| 10 | 16 ± 1 | | 9 ± 1 | | 12 ± 2 | | | | 9 ± 0 | | 11 ± 1
| 33 | 11 ± 1 | | 9 ± 0 | | 9 ± 1 | | 12 ± 4 | | 10 ± 1 | | 11 ± 2 | | 16 ± 1
| 66 | | | 8 ± 1 | | 12 ± 1 | | 13 ± 3 | | 11 ± 1 | | 11 ± 0 | | 13 ± 3
| 100 | 13 ± 3 | | 9 ± 1 | | 12 ± 2 | | 10 ± 1 | | 9 ± 1 | | 8 ± 0 | | 14 ± 1
| 166 | | | 8 ± 1 | | 10 ± 2 | | 11 ± 2 | | 10 ± 1 | | 10 ± 1 | | 13 ± 3
| 333 | 8 ± 1 | | 11 ± 2 | | | | 13 ± 0 | | 7 ± 2 | | 6 ± 1 | | 20 ± 3
| 666 | 10 ± 2
Trial summary | | Negative | | Negative | | Negative | | Negative | | Negative | | Negative | | Negative
Positive control | | 887 ± 36 | | 347 ± 25 | | 247 ± 20 | | 264 ± 8 | | 314 ± 12 | | 130 ± 8 | | 210 ± 18

^a^ Study was performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by.^157^ 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ Slight toxicity and precipate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Mutagenicity of 2,3-Butanedione in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100 | 0 | 109 ± 7 | 93 ± 7 | 130 ± 13 | 92 ± 13
| 100 | 134 ± 15 | 106 ± 14 | 137 ± 4 | 101 ± 6
| 200 | 165 ± 18 | 152 ± 26
| 250 | | | 164 ± 12 | 137 ± 15
| 300 | 156 ± 5 | 144 ± 2
| 500 | 91 ± 9^b^ | 69 ± 11^b^ | 160 ± 10 | 176 ± 26
| 750 | 2 ± 1^b^ | Toxic | 72 ± 21^b^ | 122 ± 19^b^
| 1,000 | Toxic | Toxic | 18 ± 4^b^ | 49 ± 11^b^
| 2,000 | | | Toxic | Toxic
Trial summary | | Equivocal | Equivocal | Negative | Weakly positive
Positive control^c^ | | 590 ± 61 | 677 ± 63 | 665 ± 94 | 543 ± 35
TA97^a^ | 0 | 126 ± 26 | 102 ± 14 | 150 ± 8 | 127 ± 13
| 100 | 145 ± 16 | 172 ± 26 | 155 ± 13 | 165 ± 11
| 200 | 183 ± 22 | 148 ± 10
| 250 | | | 190 ± 31 | 195 ± 12
| 300 | 212 ± 11 | 206 ± 20
| 500 | 170 ± 26^b^ | 164 ± 32 | 250 ± 18 | 197 ± 11
| 750 | 166 ± 9^b^ | 123 ± 19^b^ | 164 ± 5^b^ | 100 ± 9^b^
| 1,000 | 148 ± 9^b^ | 61 ± 22^b^ | 9 ± 2^b^ | 13 ± 10^b^
| 2,000 | | | Toxic | Toxic
Trial summary | | Positive | Positive | Weakly Positive | Equivocal
Positive control | | 1,689 ± 54 | 2,207 ± 297 | 3,181 ± 499 | 2,082 ± 256
TA98 | 0 | 14 ± 4 | 17 ± 6 | 20 ± 5 | 21 ± 8
| 100 | 17 ± 4 | 27 ± 4 | 19 ± 4 | 26 ± 10
| 200 | 18 ± 0 | 20 ± 4
| 250 | | | 22 ± 8 | 26 ± 5
| 300 | 16 ± 3 | 24 ± 5
| 500 | 18 ± 3 | 19 ± 3 | 15 ± 5 | 23 ± 4
| 750 | 9 ± 2^b^ | 9 ± 6^b^ | 14 ± 1^b^ | 13 ± 6^b^
| 1,000 | 3 ± 2^b^ | 6 ± 1^b^ | 2 ± 1^b^ | 7 ± 2^b^
| 2,000 | | | Toxic | Toxic
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 609 ± 64 | 596 ± 77 | 811 ± 73 | 1,385 ± 139
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 141 ± 5 | 128 ± 14 | 175 ± 20 | 140 ± 4
| 100 | 218 ± 22 | 206 ± 31 | 263 ± 32 | 280 ± 11
| 200 | 279 ± 21 | 220 ± 40
| 250 | | | 319 ± 23 | 270 ± 26
| 300 | 275 ± 24 | 260 ± 11
| 500 | 271 ± 57 | 278 ± 40 | 346 ± 38 | 298 ± 43
| 750 | 165 ± 39^b^ | 98 ± 27^b^ | 342 ± 20 | 275 ± 23
| 1,000 | 113 ± 32^b^ | 13 ± 3^b^ | 196 ± 57^b^ | 179 ± 14^b^
| 2,000 | | | Toxic | 11 ± 4^b^
Trial summary | | Positive | Positive | Positive | Positive
Positive control | | 2,111 ± 228 | 1,566 ± 137 | 1,063 ± 120 | 1,037 ± 58

^a^ Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard deviation) from three plates. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), ICR191 (TA97a), 2-nitrofluorene (TA98), and 4-nitroquinoline-N-oxide (E. coli). The positive control for metabolic activation was 2-aminoanthracene (TA97a, TA98, E. coli) or benzo[a]pyrene (TA100).

Table E-3 Induction of Micronuclei in Bone Marrow Polychromatic Erythrocytes of Male Mice Treated with 2,3-Butanedione by Intraperitoneal Injection for Three Days^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%)
Phosphate buffered saline^d^ | 0 | 5 | 2.1 ± 0.29 | | 45.50 ± 0.00
2,3-Butanedione | 7.812 | 5 | 0.9 ± 0.33 | 0.9858 | 59.58 ± 0.82
| 15.625 | 5 | 0.7 ± 0.30 | 0.9959 | 56.30 ± 2.43
| 31.25 | 5 | 1.5 ± 0.45 | 0.8416 | 63.60 ± 1.94
| 62.5 | 5 | 0.9 ± 0.19 | 0.9858 | 62.88 ± 1.97
| 125 | 5 | 0.7 ± 0.25 | 0.9959 | 58.32 ± 2.50
| 250 | 5 | 0.7 ± 0.20 | 0.9959 | 58.88 ± 1.87
| 500 | 5 | 1.6 ± 0.29 | 0.7947 | 63.32 ± 1.54
| | | P = 0.361^e^
Cyclophosphamide^f^ | 15 | 5 | 9.9 ± 1.18 | 0.0000 | 56.12 ± 1.26

^a^ Study was performed at Environmental Health Research and Testing, Inc. (Lexington, KY). The detailed protocol is presented by Shelby et al.^107^. PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.0036; positive control values are significant at P ≤ 0.05.

^d^ Vehicle control.

^e^ Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed trend test; significant at P ≤ 0.025.

^f^ Positive control.

Table E-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Treatment with 2,3-Butanedione by Inhalation for Three Months^a^

| Exposure Concentration (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 1.08 ± 0.14 | | 0.13 ± 0.05 | | 0.765 ± 0.09
2,3-Butanedione
| 6.25 | 5 | 0.79 ± 0.07 | 1.0000 | 0.08 ± 0.01 | 0.7622 | 0.737 ± 0.05 | 1.0000
| 12.5 | 5 | 0.84 ± 0.19 | 1.0000 | 0.08 ± 0.01 | 0.8413 | 0.875 ± 0.04 | 0.4453
| 25 | 5 | 0.98 ± 0.12 | 1.0000 | 0.09 ± 0.02 | 0.8700 | 0.895 ± 0.10 | 0.4764
| 50 | 5 | 0.87 ± 0.07 | 1.0000 | 0.19 ± 0.07 | 0.4934 | 0.823 ± 0.06 | 0.4900
| 100 | 5 | 0.79 ± 0.04 | 1.0000 | 0.11 ± 0.03 | 0.5034 | 0.828 ± 0.09 | 0.4994
| | | P = 0.809^e^ | | P = 0.236 | | P = 0.641
Female
Air | 0 | 5 | 1.13 ± 0.23 | | 0.17 ± 0.04 | | 1.072 ± 0.14
2,3-Butanedione
| 6.25 | 5 | 0.91 ± 0.09 | 1.0000 | 0.09 ± 0.02 | 0.7364 | 0.977 ± 0.06 | 1.0000
| 12.5 | 5 | 0.95 ± 0.17 | 1.0000 | 0.21 ± 0.06 | 0.6615 | 0.961 ± 0.10 | 1.0000
| 25 | 5 | 0.75 ± 0.14 | 1.0000 | 0.16 ± 0.04 | 0.6958 | 1.091 ± 0.15 | 1.0000
| 50 | 5 | 1.01 ± 0.05 | 1.0000 | 0.11 ± 0.01 | 0.7147 | 0.936 ± 0.07 | 1.0000
| 100 | 5 | 1.31 ± 0.26 | 0.8488 | 0.26 ± 0.06 | 0.0990 | 0.774 ± 0.18 | 1.0000
| | | P = 0.158 | | P = 0.054 | | P = 0.319

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.^160^, MacGregor et al.^159^, and Witt et al.^158^. NCE=normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s or Williams’ test.

^d^ Chamber control.

^e^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table E-5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with 2,3-Butanedione by Inhalation for Three Months^a^

| Exposure Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 2.42 ± 0.08 | | 1.45 ± 0.03 | | 1.442 ± 0.06
2,3-Butanedione
| 6.25 | 5 | 2.58 ± 0.15 | 0.3212 | 1.50 ± 0.04 | 0.5605 | 1.540 ± 0.10 | 0.8501
| 12.5 | 5 | 2.48 ± 0.13 | 0.3836 | 1.42 ± 0.02 | 0.6452 | 1.486 ± 0.06 | 0.9499
| 25 | 5 | 2.53 ± 0.15 | 0.4091 | 1.47 ± 0.04 | 0.6794 | 1.495 ± 0.05 | 0.9751
| 50 | 5 | 2.71 ± 0.25 | 0.3145 | 1.45 ± 0.05 | 0.6985 | 1.441 ± 0.20 | 0.9852
| 100 | 5 | 2.47 ± 0.18 | 0.3231 | 1.37 ± 0.05 | 0.7120 | 1.547 ± 0.10 | 0.7518
| | | P = 0.431^e^ | | P = 0.979 | | P = 0.848
Female
Air | 0 | 5 | 2.20 ± 0.33 | | 1.08 ± 0.02 | | 1.414 ± 0.15
2,3-Butanedione
| 6.25 | 5 | 1.82 ± 0.13 | 1.0000 | 1.04 ± 0.03 | 0.8395 | 1.342 ± 0.12 | 1.0000
| 12.5 | 5 | 2.06 ± 0.14 | 1.0000 | 1.11 ± 0.02 | 0.9049 | 1.401 ± 0.12 | 1.0000
| 25 | 5 | 2.05 ± 0.19 | 1.0000 | 1.05 ± 0.03 | 0.9248 | 1.332 ± 0.09 | 1.0000
| 50 | 5 | 2.00 ± 0.08 | 1.0000 | 1.04 ± 0.02 | 0.9357 | 1.472 ± 0.16 | 0.9074
| 100 | 5 | 1.65 ± 0.11 | 1.0000 | 0.92 ± 0.03 | 0.9420 | 1.627 ± 0.07 | 0.2558
| | | P = 0.813 | | P = 1.000 | | P = 0.062

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al^160^, MacGregor et al.^159^, and Witt et al.^158^. NCE=normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s or Williams’ test.

^d^ Chamber control.

^e^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.