# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of 2,3-Butanedione

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 10 | 6 | 4 | 15
Natural deaths | 4 | 4 | 4 | 17
Survivors
Died last week of study | – | – | – | 1
Terminal euthanasia | 36 | 40 | 42 | 17
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (42) | (45) | (45) | (37)
Hemangiosarcoma, metastatic, liver | – | 1 (2%) | – | –
Intestine large, cecum | (47) | (49) | (50) | (41)
Intestine large, colon | (47) | (49) | (50) | (46)
Intestine large, rectum | (49) | (49) | (46) | (43)
Intestine small, duodenum | (47) | (48) | (49) | (38)
Polyp adenomatous | – | – | 1 (2%) | –
Intestine small, ileum | (47) | (48) | (49) | (39)
Intestine small, jejunum | (46) | (49) | (49) | (39)
Liver | (50) | (50) | (50) | (50)
Granulosa-theca tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Hemangiosarcoma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Hepatoblastoma | 1 (2%) | 1 (2%) | – | –
Hepatocellular adenoma | 4 (8%) | 10 (20%) | 7 (14%) | 2 (4%)
Hepatocellular adenoma, multiple | 2 (4%) | 1 (2%) | – | 1 (2%)
Hepatocellular carcinoma | 4 (8%) | 4 (8%) | 3 (6%) | –
Hepatocellular carcinoma, multiple | 1 (2%) | 1 (2%) | – | –
Mesentery | (6) | (10) | (4) | (1)
Hemangiosarcoma, metastatic, skeletal muscle | – | – | – | 1 (100%)
Hepatoblastoma, metastatic, liver | 1 (17%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | – | 1 (10%) | – | –
Pancreas | (50) | (50) | (50) | (47)
Granulosa-theca tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Salivary glands | (49) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (49)
Granulosa-theca tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Squamous cell papilloma | – | 1 (2%) | – | –
Stomach, glandular | (49) | (50) | (50) | (46)
Granulosa-theca tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Capsule, hemangiosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Subcapsular, adenoma | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (49) | (50)
Pheochromocytoma benign | 1 (2%) | – | – | –
Islets, pancreatic | (49) | (50) | (49) | (48)
Parathyroid gland | (38) | (39) | (46) | (46)
Pituitary gland | (49) | (49) | (50) | (48)
Pars distalis, adenoma | 2 (4%) | 4 (8%) | 2 (4%) | –
Pars distalis, carcinoma | – | 1 (2%) | 1 (2%) | –
Pars intermedia, adenoma | – | 1 (2%) | – | 1 (2%)
Pars intermedia, carcinoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (48) | (50)
Carcinoma | – | – | 1 (2%) | –
Follicular cell, adenoma | 1 (2%) | – | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (47) | (49) | (48) | (44)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Ovary | (49) | (50) | (49) | (50)
Cystadenoma | | 2 (4%) | 3 (6%) | –
Granulosa-theca tumor malignant | 1 (2%) | – | – | –
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Luteoma | – | 1 (2%) | 3 (6%) | –
Teratoma benign | – | 1 (2%) | – | –
Periovarian tissue, hemangiosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Periovarian tissue, hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Granular cell tumor benign | – | – | 1 (2%) | –
Hemangioma | – | – | – | 1 (2%)
Polyp stromal | – | 2 (4%) | 2 (4%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (49)
Hemangiosarcoma, metastatic, spleen | – | 1 (2%) | 1 (2%) | –
Lymph node | (11) | (10) | (11) | (7)
Iliac, hepatoblastoma, metastatic, liver | 1 (9%) | – | – | –
Pancreatic, hepatocellular carcinoma, metastatic, liver | – | 1 (10%) | – | –
Lymph node, bronchial | (40) | (42) | (43) | (43)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Lymph node, mandibular | (39) | (47) | (45) | (39)
Carcinoma, metastatic, Harderian gland | 1 (3%) | – | – | –
Lymph node, mediastinal | (40) | (38) | (41) | (33)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | 1 (3%) | – | – | –
Lymph node, mesenteric | (49) | (50) | (50) | (45)
Granulosa-theca tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (48)
Hemangiosarcoma | – | 1 (2%) | 2 (4%) | –
Thymus | (47) | (50) | (49) | (45)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (49) | (50) | (50) | (49)
Adenoma | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | 1 (2%) | – | – | –
Melanoma malignant | – | 1 (2%) | – | –
Neural crest tumor | – | 1 (2%) | – | –
Squamous cell carcinoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibrosarcoma | – | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (6) | (1) | (3) | (4)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (33%) | –
Granulosa-theca tumor malignant, metastatic, ovary | 1 (17%) | – | – | –
Hemangiosarcoma | – | – | – | 1 (25%)
Sarcoma | 1 (17%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pituitary gland | – | 1 (2%) | – | –
Peripheral nerve | (2) | (1) | (2) | (2)
Spinal cord | (2) | (1) | (2) | (2)
Respiratory System
Larynx | (49) | (50) | (50) | (49)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 4 (8%) | 2 (4%) | 1 (2%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | –
Alveolar/bronchiolar carcinoma | 2 (4%) | 1 (2%) | 2 (4%) | –
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | – | – | –
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | – | 2 (4%) | – | –
Nose | (50) | (50) | (50) | (50)
Adenocarcinoma | | | | 2 (4%)
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Pleura | (0) | (0) | (1) | (0)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (100%) | –
Trachea | (50) | (49) | (50) | (50)
Special Senses System
Ear | (0) | (0) | (0) | (1)
Eye | (50) | (49) | (50) | (49)
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | 3 (6%) | 3 (6%) | 2 (4%)
Carcinoma | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (49)
Carcinoma | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (49)
Systemic Lesions
Multiple organsb | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 3 (6%) | – | 1 (2%)
Lymphoma malignant | 9 (18%) | 6 (12%) | 16 (32%) | 4 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 34 | 33 | 34 | 13
Total primary neoplasms | 43 | 53 | 51 | 18
Total animals with benign neoplasms | 15 | 24 | 22 | 6
Total benign neoplasms | 18 | 31 | 25 | 8
Total animals with malignant neoplasms | 24 | 19 | 23 | 9
Total malignant neoplasms | 25 | 21 | 26 | 10
Total animals with metastatic neoplasms | 3 | 6 | 3 | 1
Total metastatic neoplasms | 16 | 8 | 9 | 5
Total animals with uncertain neoplasms benign or malignant | – | 1 | – | –
Total uncertain neoplasms | – | 1 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Harderian Gland: Adenoma
Overall rate^a^ | 3/50 (6%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate^b^ | 6.7% | 6.3% | 6.3% | 6.1%
Terminal rate^c^ | 3/36 (8%) | 3/40 (8%) | 3/42 (7%) | 0/17 (0%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | 547
Poly-3 test^d^ | P = 0.526N | P = 0.636N | P = 0.638N | P = 0.636N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 8.9% | 6.3% | 6.3% | 6.1%
Terminal rate | 3/36 (8%) | 3/40 (8%) | 3/42 (7%) | 0/17 (0%)
First incidence (days) | 690 | 731 (T) | 731 (T) | 547
Poly-3 test | P = 0.387N | P = 0.471N | P = 0.474N | P = 0.488N
Liver: Hepatocellular Adenoma
Overall rate | 6/50 (12%) | 11/50 (22%) | 7/50 (14%) | 3/50 (6%)
Adjusted rate | 13.3% | 23.1% | 14.8% | 9.2%
Terminal rate | 5/36 (14%) | 11/40 (28%) | 7/42 (17%) | 2/17 (12%)
First incidence (days) | 653 | 731 (T) | 731 (T) | 585
Poly-3 test | P = 0.281N | P = 0.168 | P = 0.534 | P = 0.428N
Liver: Hepatocellular Carcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 11.1% | 10.5% | 6.3% | 0.0%
Terminal rate | 5/36 (14%) | 5/40 (13%) | 3/42 (7%) | 0/17 (0%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | –^e^
Poly-3 test | P = 0.047N | P = 0.594N | P = 0.329N | P = 0.073N
Liver: Hepatocellular Adenoma or Hepatocellular Carcinoma
Overall rate | 11/50 (22%) | 15/50 (30%) | 9/50 (18%) | 3/50 (6%)
Adjusted rate | 24.3% | 31.5% | 19.0% | 9.2%
Terminal rate | 10/36 (28%) | 15/40 (38%) | 9/42 (21%) | 2/17 (12%)
First incidence (days) | 653 | 731 (T) | 731 (T) | 585
Poly-3 test | P = 0.044N | P = 0.293 | P = 0.358N | P = 0.083N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 13.2% | 10.5% | 6.3% | 0.0%
Terminal rate | 5/36 (14%) | 5/40 (13%) | 3/42 (7%) | 0/17 (0%)
First incidence (days) | 590 | 731 (T) | 731 (T) | –
Poly-3 test | P = 0.026N | P = 0.468N | P = 0.222N | P = 0.046N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 12/50 (24%) | 15/50 (30%) | 9/50 (18%) | 3/50 (6%)
Adjusted rate | 26.2% | 31.5% | 19.0% | 9.2%
Terminal rate | 10/36 (28%) | 15/40 (38%) | 9/42 (21%) | 2/17 (12%)
First incidence (days) | 590 | 731 (T) | 731 (T) | 585
Poly-3 test | P = 0.030N | P = 0.369 | P = 0.279N | P = 0.058N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 6.7% | 10.5% | 4.2% | 3.1%
Terminal rate | 3/36 (8%) | 5/40 (13%) | 1/42 (2%) | 1/17 (6%)
First incidence (days) | 731 (T) | 731 (T) | 714 | 731 (T)
Poly-3 test | P = 0.229N | P = 0.388 | P = 0.476N | P = 0.435N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 6.6% | 2.1% | 4.2% | 0.0%
Terminal rate | 2/36 (6%) | 0/40 (0%) | 1/42 (2%) | 0/17 (0%)
First incidence (days) | 663 | 697 | 639 | –
Poly-3 test | P = 0.154N | P = 0.286N | P = 0.476N | P = 0.194N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 13.3% | 12.6% | 8.4% | 3.1%
Terminal rate | 5/36 (14%) | 5/40 (13%) | 2/42 (5%) | 1/17 (6%)
First incidence (days) | 663 | 697 | 639 | 731 (T)
Poly-3 test | P = 0.087N | P = 0.582N | P = 0.336N | P = 0.136N
Ovary: Cystadenoma
Overall rate | 0/49 (0%) | 2/50 (4%) | 3/49 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 4.2% | 6.5% | 0.0%
Terminal rate | 0/35 (0%) | 2/40 (5%) | 3/41 (7%) | 0/17 (0%)
First incidence (days) | – | 731 (T) | 731 (T) | –
Poly-3 test | P = 0.465 | P = 0.255 | P = 0.128 | –^f^
Ovary: Luteoma
Overall rate | 0/49 (0%) | 1/50 (2%) | 3/49 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 2.1% | 6.5% | 0.0%
Terminal rate | 0/35 (0%) | 1/40 (3%) | 3/41 (7%) | 0/17 (0%)
First incidence (days) | – | 731 (T) | 731 (T) | –
Poly-3 test | P = 0.390 | P = 0.516 | P = 0.128 | –
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 2/49 (4%) | 4/49 (8%) | 2/50 (4%) | 0/48 (0%)
Adjusted rate | 4.5% | 8.4% | 4.2% | 0.0%
Terminal rate | 1/35 (3%) | 2/39 (5%) | 2/42 (5%) | 0/17 (0%)
First incidence (days) | 663 | 561 | 731 (T) | –
Poly-3 test | P = 0.199N | P = 0.371 | P = 0.669N | P = 0.323N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 2/49 (4%) | 5/49 (10%) | 3/50 (6%) | 0/48 (0%)
Adjusted rate | 4.5% | 10.5% | 6.3% | 0.0%
Terminal rate | 1/35 (3%) | 3/39 (8%) | 3/42 (7%) | 0/17 (0%)
First incidence (days) | 663 | 561 | 731 (T) | –
Poly-3 test | P = 0.235N | P = 0.246 | P = 0.531 | P = 0.323N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 0.0% | 4.2% | 6.3% | 9.0%
Terminal rate | 0/36 (0%) | 1/40 (3%) | 2/42 (5%) | 0/17 (0%)
First incidence (days) | – | 703 | 713 | 547
Poly-3 test | P = 0.049 | P = 0.251 | P = 0.128 | P = 0.074
All Organs: Histiocytic Sarcoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 2.2% | 6.3% | 0.0% | 3.0%
Terminal rate | 0/36 (0%) | 2/40 (5%) | 0/42 (0%) | 0/17 (0%)
First incidence (days) | 499 | 644 | – | 252
Poly-3 test | P = 0.458N | P = 0.323 | P = 0.493N | P = 0.682
All Organs: Malignant Lymphoma
Overall rate | 9/50 (18%) | 6/50 (12%) | 16/50 (32%) | 4/50 (8%)
Adjusted rate | 19.9% | 12.6% | 33.2% | 12.0%
Terminal rate | 7/36 (19%) | 5/40 (13%) | 14/42 (33%) | 1/17 (6%)
First incidence (days) | 687 | 680 | 592 | 325
Poly-3 test | P = 0.527 | P = 0.249N | P = 0.110 | P = 0.268N
All Organs: Benign Neoplasms
Overall rate | 15/50 (30%) | 24/50 (48%) | 22/50 (44%) | 6/50 (12%)
Adjusted rate | 32.7% | 49.1% | 46.1% | 18.2%
Terminal rate | 11/36 (31%) | 20/40 (50%) | 20/42 (48%) | 4/17 (24%)
First incidence (days) | 653 | 561 | 639 | 547
Poly-3 test | P = 0.148N | P = 0.076 | P = 0.130 | P = 0.121N
All Organs: Malignant Neoplasms
Overall rate | 24/50 (48%) | 19/50 (38%) | 23/50 (46%) | 9/50 (18%)
Adjusted rate | 50.7% | 39.2% | 47.3% | 25.6%
Terminal rate | 16/36 (44%) | 14/40 (35%) | 19/42 (45%) | 3/17 (18%)
First incidence (days) | 499 | 644 | 592 | 252
Poly-3 test | P = 0.039N | P = 0.176N | P = 0.451N | P = 0.018N
All Organs: Benign or Malignant Neoplasms
Overall rate | 34/50 (68%) | 33/50 (66%) | 34/50 (68%) | 13/50 (26%)
Adjusted rate | 71.0% | 66.5% | 69.9% | 36.4%
Terminal rate | 24/36 (67%) | 25/40 (63%) | 29/42 (69%) | 6/17 (35%)
First incidence (days) | 499 | 561 | 592 | 252
Poly-3 test | P = 0.002N | P = 0.396N | P = 0.540N | P < 0.001N

T = Terminal euthanasia

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 10 | 6 | 4 | 15
Natural deaths | 4 | 4 | 4 | 17
Survivors
Died last week of study | – | – | – | 1
Terminal euthanasia | 36 | 40 | 42 | 17
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Periesophageal tissue, inflammation, chronic active | – | – | – | 9 (18%)
Gallbladder | (42) | (45) | (45) | (37)
Hyperplasia | – | 1 (2%) | – | –
Inflammation | – | – | – | 3 (8%)
Ulcer | – | 1 (2%) | – | –
Intestine large, cecum | (47) | (49) | (50) | (41)
Inflammation | 2 (4%) | – | 2 (4%) | –
Inflammation, granulomatous | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | – | –
Intestine large, colon | (47) | (49) | (50) | (46)
Intestine large, rectum | (49) | (49) | (46) | (43)
Inflammation | – | 1 (2%) | – | –
Intestine small, duodenum | (47) | (48) | (49) | (38)
Inflammation | 1 (2%) | 2 (4%) | – | –
Necrosis | 1 (2%) | – | – | –
Intestine small, ileum | (47) | (48) | (49) | (39)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Necrosis | 1 (2%) | 1 (2%) | – | –
Ulcer | 1 (2%) | – | – | –
Intestine small, jejunum | (46) | (49) | (49) | (39)
Liver | (50) | (50) | (50) | (50)
Amyloid deposition | – | – | 1 (2%) | –
Angiectasis | 1 (2%) | – | – | 1 (2%)
Basophilic focus | 1 (2%) | 3 (6%) | 3 (6%) | 1 (2%)
Clear cell focus | 1 (2%) | 7 (14%) | 3 (6%) | –
Cyst | 1 (2%) | – | 1 (2%) | 2 (4%)
Eosinophilic focus | 4 (8%) | 4 (8%) | – | 1 (2%)
Fatty change | – | 1 (2%) | 2 (4%) | –
Fibrosis, focal | – | 1 (2%) | – | –
Hematopoietic cell proliferation | – | 1 (2%) | 1 (2%) | 1 (2%)
Hepatodiaphragmatic nodule | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 2 (4%) | 4 (8%) | –
Infiltration cellular, lymphocyte | – | – | – | 1 (2%)
Inflammation | – | – | 1 (2%) | –
Mixed cell focus | 2 (4%) | – | – | –
Tension lipidosis | – | – | – | 1 (2%)
Centrilobular, hepatocyte, hypertrophy | – | – | – | 1 (2%)
Hepatocyte, degeneration | – | 1 (2%) | – | –
Hepatocyte, necrosis | 3 (6%) | 4 (8%) | 1 (2%) | 1 (2%)
Kupffer cell, hypertrophy | – | – | – | 1 (2%)
Mesentery | (6) | (10) | (4) | (1)
Fat, necrosis | 4 (67%) | 9 (90%) | 4 (100%) | –
Pancreas | (50) | (50) | (50) | (47)
Cyst | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | –
Necrosis | – | 1 (2%) | – | –
Acinus, atrophy | 1 (2%) | 2 (4%) | 1 (2%) | –
Salivary glands | (49) | (50) | (50) | (50)
Inflammation, chronic active | – | – | – | 3 (6%)
Stomach, forestomach | (50) | (50) | (50) | (49)
Infiltration cellular, lymphoid | – | – | 1 (2%) | –
Inflammation | 3 (6%) | 1 (2%) | 3 (6%) | –
Mineralization | 1 (2%) | – | – | –
Epithelium, hyperplasia | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Stomach, glandular | (49) | (50) | (50) | (46)
Cyst | 1 (2%) | – | – | –
Degeneration | – | 1 (2%) | – | –
Infiltration cellular, lymphoid | 1 (2%) | – | 1 (2%) | –
Inflammation | 5 (10%) | – | 1 (2%) | 2 (4%)
Mineralization | 3 (6%) | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1 (2%) | – | 3 (6%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 4 (8%) | 1 (2%) | 2 (4%) | 4 (8%)
Inflammation, acute | 2 (4%) | – | – | 2 (4%)
Inflammation, chronic active | – | 2 (4%) | 1 (2%) | 7 (14%
Mineralization | – | 1 (2%) | – | 1 (2%)
Necrosis | 1 (2%) | – | – | 2 (4%)
Polyarteritis | 1 (2%) | – | – | 3 (6%)
Valve, inflammation, chronic active | – | – | – | 1 (2%)
Valve, thrombosis | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 1 (2%) | – | –
Angiectasis | – | – | – | 2 (4%)
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia | – | – | 1 (2%) | 1 (2%)
Hypertrophy | – | – | – | 2 (4%)
Inflammation, chronic active | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | 1 (2%) | –
Vacuolization cytoplasmic | 1 (2%) | 1 (2%) | – | –
Zona fasciculata, hyperplasia, focal | – | 1 (2%) | – | –
Zona fasciculata, hypertrophy, focal | 2 (4%) | – | 2 (4%) | 3 (6%)
Adrenal medulla | (50) | (50) | (49) | (50)
Hyperplasia | 2 (4%) | 4 (8%) | 1 (2%) | 2 (4%)
Islets, pancreatic | (49) | (50) | (49) | (48)
Hyperplasia | – | 1 (2%) | – | –
Parathyroid gland | (38) | (39) | (46) | (46)
Hyperplasia | – | – | 1 (2%) | –
Pituitary gland | (49) | (49) | (50) | (48)
Pars distalis, angiectasis | 3 (6%) | 1 (2%) | 1 (2%) | –
Pars distalis, hyperplasia | 15 (31%) | 7 (14%) | 6 (12%) | 1 (2%)
Pars distalis, inflammation, suppurative | – | – | 1 (2%) | –
Pars intermedia, angiectasis | – | – | 1 (2%) | –
Thyroid gland | (50) | (49) | (48) | (50)
Inflammation, chronic active | – | – | – | 9 (18%)
Mineralization | – | – | – | 1 (2%)
Follicular cell, hyperplasia | – | 2 (4%) | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (47) | (49) | (48) | (44)
Ovary | – | – | (49) | (50)
Angiectasis | – | – | 1 (2%)
Cyst | 15 (31%) | 17 (34%) | 12 (24%) | 12 (24%)
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Hyperplasia, tubular | – | 1 (2%) | – | –
Inflammation | 2 (4%) | 1 (2%) | 3 (6%) | 6 (12%)
Mineralization | – | 1 (2%) | 1 (2%) | –
Necrosis | – | 1 (2%) | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 4 (8%) | 2 (4%) | –
Hemorrhage | 1 (2%) | – | – | –
Inflammation | 4 (8%) | 2 (4%) | – | –
Thrombosis | 1 (2%) | 3 (6%) | 1 (2%) | –
Artery, necrosis | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 42 (84%) | 43 (86%) | 47 (94%) | 30 (60%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (49)
Myeloid cell, hyperplasia | 3 (6%) | 2 (4%) | 7 (14%) | 33 (67%)
Lymph node | (11) | (10) | (11) | (7)
Deep cervical, hyperplasia, lymphoid | – | – | 1 (9%) | 4 (57%)
Deep cervical, infiltration cellular, plasma cell | – | – | – | 1 (14%)
Iliac, ectasia | – | 1 (10%) | – | –
Lumbar, ectasia | 1 (9%) | 1 (10%) | 1 (9%) | –
Lumbar, hyperplasia | 1 (9%) | – | – | –
Lumbar, hyperplasia, lymphoid | 1 (9%) | – | 1 (9%) | –
Renal, amyloid deposition | 1 (9%) | – | – | –
Renal, ectasia | – | – | 1 (9%) | –
Renal, hyperplasia, lymphoid | 2 (18%) | 1 (10%) | – | –
Renal, necrosis | 1 (9%) | – | – | –
Lymph node, bronchial | (40) | (42) | (43) | (43)
Ectasia | 1 (3%) | – | – | –
Hematopoietic cell proliferation | – | 1 (2%) | – | 1 (2%)
Hyperplasia, lymphoid | 5 (13%) | 7 (17%) | 4 (9%) | 1 (2%)
Inflammation, chronic active | – | – | – | 5 (12%)
Necrosis, lymphoid | – | 1 (2%) | – | 1 (2%)
Lymph node, mandibular | (39) | (47) | (45) | (39)
Amyloid deposition | 1 (3%) | – | – | –
Ectasia | – | 1 (2%) | | 3 (8%)
Hematopoietic cell proliferation | – | – | 2 (4%) | 1 (3%)
Hyperplasia, lymphoid | 4 (10%) | 5 (11%) | 12 (27%) | 12 (31%)
Hyperplasia, plasma cell | – | – | – | 2 (5%)
Infiltration cellular, plasma cell | 1 (3%) | – | – | 5 (13%)
Infiltration cellular, polymorphonuclear | – | – | – | 1 (3%)
Inflammation, suppurative | – | – | – | 1 (3%)
Lymph node, mediastinal | (40) | (38) | (41) | (33)
Hematopoietic cell proliferation | – | 1 (3%) | – | –
Hyperplasia, lymphoid | 1 (3%) | 2 (5%) | 2 (5%) | 1 (3%)
Hyperplasia, plasma cell | – | – | 1 (2%) | 1 (3%)
Inflammation, acute | 1 (3%) | – | – | –
Inflammation, chronic active | – | – | – | 2 (6%)
Necrosis, lymphoid | – | 1 (3%) | | 1 (3%)
Lymph node, mesenteric | (49) | (50) | (50) | (45)
Ectasia | – | 1 (2%) | 1 (2%) | –
Hematopoietic cell proliferation | – | – | – | 2 (4%)
Hyperplasia, lymphoid | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Infiltration cellular, plasma cell | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (48)
Amyloid deposition | – | – | 1 (2%) | –
Angiectasis | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 8 (16%) | 14 (28%) | 5 (10%) | 11 (23%)
Hyperplasia, lymphoid | 10 (20%) | 15 (30%) | 10 (20%) | 4 (8%)
Inflammation | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Necrosis | – | 1 (2%) | 1 (2%) | 3 (6%)
Lymphoid follicle, atrophy | – | – | – | 1 (2%)
Thymus | (47) | (50) | (49) | (45)
Atrophy | 4 (9%) | 5 (10%) | 2 (4%) | 12 (27%)
Cyst | – | 1 (2%) | – | –
Ectopic parathyroid gland | 4 (9%) | 8 (16%) | 4 (8%) | 3 (7%)
Hyperplasia, lymphoid | 3 (6%) | 4 (8%) | 2 (4%) | 1 (2%)
Inflammation, chronic | 2 (4%) | – | – | –
Inflammation, chronic active | – | – | – | 8 (18%)
Integumentary System
Mammary gland | (49) | (50) | (50) | (49)
Hyperplasia | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Erosion | 1 (2%) | – | – | –
Fibrosis | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 2 (4%) | – | 3 (6%)
Epidermis, hyperplasia | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, necrosis | – | – | – | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 13 (26%) | 12 (24%) | 17 (34%) | 3 (6%)
Skeletal muscle | (6) | (1) | (3) | (4)
Degeneration | 2 (33%) | – | 1 (33%) | 1 (25%)
Inflammation | – | 1 (100%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Infiltration cellular | – | 1 (2%) | – | 1 (2%)
Infiltration cellular, lymphocyte | 2 (4%) | – | 2 (4%) | 5 (10%)
Inflammation, acute | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic | – | – | 1 (2%) | –
Peripheral nerve | (2) | (1) | (2) | (2)
Degeneration | 1 (50%) | – | 2 (100%) | 1 (50%)
Spinal cord | (2) | (1) | (2) | (2)
Respiratory System
Larynx | (49) | (50) | (50) | (49)
Inflammation, chronic active | 4 (8%) | 5 (10%) | 22 (44%) | 36 (73%)
Lumen, exudate | – | – | – | 4 (8%)
Respiratory epithelium, hyperplasia | – | – | 4 (8%) | 1 (2%)
Respiratory epithelium, metaplasia, atypical, squamous | – | 1 (2%) | – | 1 (2%)
Respiratory epithelium, metaplasia, squamous | 2 (4%) | – | 6 (12%) | 48 (98%)
Respiratory epithelium, necrosis | 1 (2%) | 1 (2%) | 14 (28%) | 32 (65%)
Respiratory epithelium, regeneration | – | – | 3 (6%) | 30 (61%)
Squamous epithelium, hyperplasia | 4 (8%) | 13 (26%) | 34 (68%) | 40 (82%)
Submucosa, mineralization | – | 1 (2%) | – | –
Lung | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | 5 (10%)
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | 2 (4%)
Necrosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia, focal | 3 (6%) | – | – | –
Alveolus, infiltration cellular, histiocyte | 2 (4%) | 3 (6%) | 3 (6%) | 4 (8%)
Alveolus, inflammation, suppurative | – | – | – | 1 (2%)
Alveolus, epithelium, hyperplasia | – | – | 1 (2%) | –
Artery, mediastinum, inflammation, chronic active | – | – | – | 1 (2%)
Bronchiole, inflammation, suppurative | – | – | – | 1 (2%)
Bronchiole, inflammation, chronic | – | – | – | 1 (2%)
Bronchiole, epithelium, hyperplasia | 1 (2%) | – | – | 2 (4%)
Bronchus, inflammation, suppurative | – | – | – | 2 (4%)
Bronchus, regeneration | – | – | – | 1 (2%)
Bronchus, epithelium, degeneration | – | – | – | 4 (8%)
Bronchus, epithelium, necrosis | 2 (4%) | – | – | 5 (10%)
Bronchus, epithelium, regeneration | 2 (4%) | – | – | 38 (76%)
Bronchus, smooth muscle, mineralization | – | – | – | 3 (6%)
Bronchus, submucosa, fibrosis | – | – | – | 5 (10%)
Interstitium, fibrosis | – | – | – | 1 (2%)
Mediastinum, inflammation, suppurative | – | 1 (2%) | 1 (2%) | 8 (16%)
Mediastinum, inflammation, chronic active | – | – | 1 (2%) | 7 (14%)
Pleura, inflammation, suppurative | – | – | – | 5 (10%)
Pleura, inflammation, chronic active | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Foreign body | – | – | 3 (6%) | 3 (6%)
Inflammation, suppurative | 3 (6%) | 20 (40%) | 50 (100%) | 50 (100%)
Glands, respiratory epithelium, cyst | – | – | – | 2 (4%)
Glands, sinus, metaplasia, respiratory | – | – | – | 12 (24%)
Lamina propria, fibrosis | – | – | 47 (94%) | 49 (98%)
Lateral wall, inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Mucosa, regeneration | – | – | 39 (78%) | 48 (96%)
Olfactory epithelium, accumulation, hyaline droplet | 11 (22%) | 11 (22%) | 17 (34%) | 2 (4%)
Olfactory epithelium, atrophy | – | 41 (82%) | 49 (98%) | 45 (90%)
Olfactory epithelium, metaplasia, respiratory | – | 22 (44%) | 46 (92%) | 49 (98%)
Olfactory epithelium, necrosis | – | – | 1 (2%) | 20 (40%)
Respiratory epithelium, accumulation, hyaline droplet | 18 (36%) | 28 (56%) | 28 (56%) | 3 (6%)
Respiratory epithelium, hyperplasia | – | 1 (2%) | – | 2 (4%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | 9 (18%) | 48 (96%) | 50 (100%)
Respiratory epithelium, necrosis | 1 (2%) | 5 (10%) | 33 (66%) | 50 (100%)
Septum, perforation | – | – | 6 (12%) | 5 (10%)
Turbinate, atrophy | – | 32 (64%) | 50 (100%) | 50 (100%)
Turbinate, necrosis | – | – | 1 (2%) | 11 (22%)
Pleura | (0) | (0) | (1) | (0)
Trachea | (50) | (49) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | 4 (8%) | 42 (84%)
Necrosis | – | – | 3 (6%) | 48 (96%)
Carina, inflammation, chronic active | – | – | – | 1 (2%)
Carina, epithelium, regeneration | – | – | – | 1 (2%)
Carina, submucosa, fibrosis | – | – | – | 6 (12%)
Carina, submucosa, mineralization | – | – | – | 5 (10%)
Epithelium, hyperplasia | – | – | 1 (2%) | 1 (2%)
Epithelium, metaplasia, squamous | – | – | – | 2 (4%)
Epithelium, regeneration | – | – | 9 (18%) | 45 (90%)
Glands, hyperplasia | – | – | – | 1 (2%)
Lumen, exudate | – | – | – | 12 (24%)
Submucosa, fibrosis | – | – | – | 44 (88%)
Special Senses System
Ear | (0) | (0) | (0) | (1)
Inflammation, suppurative | – | – | – | 1 (100%)
Eye | (50) | (49) | (50) | (49)
Anterior chamber, inflammation, suppurative | – | – | 4 (8%) | 3 (6%)
Cornea, fibrosis | – | – | 1 (2%) | –
Cornea, inflammation, acute | 1 (2%) | 2 (4%) | 20 (40%) | 23 (47%)
Cornea, mineralization | – | – | 13 (26%) | 16 (33%)
Cornea, necrosis | – | – | – | 6 (12%)
Cornea, epithelium, hyperplasia | 2 (4%) | 2 (4%) | 10 (20%) | 9 (18%)
Cornea, epithelium, ulcer | – | – | 10 (20%) | 10 (20%)
Lens, cataract | – | – | – | 2 (4%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | 4 (8%) | 1 (2%) | 4 (8%)
Inflammation | – | – | – | 1 (2%)
Pigmentation, porphyrin | – | – | – | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (49)
Amyloid deposition | – | – | 1 (2%) | –
Cyst | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | 3 (6%) | 3 (6%) | –
Infarct | – | 3 (6%) | 3 (6%) | 2 (4%)
Inflammation | – | – | – | 1 (2%)
Metaplasia, osseous | 1 (2%) | 1 (2%) | 1 (2%) | –
Necrosis | – | 1 (2%) | – | –
Nephropathy | 14 (28%) | 15 (30%) | 6 (12%) | 6 (12%)
Capsule, inflammation | – | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (49)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.