# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of 2,3-Butanedione

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 6 | 5 | 4 | 14
Natural deaths | 9 | 5 | 9 | 11
Survivors
Terminal euthanasia | 35 | 39 | 37 | 25
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (45) | (42) | (43) | (43)
Intestine large, cecum | (46) | (48) | (47) | (48)
Intestine large, colon | (46) | (47) | (48) | (47)
Intestine large, rectum | (46) | (46) | (45) | (49)
Intestine small, duodenum | (45) | (47) | (44) | (44)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Polyp adenomatous | 1 (2%) | – | – | –
Intestine small, ileum | (45) | (47) | (44) | (46)
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Intestine small, jejunum | (44) | (46) | (43) | (43)
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatoblastoma | 1 (2%) | – | 1 (2%) | –
Hepatocellular adenoma | 6 (12%) | 9 (18%) | 11 (22%) | 3 (6%)
Hepatocellular adenoma, multiple | 11 (22%) | 7 (14%) | 4 (8%) | 1 (2%)
Hepatocellular carcinoma | 10 (20%) | 6 (12%) | 5 (10%) | 6 (12%)
Hepatocellular carcinoma, multiple | 7 (14%) | 5 (10%) | 8 (16%) | –
Hepatocholangiocarcinoma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, multiple | 1 (2%) | – | – | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Mesentery | (4) | (1) | (5) | (0)
Hepatoblastoma, metastatic, liver | – | – | 1 (20%) | –
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (20%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (20%) | –
Sarcoma, metastatic, uncertain primary site | 1 (25%) | – | – | –
Pancreas | (48) | (48) | (50) | (50)
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Salivary glands | (50) | (49) | (50) | (50)
Stomach, forestomach | (48) | (48) | (49) | (50)
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Squamous cell papilloma | – | 1 (2%) | – | –
Stomach, glandular | (47) | (48) | (49) | (49)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Tooth | (2) | (2) | (1) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Hemangioma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Adenoma | – | 1 (2%) | 1 (2%) | –
Subcapsular, adenoma | 2 (4%) | 7 (14%) | 3 (6%) | 2 (4%)
Adrenal medulla | (50) | (48) | (50) | (50)
Islets, pancreatic | (48) | (48) | (49) | (50)
Adenoma | – | – | 2 (4%) | –
Parathyroid gland | (40) | (39) | (44) | (37)
Pituitary gland | (50) | (49) | (50) | (50)
Thyroid gland | (50) | (49) | (50) | (50)
Follicular cell, adenoma | – | 1 (2%) | 1 (2%) | –
General Body System
Tissue NOS | (0) | (0) | (0) | (1)
Genital System
Epididymis | (49) | (49) | (50) | (49)
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Preputial gland | (50) | (49) | (50) | (49)
Prostate gland | (49) | (49) | (49) | (50)
Carcinoma, metastatic, urinary bladder | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Seminal vesicle | (49) | (49) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Testes | (49) | (49) | (50) | (49)
Hematopoietic System
Bone marrow | (48) | (47) | (50) | (49)
Hemangiosarcoma, metastatic, spleen | – | 2 (4%) | – | –
Mast cell tumor malignant | 1 (2%) | – | – | –
Lymph node | (5) | (1) | (3) | (8)
Pancreatic, hepatoblastoma, metastatic, liver | – | – | 1 (33%) | –
Renal, hepatocholangiocarcinoma, metastatic, liver | 1 (20%) | – | – | –
Lymph node, bronchial | (34) | (43) | (38) | (31)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (3%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (3%) | – | – | –
Lymph node, mandibular | (36) | (33) | (30) | (32)
Lymph node, mediastinal | (37) | (33) | (38) | (32)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (3%) | – | 1 (3%) | –
Hepatoblastoma, metastatic, liver | – | – | 1 (3%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (3%) | – | 1 (3%) | –
Sarcoma, metastatic, uncertain primary site | 1 (3%) | – | – | –
Lymph node, mesenteric | (47) | (47) | (49) | (47)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Spleen | (48) | (49) | (50) | (50)
Hemangiosarcoma | – | 2 (4%) | – | –
Thymus | (43) | (42) | (44) | (30)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (1) | (0) | (0) | (1)
Skin | (50) | (49) | (50) | (49)
Carcinoma | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (2) | (4) | (5) | (2)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (50%) | – | 1 (20%) | –
Hepatoblastoma, metastatic, liver | – | – | 1 (20%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (50%) | – | 1 (20%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (0) | (2) | (1) | (1)
Spinal cord | (0) | (2) | (1) | (1)
Respiratory System
Larynx | (49) | (49) | (49) | (50)
Lung | (50) | (49) | (50) | (50)
Alveolar/bronchiolar adenoma | 4 (8%) | 5 (10%) | 5 (10%) | 4 (8%)
Alveolar/bronchiolar adenoma, multiple | 1 (2%) | – | – | –
Alveolar/bronchiolar carcinoma | 4 (8%) | 3 (6%) | 4 (8%) | 2 (4%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | – | 2 (4%) | 1 (2%)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 4 (8%) | 2 (4%) | 7 (14%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | –
Nose | (49) | (48) | (50) | (50)
Turbinate, polyp | 1 (2%) | – | – | –
Trachea | (48) | (49) | (49) | (49)
Special Senses System
Eye | (49) | (49) | (50) | (50)
Harderian gland | (50) | (49) | (50) | (50)
Adenoma | 3 (6%) | 6 (12%) | 2 (4%) | 3 (6%)
Carcinoma | – | 1 (2%) | – | 1 (2%)
Urinary System
Kidney | (49) | (50) | (50) | (50)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Urinary bladder | (49) | (48) | (50) | (49)
Carcinoma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Systemic Lesions
Multiple organsb | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 1 (2%) | 2 (4%) | –
Lymphoma malignant | 6 (12%) | 4 (8%) | 3 (6%) | 2 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 37 | 37 | 36 | 18
Total primary neoplasms | 61 | 60 | 56 | 27
Total animals with benign neoplasms | 22 | 27 | 21 | 11
Total benign neoplasms | 29 | 37 | 29 | 14
Total animals with malignant neoplasms | 27 | 20 | 24 | 12
Total malignant neoplasms | 32 | 23 | 27 | 13
Total animals with metastatic neoplasms | 8 | 5 | 11 | –
Total metastatic neoplasms | 28 | 6 | 33 | –
Total animals with malignant neoplasms of uncertain primary site | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Adrenal Cortex: Adenoma
Overall rate^a^ | 2/50 (4%) | 8/49 (16%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate^b^ | 4.4% | 17.6% | 6.6% | 5.2%
Terminal ratec | 1/35 (3%) | 7/39 (18%) | 3/37 (8%) | 2/25 (8%)
First incidence (days) | 590 | 611 | 729 (T) | 729 (T)
Poly-3 test^d^ | P = 0.381N | P = 0.046 | P = 0.505 | P = 0.632
Harderian Gland: Adenoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 6.7% | 13.0% | 4.4% | 7.9%
Terminal rate | 2/35 (6%) | 5/39 (13%) | 2/37 (5%) | 2/25 (8%)
First incidence (days) | 667 | 574 | 729 (T) | 718
Poly-3 test | P = 0.471N | P = 0.255 | P = 0.492N | P = 0.585
Harderian Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 6.7% | 15.2% | 4.4% | 10.4%
Terminal rate | 2/35 (6%) | 5/39 (13%) | 2/37 (5%) | 2/25 (8%)
First incidence (days) | 667 | 574 | 729 (T) | 650
Poly-3 test | P = 0.542 | P = 0.168 | P = 0.492N | P = 0.416
Liver: Hepatocellular Adenoma
Overall rate | 17/50 (34%) | 16/50 (32%) | 15/50 (30%) | 4/50 (8%)
Adjusted rate | 37.4% | 34.7% | 32.4% | 10.5%
Terminal rate | 15/35 (43%) | 14/39 (36%) | 13/37 (35%) | 4/25 (16%)
First incidence (days) | 590 | 611 | 554 | 729 (T)
Poly-3 test | P = 0.005N | P = 0.482N | P = 0.391N | P = 0.004N
Liver: Hepatocellular Carcinoma
Overall rate | 17/50 (34%) | 11/50 (22%) | 13/50 (26%) | 6/50 (12%)
Adjusted rate | 36.0% | 22.6% | 27.6% | 15.7%
Terminal rate | 8/35 (23%) | 5/39 (13%) | 8/37 (22%) | 6/25 (24%)
First incidence (days) | 519 | 396 | 527 | 729 (T)
Poly-3 test | P = 0.043N | P = 0.112N | P = 0.258N | P = 0.031N
Liver: Hepatocellular Adenoma or Hepatocellular Carcinoma
Overall rate | 31/50 (62%) | 27/50 (54%) | 25/50 (50%) | 8/50 (16%)
Adjusted rate | 64.9% | 55.0% | 52.4% | 21.0%
Terminal rate | 21/35 (60%) | 19/39 (49%) | 18/37 (49%) | 8/25 (32%)
First incidence (days) | 519 | 396 | 527 | 729 (T)
Poly-3 test | P < 0.001N | P = 0.214N | P = 0.148N | P < 0.001N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 18/50 (36%) | 11/50 (22%) | 14/50 (28%) | 6/50 (12%)
Adjusted rate | 37.6% | 22.6% | 29.7% | 15.7%
Terminal rate | 8/35 (23%) | 5/39 (13%) | 9/37 (24%) | 6/25 (24%)
First incidence (days) | 519 | 396 | 527 | 729 (T)
Poly-3 test | P = 0.035N | P = 0.082N | P = 0.275N | P = 0.021N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 32/50 (64%) | 27/50 (54%) | 26/50 (52%) | 8/50 (16%)
Adjusted rate | 66.2% | 55.0% | 54.5% | 21.0%
Terminal rate | 21/35 (60%) | 19/39 (49%) | 19/37 (51%) | 8/25 (32%)
First incidence (days) | 519 | 396 | 527 | 729 (T)
Poly-3 test | P < 0.001N | P = 0.175N | P = 0.165N | P < 0.001N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 5/49 (10%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 11.2% | 11.1% | 10.9% | 10.4%
Terminal rate | 5/35 (14%) | 5/39 (13%) | 4/37 (11%) | 2/25 (8%)
First incidence (days) | 729 (T) | 729 (T) | 722 | 650
Poly-3 test | P = 0.511N | P = 0.625N | P = 0.616N | P = 0.591N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 5/50 (10%) | 3/49 (6%) | 6/50 (12%) | 3/50 (6%)
Adjusted rate | 11.2% | 6.7% | 13.0% | 7.9%
Terminal rate | 4/35 (11%) | 3/39 (8%) | 3/37 (8%) | 3/25 (12%)
First incidence (days) | 722 | 729 (T) | 588 | 729 (T)
Poly-3 test | P = 0.481N | P = 0.351N | P = 0.523 | P = 0.446N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 9/50 (18%) | 8/49 (16%) | 10/50 (20%) | 7/50 (14%)
Adjusted rate | 20.1% | 17.7% | 21.6% | 18.1%
Terminal rate | 8/35 (23%) | 8/39 (21%) | 7/37 (19%) | 5/25 (20%)
First incidence (days) | 722 | 729 (T) | 588 | 650
Poly-3 test | P = 0.508N | P = 0.492N | P = 0.532 | P = 0.519N
All Organs: Malignant Lymphoma
Overall rate | 6/50 (12%) | 4/50 (8%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 13.2% | 8.6% | 6.5% | 5.2%
Terminal rate | 4/35 (11%) | 2/39 (5%) | 0/37 (0%) | 1/25 (4%)
First incidence (days) | 519 | 480 | 637 | 718
Poly-3 test | P = 0.133N | P = 0.356N | P = 0.236N | P = 0.197N
All Organs: Benign Neoplasms
Overall rate | 22/50 (44%) | 27/50 (54%) | 21/50 (42%) | 11/50 (22%)
Adjusted rate | 48.1% | 58.0% | 45.0% | 28.4%
Terminal rate | 19/35 (54%) | 24/39 (62%) | 18/37 (49%) | 8/25 (32%)
First incidence (days) | 590 | 574 | 554 | 650
Poly-3 test | P = 0.019N | P = 0.226 | P = 0.462N | P = 0.049N
All Organs: Malignant Neoplasms
Overall rate | 27/50 (54%) | 20/50 (40%) | 24/50 (48%) | 12/50 (24%)
Adjusted rate | 55.1% | 40.5% | 49.9% | 31.0%
Terminal rate | 14/35 (40%) | 11/39 (28%) | 14/37 (38%) | 9/25 (36%)
First incidence (days) | 519 | 396 | 527 | 650
Poly-3 test | P = 0.038N | P = 0.105N | P = 0.379N | P = 0.019N
All Organs: Malignant or Benign Neoplasms
Overall rate | 37/50 (74%) | 37/50 (74%) | 36/50 (72%) | 18/50 (36%)
Adjusted rate | 75.5% | 74.9% | 73.3% | 46.5%
Terminal rate | 24/35 (69%) | 28/39 (72%) | 24/37 (65%) | 14/25 (56%)
First incidence (days) | 519 | 396 | 527 | 650
Poly-3 test | P = 0.003N | P = 0.565N | P = 0.493N | P = 0.003N

T = Terminal euthanasia

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

Table C-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 6 | 5 | 4 | 14
Natural deaths | 9 | 5 | 9 | 11
Survivors
Terminal euthanasia | 35 | 39 | 37 | 25
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Periesophageal tissue, inflammation, chronic active | – | – | – | 3 (6%)
Submucosa, inflammation, chronic active | – | – | – | 1 (2%)
Gallbladder | (45) | (42) | (43) | (43)
Inflammation | | | | 1 (2%)
Intestine large, cecum | (46) | (48) | (47) | (48)
Inflammation | 7 (15%) | – | 2 (4%) | –
Intestine large, colon | (46) | (47) | (48) | (47)
Intestine large, rectum | (46) | (46) | (45) | (49)
Inflammation | – | – | – | 1 (2%)
Intestine small, duodenum | (45) | (47) | (44) | (44)
Inflammation | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Intestine small, ileum | (45) | (47) | (44) | (46)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 2 (5%) | –
Inflammation | 3 (7%) | – | 1 (2%) | –
Intestine small, jejunum | (44) | (46) | (43) | (43)
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation | 1 (2%) | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Basophilic focus | 7 (14%) | 5 (10%) | 7 (14%) | 6 (12%)
Clear cell focus | 2 (4%) | 5 (10%) | 5 (10%) | –
Cyst | 1 (2%) | 1 (2%) | – | –
Eosinophilic focus | 4 (8%) | 6 (12%) | 4 (8%) | 4 (8%)
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hepatodiaphragmatic nodule | 1 (2%) | – | – | –
Mixed cell focus | 4 (8%) | 7 (14%) | 2 (4%) | 1 (2%)
Pigmentation, ceroid | 1 (2%) | – | – | –
Syncytial alteration | – | 1 (2%) | – | –
Tension lipidosis | – | 2 (4%) | – | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Hepatocyte, degeneration | 2 (4%) | – | – | –
Hepatocyte, necrosis | 4 (8%) | 5 (10%) | 1 (2%) | 3 (6%)
Mesentery | (4) | (1) | (5) | (0)
Hemorrhage | 1 (25%) | – | – | –
Artery, thrombosis | 1 (25%) | – | – | –
Fat, necrosis | 1 (25%) | 1 (100%) | 2 (40%) | –
Pancreas | (48) | (48) | (50) | (50)
Necrosis | – | – | 1 (2%) | –
Acinus, atrophy | 2 (4%) | – | 1 (2%) | –
Salivary glands | (50) | (49) | (50) | (50)
Stomach, forestomach | (48) | (48) | (49) | (50)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Epithelium, hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Stomach, glandular | (47) | (48) | (49) | (49)
Inflammation | 3 (6%) | 4 (8%) | 2 (4%) | –
Mineralization | – | – | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Tooth | (2) | (2) | (1) | (0)
Dysplasia | 2 (100%) | 2 (100%) | 1 (100%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (49)
Cardiomyopathy | 4 (8%) | 1 (2%) | 8 (16%) | 3 (6%)
Inflammation, acute | 1 (2%) | – | 1 (2%) | 3 (6%)
Inflammation, chronic active | – | – | 1 (2%) | 5 (10%)
Mineralization | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | 3 (6%)
Polyarteritis | 3 (6%) | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | – | –
Valve, inflammation, chronic active | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Zona fasciculata, hypertrophy, focal | 23 (46%) | 26 (53%) | 35 (70%) | 9 (18%)
Adrenal medulla | (50) | (48) | (50) | (50)
Hyperplasia | – | – | 3 (6%) | –
Islets, pancreatic | (48) | (48) | (49) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 4 (8%) | –
Parathyroid gland | (40) | (39) | (44) | (37)
Pituitary gland | (50) | (49) | (50) | (50)
Pars distalis, hyperplasia | 1 (2%) | 2 (4%) | – | –
Thyroid gland | (50) | (49) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | 2 (4%)
Follicular cell, hyperplasia | – | 1 (2%) | – | 1 (2%)
General Body System
Tissue NOS | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Genital System
Epididymis | (49) | (49) | (50) | (49)
Exfoliated germ cell | 32 (65%) | 23 (47%) | 25 (50%) | 26 (53%)
Granuloma sperm | 1 (2%) | 2 (4%) | – | 1 (2%)
Infiltration cellular, lymphoid | 1 (2%) | – | – | –
Inflammation | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Preputial gland | (50) | (49) | (50) | (49)
Ectasia | – | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation | 1 (2%) | 3 (6%) | 5 (10%) | 3 (6%)
Prostate gland | (49) | (49) | (49) | (50)
Inflammation | – | 2 (4%) | – | 1 (2%)
Seminal vesicle | (49) | (49) | (50) | (50)
Dilatation | 2 (4%) | – | – | –
Testes | (49) | (49) | (50) | (49)
Interstitial cell, hyperplasia | – | – | 1 (2%) | 1 (2%)
Seminiferous tubule, degeneration | 14 (29%) | 6 (12%) | 13 (26%) | 6 (12%)
Hematopoietic System
Bone marrow | (48) | (47) | (50) | (49)
Infiltration cellular, mast cell | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | – | –
Myeloid cell, hyperplasia | 9 (19%) | 8 (17%) | 20 (40%) | 39 (80%)
Lymph node | (5) | (1) | (3) | (8)
Deep cervical, ectasia | – | – | – | 1 (13%)
Deep cervical, hematopoietic cell proliferation | – | – | – | 1 (13%)
Deep cervical, hyperplasia, lymphoid | – | – | – | 4 (50%)
Deep cervical, infiltration cellular, plasma cell | – | – | – | 1 (13%)
Pancreatic, ectasia | – | – | 1 (33%) | –
Pancreatic, hyperplasia, lymphoid | – | – | – | 1 (13%)
Renal, ectasia | 1 (20%) | – | 1 (33%) | –
Renal, hematopoietic cell proliferation | – | – | – | 1 (13%)
Lymph node, bronchial | (34) | (43) | (38) | (31)
Ectasia | – | – | – | 1 (3%)
Hematopoietic cell proliferation | – | – | 1 (3%) | –
Hyperplasia, lymphoid | – | 1 (2%) | 3 (8%) | 2 (6%)
Infiltration cellular, plasma cell | – | – | – | 1 (3%)
Inflammation, chronic active | – | – | – | 2 (6%)
Pigmentation | – | – | – | 3 (10%)
Lymph node, mandibular | (36) | (33) | (30) | (32)
Ectasia | – | – | – | 4 (13%)
Hematopoietic cell proliferation | – | – | – | 3 (9%)
Hyperplasia, lymphoid | 2 (6%) | 5 (15%) | 11 (37%) | 10 (31%)
Infiltration cellular, plasma cell | 1 (3%) | – | 2 (7%) | 14 (44%)
Lymph node, mediastinal | (37) | (33) | (38) | (32)
Hematopoietic cell proliferation | – | – | 1 (3%) | 1 (3%)
Hyperplasia, lymphoid | – | – | – | 2 (6%)
Infiltration cellular, plasma cell | – | – | 1 (3%) | 2 (6%)
Inflammation, chronic active | – | – | – | 2 (6%)
Lymph node, mesenteric | (47) | (47) | (49) | (47)
Ectasia | 1 (2%) | – | 1 (2%) | –
Hematopoietic cell proliferation | 4 (9%) | 1 (2%) | – | 2 (4%)
Hyperplasia, lymphoid | 7 (15%) | 1 (2%) | 2 (4%) | –
Inflammation | – | – | 1 (2%) | –
Spleen | (48) | (49) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Congestion | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 11 (23%) | 12 (24%) | 15 (30%) | 25 (50%)
Hyperplasia, lymphoid | – | 4 (8%) | 1 (2%) | 3 (6%)
Inflammation | 1 (2%) | – | – | 2 (4%)
Necrosis | – | – | – | 2 (4%)
Lymphoid follicle, atrophy | – | – | – | 2 (4%)
Thymus | (43) | (42) | (44) | (30)
Atrophy | 10 (23%) | 5 (12%) | 2 (5%) | 5 (17%)
Cyst | 1 (2%) | – | – | 1 (3%)
Ectopic parathyroid gland | 6 (14%) | 4 (10%) | 11 (25%) | 4 (13%)
Inflammation, chronic active | 1 (2%) | – | – | 3 (10%)
Integumentary System
Mammary gland | (1) | (0) | (0) | (1)
Skin | (50) | (49) | (50) | (49)
Hyperkeratosis | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Pigmentation, melanin | – | 1 (2%) | – | –
Epidermis, hyperplasia | – | 2 (4%) | 1 (2%) | –
Epidermis, necrosis | – | – | 1 (2%) | –
Epidermis, ulcer | 1 (2%) | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, cyst epithelial inclusion | – | – | 1 (2%) | –
Subcutaneous tissue, inflammation, suppurative | – | – | 1 (2%) | –
Subcutaneous tissue, necrosis | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%)
Maxilla, osteomalacia | – | – | – | 1 (2%)
Skeletal muscle | (2) | (4) | (5) | (2)
Degeneration | – | 1 (25%) | – | 1 (50%)
Hemorrhage, acute | – | 2 (50%) | – | –
Inflammation | – | 1 (25%) | – | 1 (50%)
Necrosis, acute | – | 1 (25%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Infiltration cellular, lymphocyte | – | – | 2 (4%) | –
Inflammation, acute | 1 (2%) | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis, chronic | 1 (2%) | – | – | –
Peripheral nerve | (0) | (2) | (1) | (1)
Degeneration | – | 1 (50%) | 1 (100%) | 1 (100%)
Spinal cord | (0) | (2) | (1) | (1)
Respiratory System
Larynx | (49) | (49) | (49) | (50)
Inflammation, suppurative | 2 (4%) | – | – | –
Inflammation, chronic active | 4 (8%) | 2 (4%) | 11 (22%) | 42 (84%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Lumen, exudate | – | – | – | 2 (4%)
Respiratory epithelium, hyperplasia | 1 (2%) | – | – | 11 (22%)
Respiratory epithelium, metaplasia, squamous | 3 (6%) | – | 6 (12%) | 50 (100%)
Respiratory epithelium, necrosis | 2 (4%) | 1 (2%) | 9 (18%) | 34 (68%)
Respiratory epithelium, regeneration | – | – | – | 32 (64%)
Squamous epithelium, hyperplasia | 3 (6%) | 7 (14%) | 15 (31%) | 42 (84%)
Lung | (50) | (49) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | 3 (6%)
Inflammation, chronic active | 1 (2%) | – | 2 (4%) | –
Mineralization | 1 (2%) | – | – | –
Thrombosis | 2 (4%) | 1 (2%) | – | 2 (4%)
Alveolar epithelium, hyperplasia | 1 (2%) | 1 (2%) | – | –
Alveolar epithelium, hyperplasia, focal | 3 (6%) | 3 (6%) | 4 (8%) | –
Alveolus, infiltration cellular, histiocyte | 7 (14%) | 2 (4%) | 3 (6%) | 9 (18%)
Bronchiole, epithelium, hyperplasia | 1 (2%) | – | 1 (2%) | 2 (4%)
Bronchus, inflammation, suppurative | – | – | – | 1 (2%)
Bronchus, epithelium, necrosis | – | – | – | 2 (4%)
Bronchus, epithelium, regeneration | – | – | – | 34 (68%)
Interstitium, fibrosis | 1 (2%) | – | 1 (2%) | –
Mediastinum, inflammation, suppurative | – | – | – | 3 (6%)
Mediastinum, inflammation, chronic active | 1 (2%) | – | – | 8 (16%)
Mediastinum, necrosis | – | – | – | 1 (2%)
Pleura, inflammation, suppurative | – | – | – | 2 (4%)
Pleura, inflammation, chronic active | – | – | 1 (2%) | –
Nose | (49) | (48) | (50) | (50)
Foreign body | – | – | 3 (6%) | –
Inflammation, suppurative | 2 (4%) | 4 (8%) | 47 (94%) | 50 (100%)
Glands, olfactory epithelium, inflammation, acute | – | 1 (2%) | – | –
Glands, respiratory epithelium, cyst | – | 1 (2%) | – | 5 (10%)
Glands, sinus, metaplasia, respiratory | – | – | 1 (2%) | 13 (26%)
Lamina propria, fibrosis | – | – | 44 (88%) | 50 (100%)
Lateral wall, inflammation, chronic active | 5 (10%) | 8 (17%) | 5 (10%) | 2 (4%)
Mucosa, regeneration | – | – | 47 (94%) | 47 (94%)
Nasopharyngeal duct, polyp, inflammatory | – | – | – | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 1 (2%) | – | 1 (2%) | 2 (4%)
Olfactory epithelium, atrophy | – | 14 (29%) | 48 (96%) | 38 (76%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | – | 39 (78%) | 45 (90%)
Olfactory epithelium, metaplasia, squamous | 1 (2%) | – | – | –
Olfactory epithelium, necrosis | – | – | – | 19 (38%)
Respiratory epithelium, accumulation, hyaline droplet | 3 (6%) | 1 (2%) | 6 (12%) | 7 (14%)
Respiratory epithelium, cyst | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 1 (2%) | – | – | 8 (16%)
Respiratory epithelium, metaplasia, squamous | – | 6 (13%) | 47 (94%) | 50 (100%)
Respiratory epithelium, necrosis | – | – | 34 (68%) | 50 (100%)
Respiratory epithelium, regeneration | – | – | 2 (4%) | –
Septum, perforation | – | – | 3 (6%) | 11 (22%)
Turbinate, atrophy | – | 8 (17%) | 49 (98%) | 50 (100%)
Turbinate, necrosis | – | – | 4 (8%) | 27 (54%)
Trachea | (48) | (49) | (49) | (49)
Inflammation, chronic active | – | – | 2 (4%) | 45 (92%)
Necrosis | – | – | – | 47 (96%)
Carina, epithelium, hyperplasia | – | – | – | 1 (2%)
Carina, epithelium, necrosis | – | – | – | 1 (2%)
Carina, submucosa, fibrosis | – | – | – | 16 (33%)
Carina, submucosa, inflammation, chronic active | – | – | – | 4 (8%)
Carina, submucosa, mineralization | – | – | – | 15 (31%)
Epithelium, hyperplasia | – | – | – | 6 (12%)
Epithelium, metaplasia, squamous | – | – | – | 5 (10%)
Epithelium, regeneration | – | – | – | 45 (92%)
Lumen, exudate | – | – | – | 4 (8%)
Submucosa, fibrosis | – | – | – | 46 (94%)
Special Senses System
Eye | (49) | (49) | (50) | (50)
Phthisis bulbi | – | – | – | 1 (2%)
Anterior chamber, inflammation, suppurative | – | – | – | 5 (10%)
Cornea, edema | – | – | – | 1 (2%)
Cornea, inflammation, acute | 2 (4%) | – | 1 (2%) | 17 (34%)
Cornea, mineralization | – | – | – | 5 (10%)
Cornea, neovascularization | – | – | – | 1 (2%)
Cornea, epithelium, hyperplasia | 1 (2%) | – | – | 9 (18%)
Cornea, epithelium, ulcer | – | – | – | 3 (6%)
Lens, cataract | 1 (2%) | 1 (2%) | – | 2 (4%)
Harderian gland | (50) | (49) | (50) | (50)
Hyperplasia | 2 (4%) | 3 (6%) | 1 (2%) | 2 (4%)
Urinary System
Kidney | (49) | (50) | (50) | (50)
Cyst | 1 (2%) | 2 (4%) | 1 (2%) | –
Infarct | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Inflammation | 1 (2%) | – | 2 (4%) | 1 (2%)
Metaplasia, osseous | 2 (4%) | 2 (4%) | 4 (8%) | 2 (4%)
Mineralization | – | 1 (2%) | – | –
Nephropathy | 34 (69%) | 26 (52%) | 25 (50%) | 10 (20%)
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Papilla, necrosis | – | – | – | 1 (2%)
Pelvis, dilatation | – | 1 (2%) | 1 (2%) | –
Urinary bladder | (49) | (48) | (50) | (49)
Angiectasis | 1 (2%) | – | – | –
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Inflammation | – | 1 (2%) | – | –
Mineralization | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.