# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of 2,3-Butanedione

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 15 | 18 | 26 | 15
Natural deaths | 1 | 1 | – | 4
Survivors
Died last week of study | – | – | – | 1
Terminal euthanasia | 34 | 31 | 24 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Leiomyosarcoma | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | – | 1 (2%)
Cholangioma | 3 (6%) | 1 (2%) | – | –
Hepatocellular adenoma | – | 1 (2%) | 1 (2%) | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Mesentery | (8) | (10) | (4) | (4)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (25%)
Cystadenocarcinoma, metastatic, ovary | – | 1 (10%) | – | –
Fat, schwannoma malignant, metastatic, uterus | – | 1 (10%) | – | –
Pancreas | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, uterus | – | – | – | 1 (2%)
Acinus, adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma, multiple | 1 (2%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | 1 (2%)
Adenoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (49) | (50)
Pheochromocytoma benign | 3 (6%) | – | – | –
Pheochromocytoma malignant | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (46) | (44) | (46) | (42)
Adenoma | – | – | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, Harderian gland | – | 1 (2%) | – | –
Pars distalis, adenoma | 26 (52%) | 24 (48%) | 24 (48%) | 23 (46%)
Pars intermedia, adenoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, adenoma | 2 (4%) | 4 (8%) | 3 (6%) | 3 (6%)
C-cell, carcinoma | 1 (2%) | – | – | –
Follicular cell, adenoma | 2 (4%) | 4 (8%) | 1 (2%) | –
Follicular cell, carcinoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (50) | (50) | (49)
Ovary | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Cystadenocarcinoma | – | 1 (2%) | – | –
Cystadenoma | – | 1 (2%) | – | –
Granulosa cell tumor malignant | – | 1 (2%) | 2 (4%) | –
Granulosa-theca tumor malignant | 1 (2%) | – | – | 1 (2%)
Sertoli cell tumor benign | – | – | – | 2 (4%)
Thecoma benign | – | – | – | 1 (2%)
Germinal epithelium, tubulostromal adenoma | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | 2 (4%) | 4 (8%) | 2 (4%) | 3 (6%)
Adenoma | – | – | – | 2 (4%)
Hemangioma | – | – | – | 1 (2%)
Leiomyoma | – | 1 (2%) | – | –
Polyp stromal | 9 (18%) | 10 (20%) | 7 (14%) | 13 (26%)
Polyp stromal, multiple | – | 3 (6%) | – | –
Sarcoma stromal | – | – | 3 (6%) | –
Schwannoma malignant | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Cervix, granular cell tumor benign | – | 3 (6%) | – | –
Cervix, hemangioma | – | – | 1 (2%) | –
Cervix, sarcoma stromal | 1 (2%) | – | – | –
Cervix, schwannoma malignant | – | – | 1 (2%) | –
Cervix, squamous cell carcinoma | – | – | 1 (2%) | –
Serosa, cystadenocarcinoma, metastatic, ovary | – | 1 (2%) | – | –
Vagina | (0) | (1) | (2) | (0)
Granular cell tumor benign | – | 1 (100%) | – | –
Polyp | – | – | 1 (50%) | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (50%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (1) | (3) | (2) | (5)
Lumbar, adenocarcinoma, metastatic, uterus | – | 1 (33%) | – | –
Renal, adenocarcinoma, metastatic, uterus | – | 2 (67%) | – | –
Lymph node, bronchial | (43) | (44) | (43) | (42)
Lymph node, mandibular | (46) | (48) | (45) | (48)
Hemangioma | 1 (2%) | – | – | –
Lymph node, mediastinal | (44) | (47) | (48) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangiosarcoma | 2 (4%) | – | – | –
Schwannoma malignant, metastatic, uterus | – | 1 (2%) | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Thymus | (49) | (50) | (49) | (50)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | 4 (8%) | 3 (6%) | 2 (4%) | 1 (2%)
Adenoma, multiple | 1 (2%) | – | – | –
Carcinoma | 2 (4%) | 4 (8%) | 1 (2%) | 8 (16%)
Carcinoma, multiple | 2 (4%) | – | – | 1 (2%)
Fibroadenoma | 12 (24%) | 10 (20%) | 9 (18%) | 8 (16%)
Fibroadenoma, multiple | 1 (2%) | 3 (6%) | 3 (6%) | 3 (6%)
Skin | (50) | (50) | (50) | (50)
Subcutaneous tissue, adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Subcutaneous tissue, hibernoma | – | – | – | 2 (4%)
Subcutaneous tissue, lipoma | – | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (3) | (7) | (5) | (5)
Adenocarcinoma, metastatic, uterus | – | 2 (29%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Oligodendroglioma benign | 1 (2%) | – | – | 1 (2%)
Schwannoma malignant, metastatic, Harderian gland | – | 1 (2%) | – | –
Peripheral nerve | (3) | (5) | (5) | (5)
Trigeminal, schwannoma malignant, metastatic, Harderian gland | – | 1 (20%) | – | –
Spinal cord | (3) | (5) | (5) | (5)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Alveolar/bronchiolar adenoma | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, uterus | – | – | – | 1 (2%)
Mediastinum, adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | – | 3 (6%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Iris, melanoma malignant | – | – | 1 (2%) | –
Optic nerve, schwannoma malignant, metastatic, Harderian gland | – | 1 (2%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Schwannoma malignant | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Urinary bladder | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | 1 (2%)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | – | 1 (2%) | – | –
Lymphoma malignant | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 40 | 45 | 44 | 40
Total primary neoplasms | 83 | 89 | 73 | 83
Total animals with benign neoplasms | 39 | 42 | 38 | 37
Total benign neoplasms | 70 | 72 | 56 | 63
Total animals with malignant neoplasms | 12 | 14 | 17 | 19
Total malignant neoplasms | 13 | 17 | 17 | 20
Total animals with metastatic neoplasms | – | 6 | 3 | 2
Total metastatic neoplasms | – | 20 | 5 | 12

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 3/50 (6%) | 0/50 (0%) | 0/49 (0%) | 0/50 (0%)
Adjusted rate^b^ | 6.8% | 0.0% | 0.0% | 0.0%
Terminal rate^c^ | 2/34 (6%) | 0/31 (0%) | 0/23 (0%) | 0/30 (0%)
First incidence (days) | 599 | –^e^ | – | –
Poly-3 test^d^ | P = 0.044N | P = 0.123N | P = 0.141N | P = 0.121N
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 0/49 (0%) | 1/50 (2%)
Adjusted rate | 6.8% | 0.0% | 0.0% | 2.3%
Terminal rate | 2/34 (6%) | 0/31 (0%) | 0/23 (0%) | 0/30 (0%)
First incidence (days) | 599 | – | – | 711
Poly-3 test | P = 0.244N | P = 0.123N | P = 0.141N | P = 0.309N
Liver: Cholangioma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 6.8% | 2.3% | 0.0% | 0.0%
Terminal rate | 2/34 (6%) | 1/31 (3%) | 0/24 (0%) | 0/30 (0%)
First incidence (days) | 614 | 731 (T) | – | –
Poly-3 test | P = 0.043N | P = 0.313N | P = 0.136N | P = 0.120N
Mammary Gland: Fibroadenoma
Overall rate | 13/50 (26%) | 13/50 (26%) | 12/50 (24%) | 11/50 (22%)
Adjusted rate | 28.7% | 30.0% | 29.3% | 24.5%
Terminal rate | 8/34 (24%) | 12/31 (39%) | 7/24 (29%) | 5/30 (17%)
First incidence (days) | 561 | 630 | 442 | 544
Poly-3 test | P = 0.341N | P = 0.542 | P = 0.571 | P = 0.414N
Mammary Gland: Adenoma
Overall rate | 5/50 (10%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 11.2% | 6.9% | 5.0% | 2.3%
Terminal rate | 2/34 (6%) | 2/31 (7%) | 2/24 (8%) | 0/30 (0%)
First incidence (days) | 614 | 687 | 731 (T) | 544
Poly-3 test | P = 0.065N | P = 0.373N | P = 0.261N | P = 0.103N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 15/50 (30%) | 15/50 (30%) | 14/50 (28%) | 11/50 (22%)
Adjusted rate | 32.6% | 34.4% | 34.2% | 24.5%
Terminal rate | 8/34 (24%) | 13/31 (42%) | 9/24 (38%) | 5/30 (17%)
First incidence (days) | 561 | 630 | 442 | 544
Poly-3 test | P = 0.202N | P = 0.515 | P = 0.526 | P = 0.267N
Mammary Gland: Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 1/50 (2%) | 9/50 (18%)
Adjusted rate | 9.0% | 9.1% | 2.5% | 19.8%
Terminal rate | 2/34 (6%) | 3/31 (10%) | 1/24 (4%) | 4/30 (13%)
First incidence (days) | 599 | 418 | 731 (T) | 491
Poly-3 test | P = 0.053 | P = 0.636 | P = 0.212N | P = 0.123
Mammary Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 7/50 (14%) | 3/50 (6%) | 10/50 (20%)
Adjusted rate | 17.8% | 15.9% | 7.5% | 21.7%
Terminal rate | 4/34 (12%) | 5/31 (16%) | 3/24 (13%) | 4/30 (13%)
First incidence (days) | 599 | 418 | 731 (T) | 491
Poly-3 test | P = 0.344 | P = 0.519N | P = 0.138N | P = 0.417
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 15/50 (30%) | 17/50 (34%) | 15/50 (30%) | 18/50 (36%)
Adjusted rate | 32.6% | 38.3% | 36.7% | 38.7%
Terminal rate | 8/34 (24%) | 14/31 (45%) | 10/24 (42%) | 9/30 (30%)
First incidence (days) | 561 | 418 | 442 | 491
Poly-3 test | P = 0.337 | P = 0.362 | P = 0.431 | P = 0.343
Nose: Squamous Cell Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate | 0/34 (0%) | 0/31 (0%) | 0/24 (0%) | 2/30 (7%)
First incidence (days) | – | – | – | 724
Poly-3 test | P = 0.011 | –^f^ | – | P = 0.118
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 26/50 (52%) | 24/50 (48%) | 24/50 (48%) | 23/50 (46%)
Adjusted rate | 53.2% | 50.7% | 51.6% | 49.0%
Terminal rate | 14/34 (41%) | 9/31 (29%) | 9/24 (38%) | 10/30 (33%)
First incidence (days) | 253 | 418 | 361 | 537
Poly-3 test | P = 0.389N | P = 0.485N | P = 0.517N | P = 0.418N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 4.6% | 9.3% | 7.5% | 6.9%
Terminal rate | 2/34 (6%) | 3/31 (10%) | 1/24 (4%) | 3/30 (10%)
First incidence (days) | 731 (T) | 687 | 723 | 731 (T)
Poly-3 test | P = 0.493 | P = 0.333 | P = 0.462 | P = 0.499
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 6.9% | 9.3% | 7.5% | 6.9%
Terminal rate | 3/34 (9%) | 3/31 (10%) | 1/24 (4%) | 3/30 (10%)
First incidence (days) | 731 (T) | 687 | 723 | 731 (T)
Poly-3 test | P = 0.527N | P = 0.495 | P = 0.624 | P = 0.662
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 4.6% | 9.3% | 2.5% | 0.0%
Terminal rate | 1/34 (3%) | 4/31 (13%) | 1/24 (4%) | 0/30 (0%)
First incidence (days) | 614 | 731 (T) | 731 (T) | –
Poly-3 test | P = 0.092N | P = 0.327 | P = 0.533N | P = 0.239N
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 5/50 (10%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 4.6% | 11.6% | 2.5% | 0.0%
Terminal rate | 1/34 (3%) | 5/31 (16%) | 1/24 (4%) | 0/30 (0%)
First incidence (days) | 614 | 731 (T) | 731 (T) | –
Poly-3 test | P = 0.077N | P = 0.206 | P = 0.533N | P = 0.239N
Uterus: Granular Cell Tumor Benign
Overall rate | 0/50 (0%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.9% | 0.0% | 0.0%
Terminal rate | 0/34 (0%) | 2/31 (7%) | 0/24 (0%) | 0/30 (0%)
First incidence (days) | – | 630 | – | –
Poly-3 test | P = 0.328N | P = 0.118 | – | –
Uterus: Stromal Polyp
Overall rate | 9/50 (18%) | 13/50 (26%) | 7/50 (14%) | 13/50 (26%)
Adjusted rate | 20.3% | 28.3% | 17.3% | 29.1%
Terminal rate | 6/34 (18%) | 6/31 (19%) | 6/24 (25%) | 9/30 (30%)
First incidence (days) | 614 | 409 | 589 | 491
Poly-3 test | P = 0.277 | P = 0.259 | P = 0.471N | P = 0.236
Uterus: Stromal Sarcoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.3% | 0.0% | 7.3% | 0.0%
Terminal rate | 0/34 (0%) | 0/31 (0%) | 1/24 (4%) | 0/30 (0%)
First incidence (days) | 579 | – | 516 | –
Poly-3 test | P = 0.495N | P = 0.505N | P = 0.280 | P = 0.503N
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 10/50 (20%) | 13/50 (26%) | 9/50 (18%) | 13/50 (26%)
Adjusted rate | 22.3% | 28.3% | 21.7% | 29.1%
Terminal rate | 6/34 (18%) | 6/31 (19%) | 6/24 (25%) | 9/30 (30%)
First incidence (days) | 579 | 409 | 516 | 491
Poly-3 test | P = 0.328 | P = 0.336 | P = 0.577N | P = 0.310
Uterus: Carcinoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 4.6% | 9.3% | 5.0% | 6.9%
Terminal rate | 2/34 (6%) | 2/31 (7%) | 2/24 (8%) | 1/30 (3%)
First incidence (days) | 731 (T) | 687 | 731 (T) | 687
Poly-3 test | P = 0.515 | P = 0.333 | P = 0.663 | P = 0.502
Uterus: Malignant Schwannoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate | 2.3% | 4.6% | 9.7% | 4.6%
Terminal rate | 0/34 (0%) | 0/31 (0%) | 0/24 (0%) | 1/30 (3%)
First incidence (days) | 635 | 418 | 528 | 633
Poly-3 test | P = 0.386 | P = 0.500 | P = 0.160 | P = 0.499
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 6.9% | 0.0% | 2.5% | 2.3%
Terminal rate | 3/34 (9%) | 0/31 (0%) | 1/24 (4%) | 1/30 (3%)
First incidence (days) | 731 (T) | – | 731 (T) | 731 (T)
Poly-3 test | P = 0.291N | P = 0.121N | P = 0.336N | P = 0.306N
All Organs: Malignant Lymphoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.3% | 2.3% | 7.4% | 2.3%
Terminal rate | 0/34 (0%) | 0/31 (0%) | 0/24 (0%) | 0/30 (0%)
First incidence (days) | 710 | 715 | 614 | 435
Poly-3 test | P = 0.570 | P = 0.758 | P = 0.281 | P = 0.758N
All Organs: Benign Neoplasms
Overall rate | 39/50 (78%) | 42/50 (84%) | 38/50 (76%) | 37/50 (74%)
Adjusted rate | 78.0% | 86.6% | 79.3% | 77.4%
Terminal rate | 23/34 (68%) | 25/31 (81%) | 17/24 (71%) | 22/30 (73%)
First incidence (days) | 253 | 409 | 361 | 491
Poly-3 test | P = 0.389N | P = 0.195 | P = 0.537 | P = 0.571N
All Organs: Malignant Neoplasms
Overall rate | 12/50 (24%) | 14/50 (28%) | 17/50 (34%) | 19/50 (38%)
Adjusted rate | 26.5% | 30.7% | 38.7% | 40.0%
Terminal rate | 7/34 (21%) | 6/31 (19%) | 4/24 (17%) | 8/30 (27%)
First incidence (days) | 579 | 137 | 516 | 435
Poly-3 test | P = 0.085 | P = 0.414 | P = 0.153 | P = 0.120
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 45/50 (90%) | 44/50 (88%) | 40/50 (80%)
Adjusted rate | 80.0% | 91.0% | 88.0% | 81.8%
Terminal rate | 24/34 (71%) | 27/31 (87%) | 18/24 (75%) | 23/30 (77%)
First incidence (days) | 253 | 137 | 361 | 435
Poly-3 test | P = 0.510N | P = 0.101 | P = 0.208 | P = 0.513

T = Terminal euthanasia

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, nose, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 15 | 18 | 26 | 15
Natural deaths | 1 | 1 | – | 4
Survivors
Died last week of study | – | – | – | 1
Terminal euthanasia | 34 | 31 | 24 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (2%) | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%)
Basophilic focus | 34 (68%) | 30 (60%) | 29 (58%) | 26 (52%)
Clear cell focus | 6 (12%) | 8 (16%) | 5 (10%) | 2 (4%)
Eosinophilic focus | 3 (6%) | 5 (10%) | 7 (14%) | 4 (8%)
Fatty change, diffuse | 1 (2%) | 1 (2%) | 2 (4%) | –
Hematopoietic cell proliferation | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%)
Hepatodiaphragmatic nodule | 3 (6%) | – | – | 2 (4%)
Infiltration cellular, lymphoid | – | 1 (2%) | – | –
Infiltration cellular, mixed cell | 6 (12%) | 6 (12%) | 3 (6%) | 3 (6%)
Mixed cell focus | – | 2 (4%) | – | 1 (2%)
Necrosis, multifocal | – | 1 (2%) | 2 (4%) | –
Pigmentation, hemosiderin | 1 (2%) | 1 (2%) | – | –
Bile duct, cyst | 2 (4%) | 1 (2%) | – | 1 (2%)
Bile duct, dilatation | – | 1 (2%) | – | –
Bile duct, hyperplasia | 8 (16%) | 12 (24%) | 15 (30%) | 10 (20%)
Centrilobular, degeneration | – | 1 (2%) | – | –
Kupffer cell, hyperplasia | – | – | 1 (2%) | –
Oval cell, hyperplasia | – | 1 (2%) | – | –
Mesentery | (8) | (10) | (4) | (4)
Fat, necrosis | 8 (100%) | 8 (80%) | 4 (100%) | 3 (75%)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Basophilic focus | – | 2 (4%) | 1 (2%) | 2 (4%)
Inflammation | – | – | 2 (4%) | –
Salivary glands | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | 3 (6%) | 5 (10%) | 3 (6%) | 1 (2%)
Mineralization | – | – | 1 (2%) | –
Ulcer | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Epithelium, erosion | – | 1 (2%) | – | –
Epithelium, hyperplasia | 3 (6%) | 6 (12%) | 3 (6%) | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Mineralization | – | – | 1 (2%) | –
Epithelium, necrosis | – | – | – | 1 (2%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | 1 (2%)
Media, hypertrophy | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 21 (42%) | 28 (56%) | 24 (48%) | 27 (54%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Amyloid deposition | – | – | 1 (2%) | –
Angiectasis | – | 2 (4%) | 1 (2%) | –
Degeneration, cystic | 12 (24%) | 7 (14%) | 12 (24%) | 12 (24%)
Hematopoietic cell proliferation | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Zona fasciculata, hyperplasia, focal | 3 (6%) | 2 (4%) | 7 (14%) | 7 (14%)
Zona fasciculata, hyperplasia, multifocal | 4 (8%) | 1 (2%) | – | 3 (6%)
Zona fasciculata, hypertrophy | 1 (2%) | – | – | –
Zona fasciculata, hypertrophy, focal | 17 (34%) | 9 (18%) | 13 (26%) | 15 (30%)
Zona fasciculata, hypertrophy, multifocal | 5 (10%) | 3 (6%) | 2 (4%) | 3 (6%)
Adrenal medulla | (50) | (50) | (49) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 4 (8%) | 2 (4%) | 1 (2%) | –
Parathyroid gland | (46) | (44) | (46) | (42)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, angiectasis, focal | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 18 (36%) | 16 (32%) | 24 (48%) | 18 (36%)
Pars intermedia, hyperplasia | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 20 (40%) | 27 (54%) | 22 (44%) | 16 (32%)
Follicular cell, hyperplasia | 2 (4%) | 4 (8%) | 1 (2%) | 2 (4%)
Follicular cell, hypertrophy | – | – | 2 (4%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (50) | (50) | (49)
Ectasia | 1 (2%) | 2 (4%) | 2 (4%) | –
Inflammation | – | 2 (4%) | – | –
Ovary | (50) | (50) | (50) | (50)
Atrophy | 27 (54%) | 22 (44%) | 25 (50%) | 27 (54%)
Cyst | 18 (36%) | 16 (32%) | 20 (40%) | 23 (46%)
Germinal epithelium, hyperplasia | – | – | – | 1 (2%)
Thecal cell, hyperplasia | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenomyosis | – | 1 (2%) | – | –
Adenomyosis, focal | 2 (4%) | – | – | –
Angiectasis, focal | – | – | – | 1 (2%)
Fibrosis, focal | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Cervix, cyst, squamous | – | 1 (2%) | – | –
Cervix, hyperplasia, squamous | 7 (14%) | 5 (10%) | 8 (16%) | 10 (20%)
Cervix, hypertrophy, stromal | – | – | 2 (4%) | 1 (2%)
Endometrial glands, hyperplasia, atypical | – | 1 (2%) | – | –
Endometrial glands, hyperplasia, focal | – | – | – | 1 (2%)
Endometrium, decidual reaction, focal | – | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 24 (48%) | 16 (32%) | 17 (34%) | 25 (50%)
Endometrium, hyperplasia, focal | – | – | 3 (6%) | 1 (2%)
Endometrium, metaplasia, squamous | 5 (10%) | 1 (2%) | 7 (14%) | 6 (12%)
Serosa, cyst multilocular | 1 (2%) | – | – | –
Vagina | (0) | (1) | (2) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Myeloid cell, hyperplasia | 12 (24%) | 19 (38%) | 20 (40%) | 36 (72%)
Lymph node | (1) | (3) | (2) | (5)
Axillary, hyperplasia, lymphoid | – | – | – | 1 (20%)
Deep cervical, infiltration cellular, plasma cell | – | – | – | 2 (40%)
Iliac, infiltration cellular, plasma cell | – | – | 1 (50%) | –
Lumbar, ectasia | 1 (100%) | – | – | –
Lumbar, infiltration cellular, plasma cell | – | – | 1 (50%) | 1 (20%)
Popliteal, inflammation | – | 1 (33%) | – | –
Renal, infiltration cellular, plasma cell | – | – | – | 1 (20%)
Lymph node, bronchial | (43) | (44) | (43) | (42)
Lymph node, mandibular | (46) | (48) | (45) | (48)
Ectasia | – | – | 1 (2%) | 1 (2%)
Hyperplasia, atypical | – | 1 (2%) | – | –
Infiltration cellular, plasma cell | – | 1 (2%) | – | 2 (4%)
Lymph node, mediastinal | (44) | (47) | (48) | (50)
Atrophy | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Infiltration cellular, plasma cell | – | 1 (2%) | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Atrophy | – | 2 (4%) | 2 (4%) | 5 (10%)
Fibrosis, focal | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | –
Infiltration cellular, plasma cell | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 37 (74%) | 40 (80%) | 38 (76%) | 39 (78%)
Pigmentation, hemosiderin | 42 (84%) | 39 (78%) | 38 (76%) | 39 (78%)
Capsule, thrombosis | – | 1 (2%) | – | –
Lymphoid follicle, atrophy | 12 (24%) | 6 (12%) | 5 (10%) | 7 (14%)
Lymphoid follicle, hyperplasia | – | 1 (2%) | – | –
Thymus | (49) | (50) | (49) | (50)
Atrophy | 45 (92%) | 42 (84%) | 45 (92%) | 49 (98%)
Cyst | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | 2 (4%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 4 (8%) | 4 (8%) | 2 (4%) | 1 (2%)
Hyperplasia | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Duct, dilatation | – | – | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | 1 (2%) | – | –
Dermis, thrombosis | 1 (2%) | – | – | –
Dorsal, inflammation, acute | – | – | – | 1 (2%)
Ear, inflammation, acute | 1 (2%) | 2 (4%) | – | –
Ear, inflammation, chronic active | – | 1 (2%) | – | –
Ear, ulcer, multifocal | – | 1 (2%) | – | –
Ear, epidermis, hyperplasia | – | 1 (2%) | – | –
Epidermis, hyperplasia | – | 1 (2%) | – | 1 (2%)
Epidermis, ulcer, multifocal | 1 (2%) | – | – | 1 (2%)
Foot, inflammation, chronic active | – | – | – | 4 (8%)
Foot, ulcer, focal | – | – | – | 4 (8%)
Inguinal, inflammation, pyogranulomatous | – | 1 (2%) | – | 2 (4%)
Inguinal, inflammation, acute | – | – | – | 1 (2%)
Lateral, inflammation, acute | – | 1 (2%) | – | –
Lateral, ulcer, focal | – | 1 (2%) | – | –
Neck, inflammation, chronic active | 1 (2%) | – | – | –
Neck, ulcer, diffuse | 1 (2%) | – | – | –
Other, inflammation, multifocal | 1 (2%) | – | – | –
Subcutaneous tissue, abscess | – | 1 (2%) | – | –
Tail, inflammation, chronic active | – | 1 (2%) | – | –
Tail, ulcer, multifocal | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosclerosis | – | – | 1 (2%) | 1 (2%)
Tarsal, tendon, inflammation | – | – | 1 (2%) | –
Skeletal muscle | (3) | (7) | (5) | (5)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | – | –
Choroid plexus, hyperplasia | – | – | 1 (2%) | –
Peripheral nerve | (3) | (5) | (5) | (5)
Spinal cord | (3) | (5) | (5) | (5)
Gliosis | – | 1 (20%) | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | – | 1 (2%) | –
Inflammation, chronic active | 4 (8%) | 2 (4%) | 4 (8%) | 25 (50%)
Respiratory epithelium, hyperplasia | – | – | – | 2 (4%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 35 (70%)
Respiratory epithelium, regeneration | – | – | – | 2 (4%)
Squamous epithelium, hyperplasia | 1 (2%) | 1 (2%) | 6 (12%) | 48 (96%)
Squamous epithelium, ulcer, focal | – | – | – | 5 (10%)
Squamous epithelium, ulcer, multifocal | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | – | 3 (6%)
Inflammation, granulomatous | 2 (4%) | 1 (2%) | 3 (6%) | 13 (26%)
Inflammation, chronic active | 2 (4%) | – | – | –
Thrombus | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Alveolar epithelium, hyperplasia, focal | 1 (2%) | 1 (2%) | | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 13 (26%) | 11 (22%) | 10 (20%) | 32 (64%)
Bronchiole, epithelium, hyperplasia | – | – | 8 (16%) | 39 (78%)
Bronchus, epithelium, atrophy | – | – | – | 7 (14%)
Bronchus, epithelium, hyperplasia | – | – | – | 46 (92%)
Bronchus, epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Bronchus, epithelium, necrosis | – | – | – | 1 (2%)
Bronchus, epithelium, regeneration | – | – | 1 (2%) | 2 (4%)
Bronchus, submucosa, inflammation, suppurative | – | – | – | 1 (2%)
Bronchus, submucosa, necrosis | – | – | – | 1 (2%)
Interstitium, fibrosis | 1 (2%) | 1 (2%) | 1 (2%) | 9 (18%)
Peribronchial, inflammation, chronic active | 1 (2%) | 2 (4%) | – | 27 (54%)
Pleura, fibrosis | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Inflammation, suppurative | 4 (8%) | 3 (6%) | 11 (22%) | 49 (98%)
Lamina propria, fibrosis | 1 (2%) | 1 (2%) | 17 (34%) | 46 (92%)
Olfactory epithelium, accumulation, hyaline droplet | 5 (10%) | 10 (20%) | 3 (6%) | 1 (2%)
Olfactory epithelium, atrophy | 1 (2%) | 1 (2%) | 14 (28%) | 24 (48%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | – | 18 (36%) | 46 (92%)
Olfactory epithelium, necrosis | – | – | – | 4 (8%)
Respiratory epithelium, hyperplasia | 1 (2%) | – | 2 (4%) | 44 (88%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | – | 1 (2%) | 44 (88%)
Respiratory epithelium, necrosis | – | – | – | 3 (6%)
Turbinate, hyperostosis | – | – | – | 8 (16%)
Trachea | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | – | 20 (40%)
Epithelium, atrophy | – | – | – | 4 (8%)
Epithelium, hyperplasia | – | – | – | 30 (60%)
Epithelium, metaplasia, squamous | – | – | – | 3 (6%)
Epithelium, necrosis | – | – | – | 1 (2%)
Epithelium, regeneration | – | – | – | 3 (6%)
Epithelium, ulcer | – | – | – | 1 (2%)
Submucosa, fibrosis | – | – | – | 19 (38%)
Submucosa, necrosis | – | – | – | 1 (2%)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Retinal detachment | – | – | 1 (2%) | –
Anterior chamber, inflammation, suppurative | 1 (2%) | – | 6 (12%) | 5 (10%)
Cornea, inflammation, chronic active | 2 (4%) | 6 (12%) | 23 (46%) | 31 (62%)
Cornea, mineralization | – | 1 (2%) | – | 2 (4%)
Cornea, necrosis | – | – | 1 (2%) | –
Cornea, endothelium, rupture | – | 1 (2%) | – | 1 (2%)
Cornea, epithelium, hyperplasia | – | 3 (6%) | 8 (16%) | 5 (10%)
Cornea, epithelium, ulcer | – | 1 (2%) | 2 (4%) | 13 (26%)
Iris, inflammation, acute | – | – | 5 (10%) | 4 (8%)
Lens, cataract | 1 (2%) | 1 (2%) | 6 (12%) | 9 (18%)
Retina, degeneration | 10 (20%) | 7 (14%) | 11 (22%) | 15 (30%)
Unilateral, phthisis bulbi | – | 1 (2%) | – | 8 (16%)
Harderian gland | (50) | (50) | (50) | (50)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | 1 (2%) | 2 (4%) | –
Calculus gross observation | – | 1 (2%) | 1 (2%) | –
Calculus microscopic observation only | 27 (54%) | 29 (58%) | 35 (70%) | 27 (54%)
Infarct | 1 (2%) | – | 2 (4%) | –
Nephropathy | 12 (24%) | 11 (22%) | 10 (20%) | 11 (22%)
Thrombosis | – | 1 (2%) | – | –
Cortex, cyst | 1 (2%) | – | 2 (4%) | –
Papilla, necrosis | – | 1 (2%) | –
Pelvis, dilatation | – | 2 (4%) | – | 2 (4%)
Pelvis, inflammation | 5 (10%) | 8 (16%) | 6 (12%) | 6 (12%)
Renal tubule, dilatation | – | 1 (2%) | – | –
Renal tubule, necrosis | – | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Calculus gross observation | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.