# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of 2,3-Butanedione

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths | – | – | – | –
Moribund | 12 | 11 | 15 | 18
Natural deaths | 2 | 2 | 2 | 10
Survivors | – | – | – | –
Died last week of study | – | 1 | – | –
Terminal euthanasia | 36 | 36 | 33 | 22
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Intestine small, ileum | (50) | (50) | (50) | (50)
Carcinoid tumor benign | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Leiomyoma | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | – | –
Hepatocellular adenoma | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Mesentery | (5) | (4) | (3) | (2)
Carcinosarcoma, metastatic, prostate | 1 (20%) | | – | –
Hemangiosarcoma | – | 1 (25%) | – | –
Fat, liposarcoma, metastatic, kidney | – | 1 (25%) | – | –
Oral mucosa | (1) | (1) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | 1 (100%)
Pancreas | (50) | (50) | (50) | (50)
Acinus, carcinosarcoma, metastatic, prostate | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Sarcoma | – | – | 1 (2%) | –
Squamous cell carcinoma | – | – | 1 (2%) | –
Squamous cell papilloma | – | 1 (2%) | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Neural crest tumor, metastatic, ear | – | – | 1 (2%) | –
Schwannoma malignant | – | 2 (4%) | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 1 (2%) | 3 (6%) | 1 (2%) | 3 (6%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Parathyroid gland | (49) | (46) | (49) | (47)
Adenoma | 1 (2%) | – | – | –
Bilateral, adenoma | – | 1 (2%) | – | –
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 9 (18%) | 14 (28%) | 9 (18%) | 5 (10%)
Pars intermedia, adenoma | 2 (4%) | 1 (2%) | – | 1 (2%)
Pars nervosa, schwannoma malignant | – | – | – | 1 (2%)
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, C-cell, adenoma | 1 (2%) | – | – | –
C-cell, adenoma | 5 (10%) | 5 (10%) | 3 (6%) | 1 (2%)
C-cell, adenoma, multiple | – | – | 1 (2%) | –
C-cell, carcinoma | – | 1 (2%) | 1 (2%) | –
Follicular cell, adenoma | 2 (4%) | 1 (2%) | 2 (4%) | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinosarcoma | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | 3 (6%) | 3 (6%) | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (6) | (4) | (9) | (7)
Lymph node, bronchial | (41) | (46) | (43) | (42)
Lymph node, mandibular | (48) | (44) | (49) | (48)
Squamous cell carcinoma, metastatic, skin | – | – | – | 1 (2%)
Lymph node, mediastinal | (42) | (47) | (47) | (47)
Hemangiosarcoma | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, thymus | – | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangioma | – | – | 1 (2%) | 1 (2%)
Hemangiosarcoma | 2 (4%) | – | 1 (2%) | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Thymus | (47) | (48) | (48) | (48)
Schwannoma malignant | – | – | 1 (2%) | –
Thymoma benign | 1 (2%) | – | 1 (2%) | –
Integumentary System | | | | –
Mammary gland | (12) | (9) | (14) | (22)
Carcinoma | 1 (8%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Trichoepithelioma | – | 1 (2%) | – | –
Epidermis, basal cell carcinoma | – | 1 (2%) | – | –
Epidermis, keratoacanthoma | 3 (6%) | 2 (4%) | 1 (2%) | –
Epidermis, pilomatrixoma | – | – | 1 (2%) | –
Epidermis, squamous cell carcinoma | – | – | 1 (2%) | 1 (2%)
Epidermis, squamous cell papilloma | – | 1 (2%) | – | –
Sebaceous gland, adenoma | 1 (2%) | – | – | –
Subcutaneous tissue, fibrosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, hemangioma | – | – | 1 (2%) | –
Subcutaneous tissue, myxoma | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (6) | (3) | (4) | (6)
Hemangiosarcoma | – | – | 1 (25%) | –
Squamous cell carcinoma, metastatic, oral mucosa | – | 1 (33%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | 1 (2%) | 1 (2%) | 1 (2%) | –
Granular cell tumor benign | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Granular cell tumor malignant | 1 (2%) | – | – | –
Squamous cell carcinoma, metastatic, oral mucosa | – | 1 (2%) | – | –
Peripheral nerve | (6) | (1) | (3) | (6)
Spinal cord | (6) | (1) | (3) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (49) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | – | – | 1 (2%)
Carcinosarcoma, metastatic, prostate | 1 (2%) | – | – | –
Neural crest tumor, metastatic, ear | – | – | 1 (2%) | –
Mediastinum, schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Squamous cell carcinoma | – | – | – | 3 (6%)
Squamous cell papilloma | – | – | – | 1 (2%)
Pleura | (0) | (1) | (0) | (0)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Neural crest tumor | – | – | 1 (100%) | –
Eye | (50) | (50) | (49) | (49)
Schwannoma malignant, metastatic, Harderian gland | – | 1 (2%) | – | –
Retina, melanoma malignant | – | 1 (2%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Schwannoma malignant | – | 1 (2%) | – | –
Lacrimal gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Liposarcoma | – | 1 (2%) | – | –
Ureter | (0) | (1) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 1 (2%) | – | –
Lymphoma malignant | 3 (6%) | – | 3 (6%) | 1 (2%)
Mesothelioma malignant | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 35 | 36 | 30 | 22
Total primary neoplasms | 53 | 57 | 39 | 27
Total animals with benign neoplasms | 27 | 30 | 22 | 16
Total benign neoplasms | 39 | 41 | 24 | 16
Total animals with malignant neoplasms | 13 | 12 | 13 | 11
Total malignant neoplasms | 14 | 16 | 13 | 11
Total animals with metastatic neoplasms | 1 | 4 | 2 | 1
Total metastatic neoplasms | 3 | 11 | 3 | 1
Total animals with uncertain neoplasms-benign or malignant | – | – | 2 | –
Total uncertain neoplasms | – | – | 2 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of 2,3-Butanedione

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 1/50 (2%) | 3/50 (6%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate^b^ | 2.3% | 6.6% | 2.3% | 7.5%
Terminal rate^c^ | 0/36 (0%) | 3/37 (8%) | 1/33 (3%) | 1/22 (5%)
First incidence (days) | 724 | 729 (T) | 729 (T) | 628
Poly-3 test^d^ | P = 0.266 | P = 0.311 | P = 0.754 | P = 0.267
Brain: Benign Granular Cell Tumor
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 6.8% | 4.4% | 4.6% | 2.5%
Terminal rate | 3/36 (8%) | 0/37 (0%) | 1/33 (3%) | 0/22 (0%)
First incidence (days) | 729 (T) | 603 | 722 | 499
Poly-3 test | P = 0.267N | P = 0.486N | P = 0.514N | P = 0.343N
Nose: Squamous Cell Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 7.5%
Terminal rate | 0/36 (0%) | 0/37 (0%) | 0/33 (0%) | 1/22 (5%)
First incidence (days) | –e | – | – | 616
Poly-3 test | P = 0.010 | –f | – | P = 0.101
Nose: Squamous Cell Papilloma or Squamous Cell Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 9.9%
Terminal rate | 0/36 (0%) | 0/37 (0%) | 0/33 (0%) | 1/22 (5%)
First incidence (days) | – | – | – | 589
Poly-3 test | P = 0.002 | – | – | P = 0.049
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 9/50 (18%) | 14/50 (28%) | 9/50 (18%) | 5/50 (10%)
Adjusted rate | 19.4% | 29.7% | 19.3% | 12.4%
Terminal rate | 4/36 (11%) | 7/37 (19%) | 1/33 (3%) | 2/22 (9%)
First incidence (days) | 379 | 600 | 527 | 616
Poly-3 test | P = 0.141N | P = 0.179 | P = 0.598N | P = 0.277N
Skin: Keratoacanthoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 6.8% | 4.4% | 2.3% | 0.0%
Terminal rate | 3/36 (8%) | 2/37 (5%) | 1/33 (3%) | 0/22 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.073N | P = 0.492N | P = 0.316N | P = 0.141N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 6.8% | 6.6% | 2.3% | 0.0%
Terminal rate | 3/36 (8%) | 3/37 (8%) | 1/33 (3%) | 0/22 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.065N | P = 0.655N | P = 0.316N | P = 0.141N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 6.8% | 6.6% | 4.7% | 2.5%
Terminal rate | 3/36 (8%) | 3/37 (8%) | 2/33 (6%) | 0/22 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 628
Poly-3 test | P = 0.231N | P = 0.655N | P = 0.514N | P = 0.346N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Trichoepithelioma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 6.8% | 11.1% | 4.7% | 2.5%
Terminal rate | 3/36 (8%) | 5/37 (14%) | 2/33 (6%) | 0/22 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 628
Poly-3 test | P = 0.173N | P = 0.365 | P = 0.514N | P = 0.346N
Testes: Adenoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 6.7% | 6.6% | 0.0% | 2.5%
Terminal rate | 2/36 (6%) | 3/37 (8%) | 0/33 (0%) | 1/22 (5%)
First incidence(days) | 694 | 729 (T) | – | 729 (T)
Poly-3 test | P = 0.152N | P = 0.656N | P = 0.125N | P = 0.350N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 13.4% | 11.1% | 9.3% | 2.5%
Terminal rate | 4/36 (11%) | 5/37 (14%) | 3/33 (9%) | 1/22 (5%)
First incidence (days) | 654 | 729 (T) | 715 | 729 (T)
Poly-3 test | P = 0.059N | P = 0.495N | P = 0.394N | P = 0.079N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 5/50 (10%) | 1/50 (2%)
Adjusted rate | 13.4% | 13.1% | 11.6% | 2.5%
Terminal rate | 4/36 (11%) | 5/37 (14%) | 4/33 (12%) | 1/22 (5%)
First incidence (days) | 654 | 586 | 715 | 729 (T)
Poly-3 test | P = 0.064N | P = 0.608N | P = 0.528N | P = 0.079N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 6.8% | 4.4% | 4.7% | 0.0%
Terminal rate | 3/36 (8%) | 2/37 (5%) | 2/33 (6%) | 0/22 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.106N | P = 0.492N | P = 0.514N | P = 0.141N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 9.0% | 4.4% | 9.3% | 2.5%
Terminal rate | 3/36 (8%) | 2/37 (5%) | 4/33 (12%) | 0/22 (0%)
First incidence (days) | 695 | 729 (T) | 729 (T) | 710
Poly-3 test | P = 0.232N | P = 0.331N | P = 0.625 | P = 0.217N
All Organs: Malignant Lymphoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 6.6% | 0.0% | 6.8% | 2.5%
Terminal rate | 1/36 (3%) | 0/37 (0%) | 1/33 (3%) | 0/22 (0%)
First incidence (days) | 523 | – | 325 | 626
Poly-3 test | P = 0.412N | P = 0.121N | P = 0.650 | P = 0.356N
All Organs: Benign Neoplasms
Overall rate | 27/50 (54%) | 30/50 (60%) | 22/50 (44%) | 16/50 (32%)
Adjusted rate | 56.7% | 61.7% | 47.0% | 37.5%
Terminal rate | 17/36 (47%) | 19/37 (51%) | 12/33 (36%) | 7/22 (32%)
First incidence (days) | 379 | 586 | 527 | 499
Poly-3 test | P = 0.017N | P = 0.384 | P = 0.228N | P = 0.049N
All Organs: Malignant Neoplasms
Overall rate | 13/50 (26%) | 12/50 (24%) | 13/50 (26%) | 11/50 (22%)
Adjusted rate | 27.7% | 25.9% | 28.8% | 25.8%
Terminal rate | 8/36 (22%) | 8/37 (22%) | 8/33 (24%) | 2/22 (9%)
First incidence (days) | 432 | 586 | 325 | 549
Poly-3 test | P = 0.494N | P = 0.514N | P = 0.546 | P = 0.515N
All Organs: Benign or Malignant Neoplasms
Overall rate | 35/50 (70%) | 36/50 (72%) | 30/50 (60%) | 22/50 (44%)
Adjusted rate | 70.0% | 73.5% | 61.3% | 49.3%
Terminal rate | 21/36 (58%) | 24/37 (65%) | 16/33 (49%) | 8/22 (36%)
First incidence (days) | 379 | 586 | 325 | 499
Poly-3 test | P = 0.010N | P = 0.438 | P = 0.242N | P = 0.028N

T = Terminal euthanasia

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, brain, nose, pituitary gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of 2,3-Butanedione^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 12 | 11 | 15 | 18
Natural deaths | 2 | 2 | 2 | 10
Survivors
Died last week of study | – | 1 | – | –
Terminal euthanasia | 36 | 36 | 33 | 22
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Metaplasia, squamous | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 2 (4%) | 6 (12%) | 1 (2%)
Basophilic focus | 12 (24%) | 16 (32%) | 18 (36%) | 4 (8%)
Clear cell focus | 27 (54%) | 21 (42%) | 27 (54%) | 12 (24%)
Degeneration, cystic | 1 (2%) | – | 2 (4%) | –
Eosinophilic focus | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Fatty change, focal | 2 (4%) | – | 1 (2%) | –
Fatty change, diffuse | 1 (2%) | – | – | –
Hematopoietic cell proliferation | 2 (4%) | – | 1 (2%) | 1 (2%)
Hepatodiaphragmatic nodule | 1 (2%) | – | 3 (6%) | 3 (6%)
Infiltration cellular, lymphocyte | 1 (2%) | – | – | –
Infiltration cellular, mixed cell | 5 (10%) | – | 5 (10%) | 4 (8%)
Mixed cell focus | 2 (4%) | 4 (8%) | 1 (2%) | –
Necrosis, focal | 1 (2%) | 1 (2%) | 1 (2%) | –
Pigmentation, hemosiderin | – | 1 (2%) | 1 (2%) | –
Tension lipidosis | – | – | 1 (2%) | –
Bile duct, cyst | – | 2 (4%) | – | 1 (2%)
Bile duct, dilatation | – | – | – | 1 (2%)
Bile duct, hyperplasia | 5 (10%) | 3 (6%) | 4 (8%) | 1 (2%)
Centrilobular, necrosis | 1 (2%) | – | – | –
Serosa, fibrosis | – | 1 (2%) | – | –
Mesentery | (5) | (4) | (3) | (2)
Fat, necrosis | 3 (60%) | 2 (50%) | 2 (67%) | 2 (100%)
Oral mucosa | (1) | (1) | (0) | (0)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 7 (14%) | 2 (4%) | 4 (8%)
Basophilic focus | – | 1 (2%) | – | –
Inflammation | – | – | – | 1 (2%)
Acinus, hyperplasia | 1 (2%) | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Basophilic focus | – | – | – | 1 (2%)
Inflammation | – | 1 (2%) | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | 4 (8%) | –
Ulcer | – | – | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | 3 (6%) | 4 (8%) | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 2 (4%)
Mineralization | – | 1 (2%) | 1 (2%) | –
Aorta, mineralization | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 31 (62%) | 38 (76%) | 28 (56%) | 25 (50%)
Inflammation, suppurative | – | – | 1 (2%) | –
Epicardium, fibrosis, focal | – | – | – | 1 (2%)
Septum interventricular, necrosis, acute | 1 (2%) | – | – | –
Valve, degeneration | – | 1 (2%) | – | –
Valve, inflammation, chronic | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Degeneration, cystic | 2 (4%) | 2 (4%) | 2 (4%) | 2 (4%)
Hematopoietic cell proliferation | – | – | 2 (4%) | –
Infiltration cellular, lipocyte | – | – | – | 1 (2%)
Bilateral, necrosis, multifocal | – | – | – | 1 (2%)
Zona fasciculata, hyperplasia | 2 (4%) | – | – | –
Zona fasciculata, hyperplasia, focal | 4 (8%) | 4 (8%) | 3 (6%) | 6 (12%)
Zona fasciculata, hyperplasia, multifocal | – | 2 (4%) | 1 (2%) | –
Zona fasciculata, hypertrophy | 3 (6%) | 2 (4%) | – | –
Zona fasciculata, hypertrophy, focal | 12 (24%) | 12 (24%) | 11 (22%) | 6 (12%)
Zona fasciculata, hypertrophy, multifocal | 14 (28%) | 9 (18%) | 18 (36%) | 11 (22%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 2 (4%) | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 1 (2%) | 5 (10%) | 2 (4%)
Parathyroid gland | (49) | (46) | (49) | (47)
Hyperplasia, focal | 1 (2%) | 1 (2%) | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 16 (32%) | 18 (36%) | 23 (46%) | 10 (20%)
Pars intermedia, hyperplasia | 1 (2%) | 3 (6%) | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 8 (16%) | 13 (26%) | 8 (16%) | 2 (4%)
Follicular cell, hyperplasia | 4 (8%) | 2 (4%) | 1 (2%) | 1 (2%)
Follicular cell, hypertrophy | 2 (4%) | 2 (4%) | 5 (10%) | 5 (10%)
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | 1 (2%) | 1 (2%) | – | –
Inflammation | – | – | – | 1 (2%)
Preputial gland | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Prostate | (50) | (50) | (50) | (50)
Inflammation | 21 (42%) | 18 (36%) | 18 (36%) | 12 (24%)
Epithelium, ventral, hyperplasia | 9 (18%) | 9 (18%) | 7 (14%) | 10 (20%)
Seminal vesicle | (50) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Edema | 4 (8%) | 2 (4%) | – | –
Germinal epithelium, degeneration | 5 (10%) | 10 (20%) | 4 (8%) | 4 (8%)
Interstitial cell, hyperplasia | 4 (8%) | 1 (2%) | 3 (6%) | 1 (2%)
Rete testes, inflammation, granulomatous | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Myeloid cell, hyperplasia | 15 (30%) | 12 (24%) | 16 (32%) | 32 (64%)
Lymph node | (6) | (4) | (9) | (7)
Axillary, infiltration cellular, plasma cell | 1 (17%) | – | 1 (11%) | –
Deep cervical, infiltration cellular, plasma cell | – | – | – | 1 (14%)
Iliac, ectasia | – | 1 (25%) | – | –
Iliac, infiltration cellular, plasma cell | – | – | – | 2 (29%)
Inguinal, infiltration cellular, plasma cell | 1 (17%) | – | – | –
Lumbar, ectasia | – | – | 1 (11%) | –
Lumbar, hyperplasia, lymphoid | 1 (17%) | – | – | –
Lumbar, infiltration cellular, plasma cell | 5 (83%) | 3 (75%) | 6 (67%) | 3 (43%)
Pancreatic, inflammation | – | – | 1 (11%) | –
Popliteal, hyperplasia, lymphoid | 1 (17%) | – | 2 (22%) | –
Popliteal, infiltration cellular, plasma cell | – | – | 4 (44%) | 2 (29%)
Popliteal, inflammation, chronic active | 1 (17%) | – | – | –
Renal, ectasia | – | – | – | 1 (14%)
Renal, infiltration cellular, plasma cell | 2 (33%) | 1 (25%) | 1 (11%) | 4 (57%)
Lymph node, bronchial | (41) | (46) | (43) | (42)
Atrophy | – | 1 (2%) | 2 (5%) | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Lymph node, mandibular | (48) | (44) | (49) | (48)
Ectasia | – | – | – | 1 (2%)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Infiltration cellular, plasma cell | – | – | – | 5 (10%)
Lymph node, mediastinal | (42) | (47) | (47) | (47)
Atrophy | 1 (2%) | – | – | 1 (2%)
Ectasia | 1 (2%) | – | – | –
Infiltration cellular, plasma cell | – | – | 1 (2%) | –
Inflammation | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Ectasia | – | 1 (2%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
Cyst | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 41 (82%) | 41 (82%) | 36 (72%) | 37 (74%)
Inflammation | – | – | 1 (2%) | –
Pigmentation, hemosiderin | 18 (36%) | 22 (44%) | 20 (40%) | 20 (40%)
Lymphoid follicle, atrophy | 6 (12%) | 5 (10%) | 4 (8%) | 12 (24%)
Thymus | (47) | (48) | (48) | (48)
Atrophy | 46 (98%) | 47 (98%) | 45 (94%) | 47 (98%)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | 2 (4%) | 1 (2%) | –
Integumentary System
Mammary gland | (12) | (9) | (14) | (22)
Galactocele | – | – | 1 (7%) | 1 (5%)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | – | – | 2 (4%)
Dorsal, inflammation, chronic active | – | – | 1 (2%) | –
Dorsal, ulcer, focal | – | – | 1 (2%) | –
Epidermis, cyst | – | – | 1 (2%) | –
Epidermis, hyperplasia | 2 (4%) | – | – | –
Foot, inflammation, acute | 3 (6%) | – | – | 1 (2%)
Foot, inflammation, chronic active | 11 (22%) | 7 (14%) | 17 (34%) | 23 (46%)
Foot, ulcer | 14 (28%) | 7 (14%) | 17 (34%) | 22 (44%)
Inguinal, inflammation, granulomatous | – | – | 1 (2%) | –
Inguinal, ulcer, focal | – | – | 1 (2%) | –
Prepuce, inflammation, acute | 1 (2%) | – | – | –
Prepuce, ulcer, focal | 1 (2%) | – | – | –
Tail, cyst epithelial inclusion | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | – | – | 1 (2%) | –
Osteosclerosis | – | – | – | 1 (2%)
Skeletal muscle | (6) | (3) | (4) | (6)
Nervous System
Brain | (50) | (50) | (50) | (50)
Cerebrum, gray matter, hemorrhage, focal | 1 (2%) | – | – | 1 (2%)
Cranial nerve, glial cell, hyperplasia | 1 (2%) | 1 (2%) | – | –
Peripheral nerve | (6) | (1) | (3) | (6)
Axon, degeneration | – | – | – | 1 (17%)
Spinal cord | (6) | (1) | (3) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | 2 (4%) | – | – | –
Inflammation, chronic active | 14 (28%) | 7 (14%) | 7 (14%) | 33 (66%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | – | 45 (90%)
Squamous epithelium, hyperplasia | 2 (4%) | 2 (4%) | 8 (16%) | 46 (92%)
Squamous epithelium, ulcer, focal | – | – | – | 15 (30%)
Squamous epithelium, ulcer, multifocal | – | – | – | 3 (6%)
Lung | (50) | (49) | (50) | (50)
Inflammation, suppurative | – | – | 1 (2%) | 15 (30%)
Inflammation, granulomatous | 4 (8%) | 3 (6%) | 1 (2%) | 4 (8%)
Inflammation, chronic active | 1 (2%) | 2 (4%) | – | –
Metaplasia, osseous | – | 1 (2%) | – | –
Thrombus | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 1 (2%) | 4 (8%) | 2 (4%) | 8 (16%)
Alveolar epithelium, hyperplasia, focal | 3 (6%) | 3 (6%) | 5 (10%) | 1 (2%)
Alveolus, edema | – | – | – | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 10 (20%) | 14 (29%) | 16 (32%) | 34 (68%)
Bronchiole, epithelium, hyperplasia | – | – | – | 33 (66%)
Bronchus, epithelium, atrophy | – | – | 1 (2%) | 23 (46%)
Bronchus, epithelium, hyperplasia | – | – | 2 (4%) | 47 (94%)
Bronchus, epithelium, metaplasia, squamous | – | – | – | 2 (4%)
Bronchus, epithelium, regeneration | – | – | 4 (8%) | 9 (18%)
Bronchus, submucosa, fibrosis | – | – | – | 5 (10%)
Interstitium, fibrosis | | 1 (2%) | 1 (2%) | 11 (22%)
Peribronchial, inflammation, chronic active | – | – | – | 13 (26%)
Pleura, fibrosis | – | – | – | 2 (4%)
Pleura, fibrosis, focal | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | 1 (2%) | 2 (4%) | –
Inflammation, suppurative | 3 (6%) | 4 (8%) | 35 (70%) | 50 (100%)
Inflammation, chronic active | 1 (2%) | – | 2 (4%) | –
Polyp, inflammatory | 1 (2%) | – | – | –
Lamina propria, fibrosis | – | – | 28 (56%) | 38 (76%)
Nerve, hyperplasia | – | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 10 (20%) | 6 (12%) | 4 (8%) | 4 (8%)
Olfactory epithelium, atrophy | – | 5 (10%) | 27 (54%) | 22 (44%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | 3 (6%) | 6 (12%) | 50 (100%)
Olfactory epithelium, necrosis | – | – | – | 6 (12%)
Respiratory epithelium, hyperplasia | – | 2 (4%) | 5 (10%) | 50 (100%)
Respiratory epithelium, metaplasia, squamous | – | – | 5 (10%) | 34 (68%)
Respiratory epithelium, necrosis | – | – | – | 2 (4%)
Turbinate, atrophy | – | – | 1 (2%) | 1 (2%)
Turbinate, hyperostosis | – | – | – | 10 (20%)
Pleura | (0) | (1) | (0) | (0)
Trachea | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | 8 (16%)
Epithelium, atrophy | – | – | – | 7 (14%)
Epithelium, hyperplasia | – | – | 1 (2%) | 32 (64%)
Epithelium, metaplasia, squamous | – | – | – | 12 (24%)
Epithelium, necrosis | – | – | – | 6 (12%)
Epithelium, regeneration | – | – | 5 (10%) | 12 (24%)
Submucosa, fibrosis | – | – | – | 27 (54%)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (50) | (50) | (49) | (49)
Anterior chamber, inflammation, suppurative | – | 1 (2%) | 6 (12%) | 3 (6%)
Bilateral, phthisis bulbi | – | – | 1 (2%) | –
Cornea, inflammation, chronic active | 1 (2%) | 6 (12%) | 16 (33%) | 28 (57%)
Cornea, mineralization | 1 (2%) | 4 (8%) | 1 (2%) | –
Cornea, necrosis | – | – | – | 2 (4%)
Cornea, epithelium, hyperplasia | – | 2 (4%) | 3 (6%) | 6 (12%)
Cornea, epithelium, ulcer | – | 1 (2%) | 4 (8%) | 6 (12%)
Iris, inflammation, acute | – | 1 (2%) | 3 (6%) | 1 (2%)
Lens, cataract | 1 (2%) | 5 (10%) | 6 (12%) | 3 (6%)
Retina, degeneration | 8 (16%) | 11 (22%) | 11 (22%) | 6 (12%)
Unilateral, inflammation, pyogranulomatous | – | – | – | 1 (2%)
Unilateral, phthisis bulbi | – | 1 (2%) | 3 (6%) | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | 3 (6%)
Metaplasia | 1 (2%) | – | – | –
Lacrimal gland | (0) | (0) | (0) | (1)
Metaplasia | – | – | – | 1 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Calculus microscopic observation only | 4 (8%) | 10 (20%) | 2 (4%) | 7 (14%)
Fibrosis, focal | – | – | 1 (2%) | –
Infarct | 1 (2%) | 1 (2%) | 1 (2%) | –
Infiltration cellular, lymphoid | – | – | 1 (2%) | –
Nephropathy | 33 (66%) | 40 (80%) | 41 (82%) | 30 (60%)
Thrombosis | – | – | 1 (2%) | –
Cortex, cyst | – | – | 2 (4%) | 1 (2%)
Papilla, necrosis | 1 (2%) | – | – | –
Pelvis, dilatation | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%)
Pelvis, inflammation | 10 (20%) | 11 (22%) | 8 (16%) | 14 (28%)
Pelvis, transitional epithelium, hyperplasia | 1 (2%) | 1 (2%) | – | –
Renal tubule, dilatation | 1 (2%) | – | – | –
Ureter | (0) | (1) | (0) | (0)
Inflammation | – | 1 (100%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Calculus gross observation | – | 1 (2%) | – | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.