# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-592

Report Series: NTP Technical Report Series

Report Series Number: 592

Official citation: National Toxicology Program (NTP). 2019. NTP technical report on the toxicology and carcinogenesis study of dietary zinc (CASRN 5263-02-5) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (feed study). Research Triangle Park, NC: National Toxicology Program. Technical Report 592.