# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology and Carcinogenesis Study of Dietary Zinc (CASRN 5263-02-5) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats (Feed Study) on July 13, 2017, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Russell C. Cattley, V.M.D., Ph.D. (Chair)
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama, USA
- Michael W. Conner, D.V.M. (Primary Reviewer)
  Global Blood Therapeutics, Inc.
  San Francisco, California, USA
- Noël Dybdal, D.V.M., Ph.D.
  Genentech
  San Francisco, California, USA
- Terry Gordon, Ph.D. (Primary Reviewer)
  New York University School of Medicine
  New York, New York, USA
- Gabriele Ludewig, Ph.D. (Primary Reviewer)
  College of Public Health
  University of Iowa
  Iowa City, Iowa, USA
- Kristini K. Miles, Ph.D.
  Kimberly-Clark Corporation
  Roswell, Georgia, USA
- Richard A. Peterson, II, D.V.M., Ph.D. (Primary Reviewer)
  AbbVie
  Chicago, Illinois, USA