# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  N.R. Catlin, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, B.S., M.T.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
  M.E. Wyde, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results, conducted pathology review and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Conducted pathology review
  C.C. Shackelford, D.V.M., Ph.D.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted study and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  D.K. Gerken, D.V.M, Ph.D.
  K.A.B. Knostman, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group
  G.D. Hill, D.V.M., Ph.D.