# References

1 World Health Organization (WHO). Zinc. Environmental health criteria 221. Geneva, Switzerland: WHO; 2001. http://www.inchem.org/documents/ehc/ehc/ehc221.htm [Accessed: February 26, 2016]
2 Institute of Medicine (IOM). Dietary reference intakes for vitamin A, vitamin K, arsenic, boron, chromium, copper, iodine, iron, manganese, molybdenum, nickel, silicon, vanadium, and zinc. A report of the Panel on Micronutrients, Subcommittees on Upper Reference Levels of Nutrients and of Interpretation and Uses of Dietary Reference Intakes, and the Standing Committee on the Scientific Evaluation of Dietary Reference Intakes, 442-501. CASRN 7440-66-6. Washington, DC: Institute of Medicine, Food and Nutrition Board, National Academies Press; 2002.
3 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for zinc. Atlanta, GA: Public Health Service, U.S. Department of Health and Human Services; 2005. https://www.atsdr.cdc.gov/toxprofiles
4 Goodwin FE. Zinc compounds. In: Kroschwitz J, Howe-Grant M, editors. Kirk-Othmer Encyclopedia of Chemical Technology. Vol. 25. 4th ed. New York, NY: John Wiley & Sons; 1998. p. 840–853.
5 Peganova S, Eder K. Zinc. In: Merian E, Anke M, Ihnat M, Stoeppler M, editors. Elements and Their Compounds in the Environment. 2nd ed. Weinheim, Germany: Wiley-VCH Verlag GmbH & Co.; 2004. p. 1203–1239.10.1002/9783527619634.ch50
6 Shacklette HT, Boerngen JG. Element concentrations in soils and other surficial materials of the conterminous United States. Washington, DC: U.S. Department of Interior; 1984. U.S. Geological Survey Professional Paper 1270.
7 U.S. Geological Survey (USGS). Zinc. Mineral commodity summaries. 2016. https://minerals.usgs.gov/minerals/pubs/commodity/zinc/mcs-2016-zinc.pdf [Accessed: September 26, 2016]
8 U.S. Environmental Protection Agency. (US EPA). Exposure and risk assessment for zinc. Washington, DC: U.S. Environmental Protection Agency, Office of Water Regulations and Standards; 1980. EPA-440/4-81-016, PB85212009, WH-553.
9 Pennington JA, Young BE, Wilson DB, Johnson RD, Vanderveen JE. Mineral content of foods and total diets: The Selected Minerals in Foods Survey, 1982 to 1984. J Am Diet Assoc. 1986; 86(7):876–891. 3722652
10 Simpson JL, Bailey LB, Pietrzik K, Shane B, Holzgreve W. Micronutrients and women of reproductive potential: Required dietary intake and consequences of dietary deficiency or excess. Part II—vitamin D, vitamin A, iron, zinc, iodine, essential fatty acids. J Matern Fetal Neona Med. 2011; 24(1):1–24. 10.3109/14767051003678226 20388054
11 National Research Council (NRC). Zinc. Baltimore, MD: University Park Press; 1979.
12 U.S. Environmental Protection Agency. (US EPA). Ambient water quality criteria for zinc—1987. Washington, DC: U.S. Environmental Protection Agency, Office of Water Regulations and Standards; 1987. EPA-440/5-87-003. PB87153581.
13 Mahaffey KR, Corneliussen PE, Jelinek CF, Fiorino JA. Heavy metal exposure from foods. Environ Health Perspect. 1975;12:63–69. 10.1289/ehp.751263 1227862
14 Allen LH. Zinc and micronutrient supplements for children. Am J Clin Nutr. 1998; 68(2) Suppl:495S–498S. 10.1093/ajcn/68.2.495S 9701167
15 Rosado JL. Zinc and copper: Proposed fortification levels and recommended zinc compounds. J Nutr. 2003; 133(9):2985S–2989S. 10.1093/jn/133.9.2985S 12949397
16 Hotz C, DeHaene J, Woodhouse LR, Villalpando S, Rivera JA, King JC. Zinc absorption from zinc oxide, zinc sulfate, zinc oxide + EDTA, or sodium-zinc EDTA does not differ when added as fortificants to maize tortillas. J Nutr. 2005; 135(5):1102–1105. 10.1093/jn/135.5.1102 15867288
17 National Academy of Sciences (NAS). Chapter V. Inorganic solutes. In: Drinking Water and Health. Vol. 1. Washington, DC: National Academies Press; 1977. p. 205–488.
18 Hemilä H, Chalker E. The effectiveness of high dose zinc acetate lozenges on various common cold symptoms: A meta-analysis. BMC Fam Pract. 2015;16:24. 10.1186/s12875-015-0237-6 25888289
19 Kurugöl Z, Bayram N, Atik T. Effect of zinc sulfate on common cold in children: Randomized, double blind study. Pediatr Int. 2007; 49(6):842–847. 10.1111/j.1442-200X.2007.02448.x 18045283
20 Science M, Johnstone J, Roth DE, Guyatt G, Loeb M. Zinc for the treatment of the common cold: A systematic review and meta-analysis of randomized controlled trials. CMAJ. 2012; 184(10):E551–E561. 10.1503/cmaj.111990 22566526
21 Allan GM, Arroll B. Prevention and treatment of the common cold: Making sense of the evidence. CMAJ. 2014; 186(3):190–199. 10.1503/cmaj.121442 24468694
22 Caruso TJ, Prober CG, Gwaltney JM Jr. Treatment of naturally acquired common colds with zinc: A structured review. Clin Infect Dis. 2007; 45(5):569–574. 10.1086/520031 17682990
23 Alexander TH, Davidson TM. Intranasal zinc and anosmia: The zinc-induced anosmia syndrome. Laryngoscope. 2006; 116(2):217–220. 10.1097/01.mlg.0000191549.17796.13 16467707
24 Carboni AA, Cullen KJ, Lavelle WG. The effects of zinc on the olfactory neuroepithelium and olfactory bulbs of the Sprague-Dawley rat after oral administration of zinc-gluconate trihydrate. Am J Rhinol. 2006; 20(3):262–268. 10.2500/ajr.2006.20.2854 16871926
25 Lim JH, Davis GE, Wang Z, Li V, Wu Y, Rue TC, Storm DR. Zicam-induced damage to mouse and human nasal tissue. PLoS One. 2009; 4(10):e7647. 10.1371/journal.pone.0007647 19876403
26 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1980-1983). Unpublished provisional data as of July 1, 1990. Cincinnati, OH: National Institute for Occupational Safety and Health; 1990.
27 U.S. Geological Survey (USGS). Trace elements and organic compounds in streambed sediment and fish tissue of coastal New England streams, 1998-99. Denver, CO: U.S. Geological Survey; 2002. Water-Resources Investigations Report 02-4179.
28 Windholz M. The Merck Index. 10th ed. Rahway, NJ: Merck & Co., Inc.; 1983. p. 1455–1458.
29 Lloyd TB. Zinc compounds. In: Grayson M, editor. Kirk-Othmer Encyclopedia of Chemical Technology. Vol. 24. 3rd ed. New York, NY: John Wiley & Sons; 1984. p. 851–863.
30 Lloyd TB, Showack W. Zinc and zinc alloys. In: Grayson M, editor. Kirk-Othmer Encyclopedia of Chemical Technology. Vol. 24. 3rd ed. New York, NY: John Wiley & Sons; 1984. p. 835–836.
31 Keen CL, Hurley LS. Zinc absorption through skin: Correction of zinc deficiency in the rat. Am J Clin Nutr. 1977; 30(4):528–530. 10.1093/ajcn/30.4.528 851081
32 Lewis RJ. Hawley’s condensed chemical dictionary. New York, NY: John Wiley & Sons, Inc.; 1997. p. 1194–1202.
33 O’Neil MJ. The Merck Index. 14th ed. Whitehouse Station, NJ: Merck & Co., Inc.; 2006. p. 1747–1750.
34 Code of Federal Regulations (CFR). 40:§ 372.365.
35 Code of Federal Regulations (CFR). 21:§ 175.105.
36 Code of Federal Regulations (CFR). 21:§ 175.300.
37 Code of Federal Regulations (CFR). 21:§ 177.2600.
38 Code of Federal Regulations (CFR). 21:§ 182.5985.
39 Code of Federal Regulations (CFR). 21:§ 182.5991.
40 Code of Federal Regulations (CFR). 21:§ 182.5994.
41 Code of Federal Regulations (CFR). 21:§ 182.5997.
42 Code of Federal Regulations (CFR). 21:§ 182.190.
43 Code of Federal Regulations (CFR). 21:§ 73.2991.
44 Yadrick MK, Kenney MA, Winterfeldt EA. Iron, copper, and zinc status: Response to supplementation with zinc or zinc and iron in adult females. Am J Clin Nutr. 1989; 49(1):145–150. 10.1093/ajcn/49.1.145 2912000
45 Risk I. Information System (IRIS). Zinc and compounds. Washington, DC: United States Environmental Protection Agency; 2003. [cited 2016 Apr 21]. https://cfpub.epa.gov/ncea/iris/iris_documents/documents/subst/0426_summary.pdf.
46 Methfessel AH, Spencer H. Zinc metabolism in the rat. I. Intestinal absorption of zinc. J Appl Physiol. 1973; 34(1):58–62. 10.1152/jappl.1973.34.1.58 4697379
47 Tacnet F, Watkins DW, Ripoche P. Studies of zinc transport into brush-border membrane vesicles isolated from pig small intestine. Biochim Biophys Acta. 1990; 1024(2):323–330. 10.1016/0005-2736(90)90361-Q 2112950
48 Davies NT. Studies on the absorption of zinc by rat intestine. Br J Nutr. 1980; 43(1):189–203. 10.1079/BJN19800078 7370210
49 Gunshin H, Noguchi T, Naito H. Effect of calcium on the zinc uptake by brush-border membrane vesicles isolated from the rat small intestine. Agric Biol Chem. 1991;55:2813–2816. 10.1271/bbb1961.55.2813
50 Sturniolo GC, Montino M, Rossetto L, Martin A, D’inca R, D’odorico A, Naccarato R. Inhibition of gastric acid secretion reduces zinc absorption in man. J Am Coll Nutr. 1991; 10(4):372–375. 10.1080/07315724.1991.10718165 1894892
51 Hempe JM, Cousins RJ. Cysteine-rich intestinal protein and intestinal metallothionein: An inverse relationship as a conceptual model for zinc absorption in rats. J Nutr. 1992; 122(1):89–95. 10.1093/jn/122.1.89 1729476
52 Cousins RJ, Liuzzi JP, Lichten LA. Mammalian zinc transport, trafficking, and signals. J Biol Chem. 2006; 281(34):24085–24089. 10.1074/jbc.R600011200 16793761
53 Richards MP, Cousins RJ. Mammalian zinc homeostasis: Requirement for RNA and metallothionein synthesis. Biochem Biophys Res Commun. 1975; 64(4):1215–1223. 10.1016/0006-291X(75)90822-0 1137597
54 Foulkes EC, McMullen DM. Kinetics of transepithelial movement of heavy metals in rat jejunum. Am J Physiol. 1987; 253(2):G134–G138. 10.1152/ajpgi.1987.253.2.G134 3618775
55 Flanagan PR, Haist J, Valberg LS. Zinc absorption, intraluminal zinc and intestinal metallothionein levels in zinc-deficient and zinc-replete rodents. J Nutr. 1983; 113(5):962–972. 10.1093/jn/113.5.962 6842305
56 Galvez-Morros M, Garcia-Martinez O, Wright AJA, Southon S. Bioavailability in the rat of zinc and iron from the basic salts Zn5(OH)8Cl2.H2O, Fe(OH)SO4 and Fe4(OH)11NO3.2H2O. Food Chem. 1992; 43(5):377–381.10.1016/0308-8146(92)90310-X
57 Lopez HW, Leenhardt F, Coudray C, Rémésy C. Minerals and phytic acid interactions: Is it a real problem for human nutrition? Int J Food Sci Technol. 2002; 37(7):727–739.10.1046/j.1365-2621.2002.00618.x
58 Nelson LS Jr, Jacobs FA, Brushmiller JG. Solubility of calcium and zinc in model solutions based on bovine and human milks. J Inorg Biochem. 1985; 24(4):255–265. 10.1016/0162-0134(85)85054-6 4045447
59 Sandström B, Sandberg AS. Inhibitory effects of isolated inositol phosphates on zinc absorption in humans. J Trace Elem Electrolytes Health Dis. 1992; 6(2):99–103. 1422186
60 Davies NT, Nightingale R. The effects of phytate on intestinal absorption and secretion of zinc, and whole-body retention of Zn, copper, iron and manganese in rats. Br J Nutr. 1975; 34(2):243–258. 10.1017/S0007114575000293 1174496
61 Fischer PW, Giroux A, L’Abbe MR. The effect of dietary zinc on intestinal copper absorption. Am J Clin Nutr. 1981; 34(9):1670–1675. 10.1093/ajcn/34.9.1670 7282591
62 Ogiso T, Ogawa N, Miura T. Inhibitory effect of high dietary zinc on copper absorption in rats. II. Binding of copper and zinc to cytosol proteins in the intestinal mucosa. Chem Pharm Bull (Tokyo). 1979; 27(2):515–521. 10.1248/cpb.27.515 445686
63 Harford C, Sarkar B. Induction of metallothionein by simultaneous administration of cadmium(II) and zinc(II). Biochem Biophys Res Commun. 1991; 177(1):224–228. 10.1016/0006-291X(91)91971-E 2043109
64 Gachot B, Poujeol P. Effects of cadmium and copper on zinc transport kinetics by isolated renal proximal cells. Biol Trace Elem Res. 1992; 35(2):93–103. 10.1007/bf02783722 1280984
65 Waalkes MP, Rehm S. Carcinogenicity of oral cadmium in the male Wistar (WFNCr) rat: Effect of chronic dietary zinc deficiency. Fundam Appl Toxicol. 1992; 19(4):512–520. 10.1016/0272-0590(92)90089-Z 1426709
66 Anderson MB, Lepak K, Farinas V, George WJ. Protective action of zinc against cobalt-induced testicular damage in the mouse. Reprod Toxicol. 1993; 7(1):49–54. 10.1016/0890-6238(93)90009-V 8448416
67 Llobet JM, Domingo JL, Colomina MT, Mayayo E, Corbella J. Subchronic oral toxicity of zinc in rats. Bull Environ Contam Toxicol. 1988; 41(1):36–43. 10.1007/BF01689056 3179524
68 Schiffer RB, Sunderman FW Jr, Baggs RB, Moynihan JA. The effects of exposure to dietary nickel and zinc upon humoral and cellular immunity in SJL mice. J Neuroimmunol. 1991; 34(2-3):229–239. 10.1016/0165-5728(91)90134-S 1918329
69 Cooke JA, Andrews SM, Johnson MS. The accumulation of lead, zinc, cadmium and fluoride in the wood mouse (Apodemus sylvaticus L.). Water Air Soil Pollut. 1990; 51:55–63.10.1007/BF00211503
70 Cousins RJ. Absorption, transport, and hepatic metabolism of copper and zinc: Special reference to metallothionein and ceruloplasmin. Physiol Rev. 1985; 65(2):238–309. 10.1152/physrev.1985.65.2.238 3885271
71 Henkin RI. Metal-albumin-amino acid interactions: Chemical and physiological interrelationships. Adv Exp Med Biol. 1974;48:299–328. 10.1007/978-1-4684-0943-7_15 4611159
72 Ansari MS, Miller WJ, Lassiter JW, Neathery MW, Gentry RP. Effects of high but nontoxic dietary zinc on zinc metabolism and adaptations in rats. Proc Soc Exp Biol Med. 1975; 150(2):534–536. 10.3181/00379727-150-39072 1208572
73 Ansari MS, Miller WJ, Neathery MW, Lassiter JW, Gentry RP, Kincaid RL. Zinc metabolism and homeostasis in rats fed a wide range of high dietary zinc levels. Proc Soc Exp Biol Med. 1976; 152(2):192–194. 10.3181/00379727-152-39358 935183
74 Seal CJ, Heaton FW. Chemical factors affecting the intestinal absorption of zinc in vitro and in vivo. Br J Nutr. 1983; 50(2):317–324. 10.1079/BJN19830099 6615763
75 Alexander J, Aaseth J, Refsvik T. Excretion of zinc in rat bile - a role of glutathione. Acta Pharmacol Toxicol (Copenh). 1981; 49(3):190–194. 10.1111/j.1600-0773.1981.tb00891.x 7336976
76 Spencer H, Osis D, Kramer L, Norris C. Intake, excretion, and retention of zinc in man In: Prasad AS, Oberleas D, editors. Trace Elements in Human Health and Disease: Vol 1 Zinc and Copper. New York, NY: Academic Press; 1976. p. 345-361.
77 Reinhold JG, Faradji B, Abadi P, Ismail-Beigi F. Decreased absorption of calcium, magnesium, zinc and phosphorus by humans due to increased fiber and phosphorus consumption as wheat bread. J Nutr. 1976; 106(4):493–503. 10.1093/jn/106.4.493 1255269
78 Sandström B, Cederblad A. Zinc absorption from composite meals. II. Influence of the main protein source. Am J Clin Nutr. 1980; 33(8):1778–1783. 10.1093/ajcn/33.8.1778 6893252
79 Aamodt RL, Rumble WF, Henkin RI. Zinc absorption in humans: Effects of age, sex, and food. In: Inglett G, editor. Nutritional Bioavailability of Zinc. Washington, DC: The American Chemical Society; 1983. p. 61–82.10.1021/bk-1983-0210.ch005
80 Istfan NW, Janghorbani M, Young VR. Absorption of stable70 Zn in healthy young men in relation to zinc intake. Am J Clin Nutr. 1983; 38(2):187–194. 10.1093/ajcn/38.2.187 6881077
81 Sandström B, Abrahamsson H. Zinc absorption and achlorhydria. Eur J Clin Nutr. 1989; 43(12):877–879. 2697554
82 Hunt JR, Lykken GI, Mullen LK. Moderate and high amounts of protein from casein enhance human absorption of zinc from whole-wheat or white rolls. Nutr Res. 1991; 11(5):413–418.10.1016/S0271-5317(05)80003-X
83 Pécoud A, Donzel P, Schelling JL. Effect of foodstuffs on the absorption of zinc sulfate. Clin Pharmacol Ther. 1975; 17(4):469–474. 10.1002/cpt1975174469 1091398
84 Spencer H, Kramer L, Osis D. Zinc metabolism in man. J Environ Pathol Toxicol Oncol. 1985; 5(6):265–278. 3900339
85 Johnson PE, Hunt JR, Ralston NV. The effect of past and current dietary Zn intake on Zn absorption and endogenous excretion in the rat. J Nutr. 1988; 118(10):1205–1209. 10.1093/jn/118.10.1205 3054020
86 Wapnir RA, Stiel L. Zinc intestinal absorption in rats: Specificity of amino acids as ligands. J Nutr. 1986; 116(11):2171–2179. 10.1093/jn/116.11.2171 3794825
87 Wastney ME, Aamodt RL, Rumble WF, Henkin RI. Kinetic analysis of zinc metabolism and its regulation in normal humans. Am J Physiol Regul Integr Comp Physiol. 1986; 251(2):R398–R408. 10.1152/ajpregu.1986.251.2.R398 3740321
88 Forssén A. Inorganic elements in the human body. I. Occurrence of Ba, Br, Ca, Cd, Cs, Cu, K, Mn, Ni, Sn, Sr, Y and Zn in the human body. Ann Med Exp Biol Fenn. 1972; 50(3):99–162. 5081903
89 He L-S, Yan X-S, Wu D-C. Age-dependent variation of zinc-65 metabolism in LACA mice. Int J Radiat Biol. 1991; 60(6):907–916. 1682403
90 Schroeder HA, Nason AP, Tipton IH, Balassa JJ. Essential trace metals in man: Zinc. Relation to environmental cadmium. J Chronic Dis. 1967; 20(4):179–210. 10.1016/0021-9681(67)90002-1 6023228
91 Moreno MA, Marin C, Vinagre F, Ostapczuk P. Trace element levels in whole blood samples from residents of the city Badajoz, Spain. Sci Total Environ. 1999; 229(3):209–215. 10.1016/S0048-9697(99)00074-1 10418170
92 Bárány E, Bergdahl IA, Bratteby L-E, Lundh T, Samuelson G, Schütz A, Skerfving S, Oskarsson A. Relationships between trace element concentrations in human blood and serum. Toxicol Lett. 2002; 134(1-3):177–184. 10.1016/S0378-4274(02)00187-X 12191876
93 Nève J, Hanocq M, Peretz A, Abi Khalil F, Pelen F, Famaey JP, Fontaine J. Pharmacokinetic study of orally administered zinc in humans: Evidence for an enteral recirculation. Eur J Drug Metab Pharmacokinet. 1991; 16(4):315–323. 10.1007/bf03189977 1823876
94 Takagi Y, Matsuda S, Imai S, Ohmori Y, Masuda T, Vinson J, Mehra M, Puri B, Kaniewski A. Survey of trace elements in human nails: An international comparison. Bull Environ Contam Toxicol. 1988; 41(5):690–695. 10.1007/BF02021020 3233368
95 Wilhelm M, Hafner D, Lombeck I, Ohnosorge FK. Monitoring of cadmium, copper, lead and zinc status in young children using toenails: Comparison with scalp hair. Sci Total Environ. 1991; 103(2-3):199–207. 10.1016/0048-9697(91)90145-5 1882232
96 Saltzman BE, Gross SB, Yeager DW, Meiners BG, Gartside PS. Total body burdens and tissue concentrations of lead, cadmium, copper, zinc, and ash in 55 human cadavers. Environ Res. 1990; 52(2):126–145. 10.1016/S0013-9351(05)80248-8 2394204
97 Beer WH, Johnson RF, Guentzel MN, Lozano J, Henderson GI, Schenker S. Human placental transfer of zinc: Normal characteristics and role of ethanol. Alcohol Clin Exp Res. 1992; 16(1):98–105. 10.1111/j.1530-0277.1992.tb00644.x 1558309
98 Ong CN, Chia SE, Foo SC, Ong HY, Tsakok M, Liouw P. Concentrations of heavy metals in maternal and umbilical cord blood. Biometals. 1993; 6(1):61–66. 10.1007/BF00154234 8471826
99 Raghunath R, Tripathi RM, Sastry VN, Krishnamoorthy TM. Heavy metals in maternal and cord blood. Sci Total Environ. 2000; 250(1-3):135–141. 10.1016/S0048-9697(00)00372-7 10811257
100 Rossowska MJ, Nakamoto T. Caffeine decreases zinc and metallothionein levels in heart of newborn and adult rats. Pediatr Res. 1992; 32(3):330–332. 10.1203/00006450-199209000-00017 1408471
101 Arnaud J, Favier A. Copper, iron, manganese and zinc contents in human colostrum and transitory milk of French women. Sci Total Environ. 1995; 159(1):9–15. 10.1016/0048-9697(94)04314-D 7846513
102 Dόrea JG. Zinc and copper in breast-milk and home-prepared milk fed to urban infants from low-income families. J Trace Elem Exp Med. 2002; 15(3):123–129.10.1002/jtra.10010
103 Prasad AS, Schulert AR, Sandstead HH, Miale A Jr, Farid Z. Zinc, iron, and nitrogen content of sweat in normal and deficient subjects. J Lab Clin Med. 1963;62:84–89. 13985939
104 Hambidge KM, Hambidge C, Jacobs M, Baum JD. Low levels of zinc in hair, anorexia, poor growth, and hypogeusia in children. Pediatr Res. 1972; 6(12):868–874. 10.1203/00006450-197212000-00003 4509185
105 Henkin RI, Mueller CW, Wolf RO. Estimation of zinc concentration of parotid saliva by flameless atomic absorption spectrophotometry in normal subjects and in patients with idiopathic hypogeusia. J Lab Clin Med. 1975; 86(1):175–180. 1151138
106 Greger JL, Sickles VS. Saliva zinc levels: Potential indicators of zinc status. Am J Clin Nutr. 1979; 32(9):1859–1866. 10.1093/ajcn/32.9.1859 474476
107 Rivlin RS. Misuse of hair analysis for nutritional assessment. Am J Med. 1983; 75(3):489–493. 10.1016/0002-9343(83)90355-8 6614034
108 Krishnan U, Que Hee SS. Ear wax: A new biological monitoring medium for metals? Bull Environ Contam Toxicol. 1992; 48(4):481–486. 10.1007/BF00199061 1504490
109 Domingo JL, Llobet JM, Paternain JL, Corbella J. Acute zinc intoxication: Comparison of the antidotal efficacy of several chelating agents. Vet Hum Toxicol. 1988; 30(3):224–228. 3388750
110 Maita K, Hirano M, Mitsumori K, Takahashi K, Shirasu Y. Subacute toxicity studies with zinc sulfate in mice and rats. J Pestic Sci. 1981;6:327–336.10.1584/jpestics.6.327
111 Straube EF, Schuster NH, Sinclair AJ. Zinc toxicity in the ferret. J Comp Pathol. 1980; 90(3):355–361. 10.1016/0021-9975(80)90003-1 6974744
112 Aulerich RJ, Bursian SJ, Poppenga RH, Braselton WE, Mullaney TP. Toleration of high concentrations of dietary zinc by mink. J Vet Diagn Invest. 1991; 3(3):232–237. 10.1177/104063879100300309 1911995
113 Allen JG, Masters HG, Peet RL, Mullins KR, Lewis RD, Skirrow SZ, Fry J. Zinc toxicity in ruminants. J Comp Pathol. 1983; 93(3):363–377. 10.1016/0021-9975(83)90024-5 6886083
114 Kadiiska M, Stoytchev T, Serbinova E. Effect of some heavy metal salts on hepatic monooxygenases after subchronic exposure. Arch Toxicol Suppl. 1985;8:313–315. 10.1007/978-3-642-69928-3_59 3868358
115 Klevay LM. Hypercholesterolemia in rats produced by an increase in the ratio of zinc to copper ingested. Am J Clin Nutr. 1973; 26(10):1060–1068. 10.1093/ajcn/26.10.1060 4754665
116 Katya-Katya M, Ensminger A, Méjean L, Debry G. The effect of zinc supplementation on plasma cholesterol levels. Nutr Res. 1984; 4(4):633–638.10.1016/S0271-5317(84)80036-6
117 Fischer PW, Giroux A, Belonje B, Shah BG. The effect of dietary copper and zinc on cholesterol metabolism. Am J Clin Nutr. 1980; 33(5):1019–1025. 10.1093/ajcn/33.5.1019 7369153
118 Sandstead HH. Zinc in human nutrition In: Bronner F, Coburn JW, editors. Disorders of Mineral Metabolism Vol 1 Trace Minerals. New York, NY: Academic Press, Inc.; 1981. p. 93-157. 10.1016/B978-0-12-135301-8.50009-1
119 Kumar V, Abbas AK, Fausto N, Mitchell RN. Robbins basic pathology. 8th ed. Philadelphia, PA: Saunders Elsevier; 2007. p. 315.
120 Brown MA, Thom JV, Orth GL, Cova P, Juarez J. Food poisoning involving zinc contamination. Arch Environ Health. 1964; 8(5):657–660. 10.1080/00039896.1964.10663736 14120562
121 Moore R. Bleeding gastric erosion after oral zinc sulphate. BMJ. 1978; 1(6115):754. 10.1136/bmj.1.6115.754 147123
122 Centers for Disease Control (CDC). Illness associated with elevated levels of zinc in fruit punch-New Mexico. MMWR Morb Mortal Wkly Rep. 1983;32:257–258. 6405169
123 Samman S, Roberts DC. The effect of zinc supplements on plasma zinc and copper levels and the reported symptoms in healthy volunteers. Med J Aust. 1987; 146(5):246–249. 10.5694/j.1326-5377.1987.tb120232.x 3547053
124 Lewis MR, Kokan L. Zinc gluconate: Acute ingestion. J Toxicol Clin Toxicol. 1998; 36(1-2):99–101. 10.3109/15563659809162595 9541053
125 Callender GR, Gentzkow CJ. Acute poisoning by the zinc and antimony content of limeade prepared in a galvanized iron can. Mil Surg (Wash). 1937;80:67–71.
126 Fischer PW, Giroux A, L’Abbe MR. Effect of zinc supplementation on copper status in adult man. Am J Clin Nutr. 1984; 40(4):743–746. 10.1093/ajcn/40.4.743 6486080
127 Davis CD, Milne DB, Nielsen FH. Changes in dietary zinc and copper affect zinc-status indicators of postmenopausal women, notably, extracellular superoxide dismutase and amyloid precursor proteins. Am J Clin Nutr. 2000; 71(3):781–788. 10.1093/ajcn/71.3.781 10702173
128 Milne DB, Davis CD, Nielsen FH. Low dietary zinc alters indices of copper function and status in postmenopausal women. Nutrition. 2001; 17(9):701–708. 10.1016/S0899-9007(01)00560-3 11527655
129 Porter KG, McMaster D, Elmes ME, Love AH. Anaemia and low serum-copper during zinc therapy. Lancet. 1977; 310(8041):774. 10.1016/S0140-6736(77)90295-1 71592
130 Prasad AS, Brewer GJ, Schoomaker EB, Rabbani P. Hypocupremia induced by zinc therapy in adults. JAMA. 1978; 240(20):2166–2168. 10.1001/jama.1978.03290200044019 359844
131 Patterson WP, Winkelmann M, Perry MC. Zinc-induced copper deficiency: Megamineral sideroblastic anemia. Ann Intern Med. 1985; 103(3):385–386. 10.7326/0003-4819-103-3-385 4026086
132 Hale WE, May FE, Thomas RG, Moore MT, Stewart RB. Effect of zinc supplementation on the development of cardiovascular disease in the elderly. J Nutr Elder. 1989; 8(2):49–58. 10.1300/J052v08n02_05 3241299
133 Broun ER, Greist A, Tricot G, Hoffman R. Excessive zinc ingestion. A reversible cause of sideroblastic anemia and bone marrow depression. JAMA. 1990; 264(11):1441–1443. 10.1001/jama.1990.03450110087033 2094240
134 Stroud S, Dyer J. Drug Watch. Am J Nurs. 1991; 91(4):61–62, 64, 66.10.2307/3426495
135 Summerfield AL, Steinberg FU, Gonzalez JG. Morphologic findings in bone marrow precursor cells in zinc-induced copper deficiency anemia. Am J Clin Pathol. 1992; 97(5):665–668. 10.1093/ajcp/97.5.665 1575212
136 Salzman MB, Smith EM, Koo C. Excessive oral zinc supplementation. J Pediatr Hematol Oncol. 2002; 24(7):582–584. 10.1097/00043426-200210000-00020 12368702
137 Willis MS, Monaghan SA, Miller ML, McKenna RW, Perkins WD, Levinson BS, Bhushan V, Kroft SH. Zinc-induced copper deficiency: A report of three cases initially recognized on bone marrow examination. Am J Clin Pathol. 2005; 123(1):125–131. 10.1309/V6GVYW2QTYD5C5PJ 15762288
138 Bonham M, O’Connor JM, Alexander HD, Coulter J, Walsh PM, McAnena LB, Downes CS, Hannigan BM, Strain JJ. Zinc supplementation has no effect on circulating levels of peripheral blood leucocytes and lymphocyte subsets in healthy adult men. Br J Nutr. 2003; 89(5):695–703. 10.1079/BJN2003826 12720590
139 Bonham M, O’Connor JM, McAnena LB, Walsh PM, Downes CS, Hannigan BM, Strain JJ. Zinc supplementation has no effect on lipoprotein metabolism, hemostasis, and putative indices of copper status in healthy men. Biol Trace Elem Res. 2003; 93(1-3):75–86. 10.1385/BTER:93:1-3:75 12835492
140 Hooper PL, Visconti L, Garry PJ, Johnson GE. Zinc lowers high-density lipoprotein-cholesterol levels. JAMA. 1980; 244(17):1960–1961. 10.1001/jama.1980.03310170058030 7420708
141 Chandra RK. Excessive intake of zinc impairs immune responses. JAMA. 1984; 252(11):1443–1446. 10.1001/jama.1984.03350110043027 6471270
142 Black MR, Medeiros DM, Brunett E, Welke R. Zinc supplements and serum lipids in young adult white males. Am J Clin Nutr. 1988; 47(6):970–975. 10.1093/ajcn/47.6.970 3163879
143 Freeland-Graves JH, Han W-H, Friedman BJ, Shorey RL. Effect of dietary Zn/Cu ratios on cholesterol and HDL cholesterol levels in women. Nutr Rep Int. 1980; 22(2):285–293.
144 Samman S, Roberts DC. The effect of zinc supplements on lipoproteins and copper status. Atherosclerosis. 1988; 70(3):247–252. 10.1016/0021-9150(88)90175-X 3365292
145 Srivastava A, Setty B. The distribution of zinc in the subcellular fractions of the rhesus monkey testis. Biol Trace Elem Res. 1985; 7(2):83–87. 10.1007/BF02916566 24259037
146 Bedwal RS, Bahuguna A. Zinc, copper and selenium in reproduction. Experientia. 1994; 50(7):626–640. 10.1007/BF01952862 8033970
147 Cushman DW, Cheung H. Concentrations of angiotensin-converting enzyme in tissues of the rat. Biochim Biophys Acta. 1971; 250(1):261–265. 10.1016/0005-2744(71)90142-2 4334856
148 Jaiswal A, Joshi P, Kumar MV, Panda JN, Singh LN. Angiotensin converting enzyme in the testis and epididymis of mammals. Andrologia. 1984; 16(5):410–416. 10.1111/j.1439-0272.1984.tb00385.x 6093633
149 Barney GH, Orgebin-Crist MC, Macapinalac MP. Genesis of esophageal parakeratosis and histologic changes in the testes of the zinc-deficient rat and their reversal by zinc repletion. J Nutr. 1968; 95(4):526–534. 10.1093/jn/95.4.526 5665655
150 Reeves PG, O’Dell BL. Zinc deficiency in rats and angiotensin-converting enzyme activity: Comparative effects on lung and testis. J Nutr. 1988; 118(5):622–626. 10.1093/jn/118.5.622 2835463
151 Parízek J, Boursnell JC, Hay MF, Babicky A, Taylor DM. Zinc in the maturing rat testis. J Reprod Fertil. 1966; 12(3):501–507. 10.1530/jrf.0.0120501 5928269
152 Cater BR, Cook MW, Gangolli SD, Grasso P. Studies on dibutyl phthalate-induced testicular atrophy in the rat: Effect on zinc metabolism. Toxicol Appl Pharmacol. 1977; 41(3):609–618. 10.1016/S0041-008X(77)80014-8 918990
153 Foster PM, Thomas LV, Cook MW, Gangolli SD. Study of the testicular effects and changes in zinc excretion produced by some n-alkyl phthalates in the rat. Toxicol Appl Pharmacol. 1980; 54(3):392–398. 10.1016/0041-008X(80)90165-9 7394794
154 Oishi S, Hiraga K. Testicular atrophy induced by di-2-ethylhexyl phthalate: Effect of zinc supplement. Toxicol Appl Pharmacol. 1983; 70(1):43–48. 10.1016/0041-008X(83)90177-1 6612737
155 Hurley LS, Swenerton H. Congenital malformations resulting from zinc deficiency in rats. Proc Soc Exp Biol Med. 1966;123:692–696. 10.3181/00379727-123-31578 6006233
156 Gombe S, Apgar J, Hansel W. Effect of zinc deficiency and restricted food intake on plasma and pituitary LH and hypothalamic LRF in female rats. Biol Reprod. 1973; 9(4):415–419. 10.1093/biolreprod/9.4.415 4585296
157 Apgar J. Effect of zinc deficiency on maintenance of pregnancy in the rat. J Nutr. 1970; 100(4):470–476. 10.1093/jn/100.4.470 5439355
158 Beach RS, Gershwin ME, Hurley LS. Growth and development in postnatally zinc-deprived mice. J Nutr. 1980; 110(2):201–211. 10.1093/jn/110.2.201 7354391
159 Soltan MH, Jenkins DM. Maternal and fetal plasma zinc concentration and fetal abnormality. BJOG. 1982; 89(1):56–58. 10.1111/j.1471-0528.1982.tb04635.x 7059547
160 Masters DG, Moir RJ. Effect of zinc deficiency on the pregnant ewe and developing foetus. Br J Nutr. 1983; 49(3):365–372. 10.1079/BJN19830045 6860622
161 Sato F, Watanabe T, Hoshi E, Endo A. Teratogenic effect of maternal zinc deficiency and its co-teratogenic effect with cadmium. Teratology. 1985; 31(1):13–18. 10.1002/tera.1420310103 3983855
162 Khan AT, Atkinson A, Graham TC, Green M, Ali S, Thompson SJ, Shireen KF. Effects of low levels of zinc on reproductive performance of rats. Published abstract. Tuskegee, AL: Tuskegee University, College of Veterinary Medicine, Nursing and Allied Health and Department of Food and Nutritional Sciences; 2001.
163 Johnson FO, Gilbreath ET, Ogden L, Graham TC, Gorham S. Reproductive and developmental toxicities of zinc supplemented rats. Reprod Toxicol. 2011; 31(2):134–143. 10.1016/j.reprotox.2010.10.009 20977935
164 Hickory W, Nanda R, Catalanotto FA. Fetal skeletal malformations associated with moderate zinc deficiency during pregnancy. J Nutr. 1979; 109(5):883–891. 10.1093/jn/109.5.883 438902
165 Warkany J, Petering HG. Congenital malformations of the central nervous system in rats produced by maternal zinc deficiency. Teratology. 1972; 5(3):319–334. 10.1002/tera.1420050307 5032641
166 Sandstead HH. Zinc nutrition in the United States. Am J Clin Nutr. 1973; 26(11):1251–1260. 10.1093/ajcn/26.11.1251 4594065
167 Schlicker SA, Cox DH. Maternal dietary zinc, and development and zinc, iron, and copper content of the rat fetus. J Nutr. 1968; 95(2):287–294. 10.1093/jn/95.2.287 5665629
168 Cox DH, Schlicker SA, Chu RC. Excess dietary zinc for the maternal rat, and zinc, iron, copper, calcium, and magnesium content and enzyme activity in maternal and fetal tissues. J Nutr. 1969; 98(4):459–466. 10.1093/jn/98.4.459 4308178
169 Ketcheson MR, Barron GP, Cox DH. Relationship of maternal dietary zinc during gestation and lactation to development and zinc, iron and copper content of the postnatal rat. J Nutr. 1969; 98(3):303–311. 10.1093/jn/98.3.303 5796415
170 Mulhern SA, Stroube WB Jr, Jacobs RM. Alopecia induced in young mice by exposure to excess dietary zinc. Experientia. 1986; 42(5):551–553. 10.1007/BF01946698 3709762
171 Apgar J. Zinc and reproduction. Annu Rev Nutr. 1985; 5(1):43–68. 10.1146/annurev.nu.05.070185.000355 3896272
172 Favier AE. The role of zinc in reproduction. Hormonal mechanisms. Biol Trace Elem Res. 1992;32:363–382. 10.1007/BF02784623 1375078
173 Walsh CT, Sandstead HH, Prasad AS, Newberne PM, Fraker PJ. Zinc: Health effects and research priorities for the 1990s. Environ Health Perspect. 1994; 102 suppl 2:5–46. 7925188
174 Xu B, Chia S-E, Ong C-N. Concentrations of cadmium, lead, selenium, and zinc in human blood and seminal plasma. Biol Trace Elem Res. 1994; 40(1):49–57. 10.1007/BF02916820 7511920
175 Ames BN, Wakimoto P. Are vitamin and mineral deficiencies a major cancer risk? Nat Rev Cancer. 2002; 2(9):694–704. 10.1038/nrc886 12209158
176 Verburg DJ, Burd LI, Hoxtell EO, Merrill LK. Acrodermatitis enteropathica and pregnancy. Obstet Gynecol. 1974; 44(2):233–237. 4607826
177 Cherry FF, Bennett EA, Bazzano GS, Johnson L, Fosmire GJ, Batson HK. Plasma zinc in hypertension/toxemia and other reproductive variables in adolescent pregnancy. Am J Clin Nutr. 1981; 34(11):2367–2375. 10.1093/ajcn/34.11.2367 6118062
178 Hambidge KM, Neldner KH, Walravens PA. Zinc, acrodermatitis enteropathica, and congenital malformations. Lancet. 1975; 305(7906):577–578. 10.1016/S0140-6736(75)91601-3 47054
179 Chaffee BW, King JC. Effect of zinc supplementation on pregnancy and infant outcomes: A systematic review. Paediatr Perinat Epidemiol. 2012; 26 Suppl 1:118–137. 10.1111/j.1365-3016.2012.01289.x 22742606
180 Meadows NJ, Ruse W, Smith MF, Day J, Keeling PW, Scopes JW, Thompson RP, Bloxam DL. Zinc and small babies. Lancet. 1981; 318(8256):1135–1137. 10.1016/S0140-6736(81)90587-0 6118578
181 Simmer K, Thompson RP. Zinc in the fetus and newborn. Acta Paediatr Scand Suppl. 1985; 74(319):158–163. 10.1111/j.1651-2227.1985.tb10126.x 3868917
182 Kynast G, Saling E. Effect of oral zinc application during pregnancy. Gynecol Obstet Invest. 1986; 21(3):117–123. 10.1159/000298940 3710284
183 Ota E, Mori R, Middleton P, Tobe-Gai R, Mahomed K, Miyazaki C, Bhutta ZA. Zinc supplementation for improving pregnancy and infant outcome. Cochrane Database Syst Rev. 2015;(2):CD000230. 10.1002/14651858.CD000230.pub5 25927101
184 Grieger JA, Clifton VL. A review of the impact of dietary intakes in human pregnancy on infant birthweight. Nutrients. 2014; 7(1):153–178. 10.3390/nu7010153 25551251
185 Tamura T, Goldenberg RL, Johnston KE, DuBard M. Maternal plasma zinc concentrations and pregnancy outcome. Am J Clin Nutr. 2000; 71(1):109–113. 10.1093/ajcn/71.1.109 10617954
186 Iannotti LL, Zavaleta N, León Z, Shankar AH, Caulfield LE. Maternal zinc supplementation and growth in Peruvian infants. Am J Clin Nutr. 2008; 88(1):154–160. 10.1093/ajcn/88.1.154 18614736
187 Swenerton H, Hurley LS. Severe zinc deficiency in male and female rats. J Nutr. 1968; 95(1):8–18. 10.1093/jn/95.1.8 5653280
188 Diamond I, Swenerton H, Hurley LS. Testicular and esophageal lesions in zinc-deficient rats and their reversibility. J Nutr. 1971; 101(1):77–84. 10.1093/jn/101.1.77 5099751
189 Newberne PM, Schrager TF, Broitman S. Esophageal carcinogenesis in the rat: Zinc deficiency and alcohol effects on tumor induction. Pathobiology. 1997; 65(1):39–45. 10.1159/000164101 9200188
190 Schrager TF, Busby WF Jr, Goldman ME, Newberne PM. Enhancement of methylbenzylnitrosamine-induced esophageal carcinogenesis in zinc-deficient rats: Effects on incorporation of [3H]thymidine into DNA of esophageal epithelium and liver. Carcinogenesis. 1986; 7(7):1121–1126. 10.1093/carcin/7.7.1121 3719907
191 Barch DH, Fox CC. Dietary zinc deficiency increases the methylbenzylnitrosamine-induced formation of O6-methylguanine in the esophageal DNA of the rat. Carcinogenesis. 1987; 8(10):1461–1464. 10.1093/carcin/8.10.1461 3652382
192 Fong LY, Li J-X, Farber JL, Magee PN. Cell proliferation and esophageal carcinogenesis in the zinc-deficient rat. Carcinogenesis. 1996; 17(9):1841–1848. 10.1093/carcin/17.9.1841 8824504
193 Fong LY, Nguyen VT, Farber JL. Esophageal cancer prevention in zinc-deficient rats: Rapid induction of apoptosis by replenishing zinc. J Natl Cancer Inst. 2001; 93(20):1525–1533. 10.1093/jnci/93.20.1525 11604475
194 Walters M, Roe FJC. A study of the effects of zinc and tin administered orally to mice over a prolonged period. Food Cosmet Toxicol. 1965;3:271–276. 10.1016/S0015-6264(65)80084-0 4285692
195 Halme E. On the carcinogenic effect of drinking water containing zinc. Vitalstoffe. 1961;6:59–66.
196 Aughey E, Grant L, Furman BL, Dryden WF. The effects of oral zinc supplementation in the mouse. J Comp Pathol. 1977; 87(1):1–14. 10.1016/0021-9975(77)90074-3 851462
197 Kmet J, Mahboubi E. Esophageal cancer in the Caspian littoral of Iran: Initial studies. Science. 1972; 175(4024):846–853. 10.1126/science.175.4024.846 5008604
198 Lin HJ, Chan WC, Fong LYY, Newberne PM. Zinc levels in serum, hair and tumors from patients with esophageal cancer. Nutr Rep Int. 1976;15:635–643.
199 van Rensburg SJ. Epidemiologic and dietary evidence for a specific nutritional predisposition to esophageal cancer. J Natl Cancer Inst. 1981; 67(2):243–251. 6943364
200 Abnet CC, Lai B, Qiao Y-L, Vogt S, Luo X-M, Taylor PR, Dong Z-W, Mark SD, Dawsey SM. Zinc concentration in esophageal biopsy specimens measured by x-ray fluorescence and esophageal cancer risk. J Natl Cancer Inst. 2005; 97(4):301–306. 10.1093/jnci/dji042 15713965
201 Kaul L, Nidiry JJ, Charles-Marcel Z, Enterline JP, Brown CO. Diet and esophageal cancer: A case-control study. Nutr Res. 1986; 6(8):905–912.10.1016/S0271-5317(86)80065-3
202 Lee D-H, Anderson KE, Folsom AR, Jacobs DR Jr. Heme iron, zinc and upper digestive tract cancer: The Iowa Women’s Health Study. Int J Cancer. 2005; 117(4):643–647. 10.1002/ijc.21215 15929082
203 Mellow MH, Layne EA, Lipman TO, Kaushik M, Hostetler C, Smith JC Jr. Plasma zinc and vitamin A in human squamous carcinoma of the esophagus. Cancer. 1983; 51(9):1615–1620. 10.1002/1097-0142(19830501)51:9<1615::AID-CNCR2820510911>3.0.CO;2-O 6831364
204 Grant WB. An ecological study of cancer mortality rates including indices for dietary iron and zinc. Anticancer Res. 2008; 28 3b:1955–1963. 18630488
205 Li P, Xu J, Shi Y, Ye Y, Chen K, Yang J, Wu Y. Association between zinc intake and risk of digestive tract cancers: A systematic review and meta-analysis. Clin Nutr. 2014; 33(3):415–420. 10.1016/j.clnu.2013.10.001 24148607
206 Yang CS. Research on esophageal cancer in China: A review. Cancer Res. 1980; 40(8 Part 1):2633–2644. 6992989
207 Marzin DR, Phi HV. Study of the mutagenicity of metal derivatives with Salmonella typhimurium TA102. Mutat Res. 1985; 155(1-2):49–51. 10.1016/0165-1218(85)90024-2 3881664
208 Nishioka H. Mutagenic activities of metal compounds in bacteria. Mutat Res. 1975; 31(3):185–189. 10.1016/0165-1161(75)90088-6 805366
209 Sharif R, Thomas P, Zalewski P, Fenech M. Zinc deficiency or excess within the physiological range increases genome instability and cytotoxicity, respectively, in human oral keratinocyte cells. Genes Nutr. 2012; 7(2):139–154. 10.1007/s12263-011-0248-4 21935692
210 Sharif R, Thomas P, Zalewski P, Graham RD, Fenech M. The effect of zinc sulphate and zinc carnosine on genome stability and cytotoxicity in the WIL2-NS human lymphoblastoid cell line. Mutat Res. 2011; 720(1-2):22–33. 10.1016/j.mrgentox.2010.12.004 21167308
211 Ho E, Ames BN. Low intracellular zinc induces oxidative DNA damage, disrupts p53, NFkappa B, and AP1 DNA binding, and affects DNA repair in a rat glioma cell line. Proc Natl Acad Sci USA. 2002; 99(26):16770–16775. 10.1073/pnas.222679399 12481036
212 Yan M, Song Y, Wong CP, Hardin K, Ho E. Zinc deficiency alters DNA damage response genes in normal human prostate epithelial cells. J Nutr. 2008; 138(4):667–673. 10.1093/jn/138.4.667 18356318
213 Ho E, Courtemanche C, Ames BN. Zinc deficiency induces oxidative DNA damage and increases p53 expression in human lung fibroblasts. J Nutr. 2003; 133(8):2543–2548. 10.1093/jn/133.8.2543 12888634
214 Song Y, Leonard SW, Traber MG, Ho E. Zinc deficiency affects DNA damage, oxidative stress, antioxidant defenses, and DNA repair in rats. J Nutr. 2009; 139(9):1626–1631. 10.3945/jn.109.106369 19625698
215 Castro CE, Kaspin LC, Chen S-S, Nolker SG. Zinc deficiency increases the frequency of single-strand DNA breaks in rat liver. Nutr Res. 1992; 12(6):721–736.10.1016/S0271-5317(05)80569-X
216 Kawasaki I, Suzuki Y, Yanagisawa H. Zinc deficiency enhances the induction of micronuclei and 8-hydroxy-2′-deoxyguanosine via superoxide radical in bone marrow of zinc-deficient rats. Biol Trace Elem Res. 2013; 154(1):120–126. 10.1007/s12011-013-9706-8 23712836
217 Özkul Y, Dursun N, Erenmemisoglu A, Süer C, Saatçi C. Effect of zinc deficiency on chromosomal abnormalities in mice. Tohoku J Exp Med. 1996; 179(4):247–251. 10.1620/tjem.179.247 8944425
218 Deknudt G, Gerber GB. Chromosomal aberrations in bone-marrow cells of mice given a normal or a calcium-deficient diet supplemented with various heavy metals. Mutat Res. 1979; 68(2):163–168. 10.1016/0165-1218(79)90144-7 514302
219 Olin KL, Shigenaga MK, Ames BN, Golub MS, Gershwin ME, Hendrickx AG, Keen CL. Maternal dietary zinc influences DNA strand break and 8-hydroxy-2′-deoxyguanosine levels in infant rhesus monkey liver. Proc Soc Exp Biol Med. 1993; 203(4):461–466. 10.3181/00379727-203-43623 8351286
220 Gocke E, King M-T, Eckhardt K, Wild D. Mutagenicity of cosmetics ingredients licensed by the European Communities. Mutat Res. 1981; 90(2):91–109. 10.1016/0165-1218(81)90072-0 6799819
221 Watanabe T, Endo A. Cytogenetic effects of cadmium on unfertilized oocytes in short-term zinc deficiency in hamsters. Mutat Res. 1997; 395(2-3):113–118. 10.1016/S1383-5718(97)00151-4 9465921
222 Song Y, Chung CS, Bruno RS, Traber MG, Brown KH, King JC, Ho E. Dietary zinc restriction and repletion affects DNA integrity in healthy men. Am J Clin Nutr. 2009; 90(2):321–328. 10.3945/ajcn.2008.27300 19515738
223 Li H, Swiercz R, Englander EW. Elevated metals compromise repair of oxidative DNA damage via the base excision repair pathway: Implications of pathologic iron overload in the brain on integrity of neuronal DNA. J Neurochem. 2009; 110(6):1774–1783. 10.1111/j.1471-4159.2009.06271.x 19619136
224 Reeves PG, Nielsen FH, Fahey GC Jr. AIN-93 purified diets for laboratory rodents: Final report of the American Institute of Nutrition ad hoc writing committee on the reformulation of the AIN-76A rodent diet. J Nutr. 1993; 123(11):1939–1951. 10.1093/jn/123.11.1939 8229312
225 Levine KE, Collins BJ, Stout MD, Wyde M, Afton SE, Essader AS, Ennis TJ, Amato KE, McWilliams AC, Fletcher BL, et al. Characterization of zinc carbonate basic as a source of zinc in a rodent study investigating the effects of dietary deficiency or excess. Anal Lett. 2017; 50(15):2447–2464. 10.1080/00032719.2017.1293073 30930463
226 National Toxicology Program (NTP). Historical controls report by route and vehicle: Harlan Sprague-Dawley Rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/ntp/historical_controls/ntp2000_2016/aug-2016-hc-report-hsd-rats-by-route.pdf [Accessed: February 14, 2017]
227 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
228 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, Connell EE, Hardisty JF. Quality assurance in pathology for rodent car-cinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
229 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
230 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481.10.1080/01621459.1958.10501452
231 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202.
232 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690.10.1093/biomet/62.3.679
233 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
234 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
235 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, UK: Chapman and Hall; 1997.
236 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
237 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
238 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
239 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero-dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
240 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
241 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
242 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
243 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
244 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145.10.1093/biomet/41.1-2.133
245 Dixon WJ, Massey FJ Jr. Introduction to Statistical Analysis. 2nd ed. New York, NY: McGraw-Hill Book Company; 1957. p. 276–278, 412.
246 Code of Federal Regulations (CFR). 21:Part 58.
247 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
248 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
249 Organisation for Economic Cooperation and Development (OECD). OECD guideline for the testing of chemicals. In vivo mammalian alkaline comet assay. Paris, France: OECD Publishing; 2014. Testing Guideline 489.
250 Tice RR, Agurell E, Anderson D, Burlinson B, Hartmann A, Kobayashi H, Miyamae Y, Rojas E, Ryu JC, Sasaki Y. Single cell gel/comet assay: Guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutagen. 2000; 35(3):206–221. 10.1002/(SICI)1098-2280(2000)35:3<206::AID-EM8>3.0.CO;2-J 10737956
251 Collins AR. The comet assay for DNA damage and repair. Principles, applications and limitations. Mol Biotechnol. 2004;26:249–261. 10.1385/MB:26:3:249 15004294
252 Brendler-Schwaab S, Hartmann A, Pfuhler S, Speit G. The in vivo comet assay: Use and status in genotoxicity testing. Mutagenesis. 2005; 20(4):245–254. 10.1093/mutage/gei033 15899933
253 Burlinson B, Tice RR, Speit G, Agurell E, Brendler-Schwaab SY, Collins AR, Escobar P, Honma M, Kumaravel TS, Nakajima M, et al. Fourth International Workgroup on Genotoxicity testing: Results of the in vivo Comet assay workgroup. Mutat Res. 2007; 627(1):31–35. 10.1016/j.mrgentox.2006.08.011 17118697
254 Pfuhler S, Wolf HU. Detection of DNA-crosslinking agents with the alkaline comet assay. Environ Mol Mutagen. 1996; 27(3):196–201. 10.1002/(sici)1098-2280(1996)27:3<196::Aid-em4>3.0.Co;2-d 8625955
255 Hartmann A, Agurell E, Beevers C, Brendler-Schwaab S, Burlinson B, Clay P, Collins A, Smith A, Speit G, Thybaud V, et al. Recommendations for conducting the in vivo alkaline Comet assay. Mutagenesis. 2003; 18(1):45–51. 10.1093/mutage/18.1.45 12473734
256 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
257 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67:233–241. 7021938
258 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Melhman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co., Inc.; 1985. p. 13–59.
259 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
260 Sasaki YF, Sekihashi K, Izumiyama F, Nishidate E, Saga A, Ishida K, Tsuda S. The comet assay with multiple mouse organs: Comparison of comet assay results and carcinogenicity with 208 chemicals selected from the IARC monographs and U.S. NTP Carcinogenicity Database. Crit Rev Toxicol. 2000; 30(6):629–799. 10.1080/10408440008951123 11145306
261 Fairweather-Tait SJ, Fox TE, Wharf SG, Ghani NA. A preliminary study of the bioavailability of iron- and zinc-glycine chelates. Food Addit Contam. 1992; 9(1):97–101. 10.1080/02652039209374049 1397394
262 Kincaid RL. Biological availability of zinc from inorganic sources with excess dietary calcium. J Dairy Sci. 1979; 62(7):1081–1085. 10.3168/jds.S0022-0302(79)83378-0 512132
263 Della Lucia CM, Santos LL, Rodrigues KC, Rodrigues VC, Martino HS, Sant’Ana HM. Bioavailability of zinc in Wistar rats fed with rice fortified with zinc oxide. Nutrients. 2014; 6(6):2279–2289. 10.3390/nu6062279 24932657
264 Kelly EJ, Quaife CJ, Froelick GJ, Palmiter RD. Metallothionein I and II protect against zinc deficiency and zinc toxicity in mice. J Nutr. 1996; 126(7):1782–1790. 8683339
265 Miller WJ. Absorption, tissue distribution, endogenous excretion, and homeostatic control of zinc in ruminants. Am J Clin Nutr. 1969; 22(10):1323–1331. 10.1093/ajcn/22.10.1323 4899225
266 Evans GW, Grace CI, Hahn C. Homeostatic regulation of zinc absorption in the rat. Proc Soc Exp Biol Med. 1973; 143(3):723–725. 10.3181/00379727-143-37400 4719459
267 Giugliano R, Millward DJ. Growth and zinc homeostasis in the severely Zn-deficient rat. Br J Nutr. 1984; 52(3):545–560. 10.1079/BJN19840122 6498147
268 King JC, Shames DM, Woodhouse LR. Zinc homeostasis in humans. J Nutr. 2000; 130(5):1360S–1366S. 10.1093/jn/130.5.1360S 10801944
269 Hess SY, Peerson JM, King JC, Brown KH. Use of serum zinc concentration as an indicator of population zinc status. Food Nutr Bull. 2007; 28(3) Suppl:S403–S429. 10.1177/15648265070283s303 17988005
270 Magee AC, Matrone G. Studies on growth, copper metabolism of rats fed high levels of zinc. J Nutr. 1960; 72(2):233–242. 10.1093/jn/72.2.233 13765181
271 van Campen DR, Scaife PU. Zinc interference with copper absorption in rats. J Nutr. 1967; 91(4):473–476. 10.1093/jn/91.4.473 6043650
272 Reeves PG. Adaptation responses in rats to long-term feeding of high-zinc diets: Emphasis on intestinal metallothionein. J Nutr Biochem. 1995; 6(1):48–54.10.1016/0955-2863(94)00008-A
273 Wapnir RA, Balkman C. Inhibition of copper absorption by zinc. Biol Trace Elem Res. 1991; 29(3):193–202. 10.1007/BF03032677 1726403
274 Underwood EJ. Trace Elements in Human and Animal Nutrition. 4th ed. Cambridge, MA: Academic Press Inc.; 1977. Zinc; p. 196–242.10.1016/B978-0-12-709065-8.50012-2
275 Oestreicher P, Cousins RJ. Copper and zinc absorption in the rat: Mechanism of mutual antagonism. J Nutr. 1985; 115(2):159–166. 10.1093/jn/115.2.159 3968585
276 Henkin RI, Schecter PJ, Friedewald WT, Demets DL, Raff M. A double blind study of the effects of zinc sulfate on taste and smell dysfunction. Am J Med Sci. 1976; 272(3):285–299. 10.1097/00000441-197611000-00006 797259
277 Johnson MA, Flagg EW. Effects of sucrose and cornstarch on the development of copper deficiency in rats fed high levels of zinc. Nutr Res. 1986; 6(11):1307–1319.10.1016/S0271-5317(86)80040-9
278 Boorman GA, Eustis SL. Proliferative lesions of the exocrine pancreas in male F344/N rats. Environ Health Perspect. 1984;56:213–217. 10.1289/ehp.8456213 6434300
279 Gabrielson KL, Remillard RL, Huso DL. Zinc toxicity with pancreatic acinar necrosis in piglets receiving total parenteral nutrition. Vet Pathol. 1996; 33(6):692–696. 10.1177/030098589603300608 8952028
280 Sutomo FX, Woutersen RA, Van den Hamer CJ. Effects of elevated zinc intake on the copper metabolism and the pancreas of the mouse. J Trace Elem Electrolytes Health Dis. 1992; 6(2):75–80. 1384853
281 Smith PA, Sunter JP, Case RM. Progressive atrophy of pancreatic acinar tissue in rats fed a copper-deficient diet supplemented with D-penicillamine or triethylene tetramine: Morphological and physiological studies. Digestion. 1982; 23(1):16–30. 10.1159/000198706 7084566
282 Millar MJ, Fischer MI, Elcoate PV, Mawson CA. The effects of dietary zinc deficiency on the reproductive system of male rats. Can J Biochem Physiol. 1958; 36(6):557–569. 10.1139/o58-062 13536888
283 Underwood E, Somers M. Studies of zinc nutrition in sheep. I. The relation of zinc to growth, testicular development, and spermatogenesis in young rams. Aust J Agric Res. 1969; 20(5):889–897.10.1071/AR9690889
284 Prasad AS. Zinc deficiency in man. Am J Dis Child. 1976; 130(4):359–361. 10.1001/archpedi.1976.02120050017002 1266819
285 Merrells KJ, Blewett H, Jamieson JA, Taylor CG, Suh M. Relationship between abnormal sperm morphology induced by dietary zinc deficiency and lipid composition in testes of growing rats. Br J Nutr. 2009; 102(2):226–232. 10.1017/s0007114508159037 19222874
286 Kumari D, Nair N, Bedwal RS. Effect of dietary zinc deficiency on testes of Wistar rats: Morphometric and cell quantification studies. J Trace Elem Med Biol. 2011; 25(1):47–53. 10.1016/j.jtemb.2010.11.002 21145718
287 Sankako MK, Garcia PC, Piffer RC, Dallaqua B, Damasceno DC, Pereira OC. Possible mechanism by which zinc protects the testicular function of rats exposed to cigarette smoke. Pharmacol Rep. 2012; 64(6):1537–1546. 10.1016/S1734-1140(12)70951-9 23406764
288 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res Genet Toxicol Environ Mutagen. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
289 Torous DK, Hall NE, Illi‐Love AH, Diehl MS, Cederbrant K, Sandelin K, Pontén I, Bolcsfoldi G, Ferguson LR, Pearson A, et al. Interlaboratory validation of a CD71‐based flow cytometric method (Microflow®) for the scoring of micronucleated reticulocytes in mouse peripheral blood. Environ Mol Mutagen. 2005; 45(1):44–55. 10.1002/em.20081 15605355
290 Dertinger SD, Camphausen K, Macgregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
291 MacGregor JT, Bishop ME, McNamee JP, Hayashi M, Asano N, Wakata A, Nakajima M, Saito J, Aidoo A, Moore MM, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. 10.1093/toxsci/kfl076 16888079
292 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
293 Recio L, Hobbs C, Caspary W, Witt KL. Dose-response assessment of four genotoxic chemicals in a combined mouse and rat micronucleus (MN) and Comet assay protocol. J Toxicol Sci. 2010; 35(2):149–162. 10.2131/jts.35.149 20371966
294 Ghanayem BI, Witt KL, Kissling GE, Tice RR, Recio L. Absence of acrylamide-induced genotoxicity in CYP2E1-null mice: Evidence consistent with a glycidamide-mediated effect. Mutat Res. 2005; 578(1-2):284–297. 10.1016/j.mrfmmm.2005.05.004 15982677
295 Nyquist RA, Kagel RO. Infrared spectra of inorganic compounds (3800-45 cm-1). In Handbook of Infrared and Raman Spectra of Inorganic Compounds and Organic Salts. Vol. 4. San Diego, CA: Academic Press Inc.; 1971; p. 1–18.10.1016/B978-0-12-523450-4.50005-5
296 Koga N, Tanaka H. Thermal decomposition of copper(II) and zinc carbonate hydroxides by means of TG-MS: Quantitative analyses of evolved gase. J Therm Anal Calorim. 2005; 82:725–729.10.1007/s10973-005-0956-3
297 Cao Z, Zhang Z, Wang F, Wang G. Synthesis and UV shielding properties of zinc oxide ultrafine particles modified with silica and trimethyl siloxane. Colloids Surf Physicochem Eng Aspects. 2009; 340(1-2):161–167. 10.1016/j.colsurfa.2009.03.024
298 Du S, Liu H, Chen Y. Large-scale preparation of porous ultrathin Ga-doped ZnO nanoneedles from 3D basic zinc carbonate superstructures. Nanotechnology. 2009; 20(8):085611. 19417459
299 Cameron C. Water-based fluids approach synthetic capabilities. Offshore. 2005;65:44.